# Appendix M Summary of Peer Review Panel Comments

On October 29, 2013, the draft Technical Report on the toxicology and carcinogenesis studies of vinylidene chloride received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.E. Wyde, NIEHS, introduced the studies on vinylidene chloride, a high production volume chemical used to make common household products, artificial turf, pipes, lacquer resins and latex, and flame-resistant carpet backing. Two-week, 3-month, and 2-year inhalation studies were conducted in F344/N rats and B6C3F1/N mice, as well as genetic toxicology studies. The proposed conclusions were clear evidence of carcinogenic activity of vinylidene chloride in male F344/N rats, some evidence of carcinogenic activity of vinylidene chloride in female F344/N rats, and clear evidence of carcinogenic activity of vinylidene chloride in male and female B6C3F1/N mice.

Dr. M.J. Hoenerhoff, NIEHS, described the molecular pathology studies of mesothelioma in vinylidene chloride-exposed F344/N rats. He provided background information about the use of molecular pathology studies, which generate supplementary and supportive data for NTP on molecular characterization of chemically induced rodent tumors. The gene mutation or expression data help discriminate spontaneous tumors from those of chemical-exposed groups, but are not used for levels-of-evidence conclusions in the NTP Technical Reports.

Mr. W.C. Norman, Patton, Boggs LLP, spoke by telephone on behalf of vinylidene chloride producers. Mr. Norman suggested that the vinylidene chloride bioassays in the draft report did not meet the NTP criteria for clear evidence of carcinogenic activity. He noted that there was a total of 18 cancer bioassays of vinylidene chloride using multiple strains of rats, mice, and hamsters in the literature, and the totality of those data did not show consistent evidence of carcinogenicity. Thus, he noted that the NTP cancer bioassays represent the first that demonstrate an apparent increase in tumors in both sexes of two species.

In addition, he said NTP had used dose levels that exceeded the maximum tolerated dose (MTD) in both rats and mice, noting that NTP and EPA guidance point to the need for caution when viewing cancer bioassays that exceed the MTD and suggested that the observed tumors might have arisen as a consequence of stress placed on the animals by dosing at levels above the MTD. Based on that factor, he said the studies should not be considered adequate for the assessment of carcinogenicity, particularly as the results were so different from the previous studies.

Dr. E. Van Miert, Solvay SA, spoke by telephone and focused on the vinylidene chloride genotoxicity assessment. He proposed that the following statement from the draft technical report is not in line with genotoxicity data in the report and public domain: “The results from a variety of genetic toxicology studies…indicate that vinylidene chloride has mutagenic, clastogenic, and aneugenic properties.” He cited several studies referenced in the draft report that indicated negative results with vinylidene chloride as well as the Concise International Chemical Assessment Document 51 from the World Health Organization, a report from the Scientific Committee on Occupational Exposure Limits of the European Commission, and a 2009 REACH [Registration, Evaluation, Authorization and Restriction of Chemicals] dossier of vinylidene chloride that suggest no evidence of genotoxicity with vinylidene chloride. He called for more research on the mode of action of vinylidene chloride.

Dr. N. Ball, Dow Chemical Company, spoke on behalf of the vinylidene chloride producers by telephone. He proposed that the experimental design and conduct of the studies do not support the conclusions regarding clear evidence of carcinogenic activity in male rats and male and female mice and some evidence in female rats. He provided two key reasons: (1) both mouse and rat studies exceeded MTD according to NTP and EPA guidance and (2) inadequate dose spacing and lack of a dose providing a no-observed-adverse-effect level (NOAEL). He discussed his concerns in more detail and asked that the Peer Review Panel consider the studies inadequate to assess carcinogenicity to humans.

Dr. Cattley, the first primary reviewer, recommended that the methods and results concerning genetic toxicology testing be revised to account for different methodologies of bacterial mutagenesis assays. He urged NTP to add findings from the molecular pathology appendix to the Results section. He suggested resolution of an apparent discrepancy between the discussion and introduction sections concerning how data from the 1982 NTP Technical Report on vinylidene chloride were referenced. He asked if a statement regarding “increased incidences of systemic neoplasms” referred only to malignant mesotheliomas or to other tumor types and noted that hemangioma is often considered a benign end-stage lesion. He asked that discussion be added concerning the progression between hemangioma and hemangiosarcoma. He recommended that the discussion concerning the mechanism of action of vinylidene chloride account for the lack of in vivo genotoxicity. He said the report should not characterize vinylidene chloride as a “weak initiator of tumorigenesis” without supporting context in the final sentence of the Discussion section.

Regarding the molecular pathology appendix, Dr. Cattley noted that isolated RNA from malignant mesotheliomas induced by vinylidene chloride was compared to the cultured rat mesothelial cell (Fred-PE cell) RNA, and he asked that NTP discuss the potential for bias arising from different RNA isolation parameters for Fred-PE cells. He questioned why the results for the spontaneous mesothelioma in that study were not presented. He recommended adding a figure from Dr. Hoenerhoff’s presentation to Appendix L to clarify confusion from Figure L-2. He suggested including discussion and explanation of the relationship between inflammation and risk of mesothelioma as cited in the literature. He suggested that NTP discuss the predicted, if not actual gene expression results, of incubating Fred-PE cells with vinylidene chloride, vinylidene chloride metabolites, or vinylidene chloride plus a metabolic activation system. He found the conclusions in the draft report acceptable and agreed with the levels of evidence.

Dr. Gordon, the second primary reviewer, found the vinylidene chloride study well conducted and the draft report well written. He suggested that the “time to first incidence” data deserved mention in the results section. He noted that the addition of the evaluation of global gene changes for the spontaneous vs. induced mesotheliomas is a major step in the right direction; however, the gene expression and pathway analyses should go beyond stating that a proinflammatory environment was associated with mesotheliomas, given that most cancers are thought to be associated with inflammation. He questioned the conclusion that proinflammatory and immune pathway genes were different for spontaneous vs. induced tumors because the gene expression changes presented in Table L-3 appear similar for those pathways. He suggested that Table L-2 needed more definitions. While he would have preferred the study to include some lower doses, he agreed with the conclusions in the draft report.

Dr. Parker, the third primary reviewer, focused his comments on the molecular pathology appendix. He noted that the analysis was done across all genes, so there was strong evidence for the segregation; however, he felt the report should discuss possible factors that could constitute potential sources of bias (e.g., site of the tissue, RNA insolation differences) and include a statement that technical factors were not associated with the gene expression. He noted that there was some segregation in the plot for vinylidene chloride in the principal component analysis (PCA). While that is secondary to the segregation between vinylidene chloride and spontaneous mesothelioma plots, the segregation in the vinylidene chloride plot itself may be important and could potentially be explained by known biological processes. He noted additional methods to illustrate segregation including cross-validation and machine learning techniques. Regarding the oncogenic signatures and inflammatory signatures, he said it was clear that there was significant overlap or enrichment of the genes of interest with these known pathways. However, he asked whether the direction of change supported overexpression or underexpression of those pathways. He suggested that producing a hypothesis or model system about the pathways involved and their direction of change would make the results much stronger. He showed interest for a direct comparison between the vinylidene chloride-exposed and spontaneous mesothelioma microarray datasets; the control dataset may inhibit the detection of other significant pathways. Generally, he agreed with the results of the study.

Dr. Zacharewski, the fourth primary reviewer, also focused on the molecular pathology appendix. He proposed that the global gene profiling study was a valuable, complementary study and could be used to differentiate between spontaneous and treatment-related tumors; however, he suggested the study is not the most appropriate method to use to determine mechanism of action. He did not find the data overly compelling for indicating significant differences between the spontaneous and vinylidene chloride-exposed tumors, and he noted that a PCA is not necessarily a statistical analysis, but more of a classification method. Although the PCA did show some separation, he suggested the separation might have been due to varying treatment of samples (e.g., the RNA was extracted in different ways, tumors were stored for different lengths of time). He suggested there would have been tremendous value in follow-up studies, such as qRT-PCR on individual genes, to demonstrate there were significant differences among the microarrays. He noted that microarrays are “last century’s technology” and RNASeq should be employed in the future.

Dr. Cattley added that the discussion regarding the dose-selection rationale for the 2-year study should be expanded to address the reduction in body weights in the male mice and the incidence and severity of nonneoplastic lesions.

Addressing the issue of the decrease in body weight, Dr. Zacharewski asked for clarification about NTP’s definition of an “inadequate study.” He also asked whether MTD was defined strictly on body weight and survival without looking at any other endpoints. Dr. N.J. Walker, NIEHS, replied that “inadequate” is defined as having major flaws in the design and conduct of a study, and he added that for issues of MTD and dose selection, all available information is considered (e.g., body weight, historic experience); there are no hard and fast guidelines. Dr. Zacharewski asked whether NTP is obliged to follow EPA guidelines, and Dr. Walker stated those guidelines are considered in decision-making, but NTP is not obliged to follow them.

Dr. Barlow remarked that, based on the results of the 3-month study, a dose between 100 and 200 ppm, perhaps 150 ppm, should have been used in the 2-year rat study. Upon reviewing the final data, however, he said it was clear that the doses used were appropriate and the study was adequately designed. He had some ambivalence regarding the data for C-cell tumors in female rats to support the call of clear evidence of carcinogenicity, given that there was not a clear dose response, and he suggested a possible change to some evidence. He noted the gene expression information was useful and interesting, but he questioned how the data would be used and whether those studies should be conducted and reported outside of the technical reports. He asked for NTP’s response on a public comment regarding genotoxicity statements in the discussion section of the draft report: “…a variety of genetic toxicology studies…indicate that vinylidene chloride has mutagenic, clastogenic, and aneugenic properties.” He recommended correction to the statement “fixation quality of the rat testes was poor.” He called for more discussion about the additional carcinogenicity studies in the literature that were not considered adequate.

Dr. Cullen mentioned that NTP had not combined the hepatocholangiocellular carcinomas with the primary liver tumors; however, in later draft technical reports, hepatoblastomas were combined with hepatocellular tumors. He asked for NTP’s rationale regarding what is grouped together and what is not.

Responding to Dr. Cattley’s comments, Dr. Wyde said he would clarify the methodologies for previous studies in the Introduction and Discussion. He would address Dr. Cattley’s suggestion to expand the discussion of the dose-selection rationale, and he acknowledged other editorial suggestions. He acknowledged Dr. Cattley’s and Dr. Barlow’s recommendations to amend the genetic toxicity discussion paragraph.

Dr. Hoenerhoff responded to comments from Dr. Cattley on gene profiling. He acknowledged Dr. Cattley’s concern about potential bias from different RNA isolation parameters, but these parameters did not appear to have an impact on altering gene expression profiles. He would address the issue of different methods of isolation between the cell lines and tumors in the Discussion section. Regarding the spontaneous mesotheliomas, he said they were too small to trigger collection during necropsy, as were the female mesotheliomas. He noted that there was not a significant inflammatory component histologically in the study, and there was not a significant difference in inflammation between the spontaneous and exposed group mesotheliomas. However, the gene expression data suggested that there is a proinflammatory component in vinylidene chloride mesotheliomas and those issues would be discussed further in the report. Regarding the potential gene expression results of incubating Fred-PE cells with vinylidene chloride or vinylidene chloride metabolites, he noted it would be valuable for follow-up in vitro validation experiments or more focused functional experiments.

Dr. Wyde responded to Dr. Gordon’s comments, stating that Dr. Hoenerhoff would address the time-to-tumor incidence data in the Results section. He agreed with Dr. Gordon about the global gene expression analysis being the first step in developing more focused, hypothesis-driven experiments to address specific questions. The gene expression experiment results suggest that there is an increased proinflammatory or immune dysfunction signature, and the Discussion would be updated to add more information on how that may influence tumorigenesis in the study. He noted that an additional figure, as seen in his presentation, would be added to Appendix L. He would address expanding Table L-3 to include more of the differentially expressed genes and genes that are exclusively expressed in vinylidene chloride mesotheliomas compared to spontaneous mesotheliomas.

Addressing Dr. Parker’s comments, Dr. Hoenerhoff said the PCA plot included all of the genes on the array. For the Discussion section, he would address particular factors influencing gene expression that are technical or biologically related to tumor site, dose, or method of RNA extraction. Regarding the variation within the vinylidene chloride treatment group in principal component 3, he said there is some variation in those samples. Additional analysis solely on the vinylidene chloride group could identify how those segregate and if it has any relationship to any other gene expression that might identify a subset of tumors or some kind of biological difference. For future studies, he would consider Dr. Parker’s suggestion about additional studies for validation, cross-validation, or machine learning. He said discussion would be added regarding the directionality of the genes associated with the proinflammatory signature. For the comment about a direct comparison of vinylidene chloride mesotheliomas with spontaneous mesotheliomas, he noted that the results from a direct comparison are difficult to interpret without the context of the normal tissue. NTP could consider a direct comparison in future studies to see if additional information can be gained.

Addressing Dr. Zacharewski’s comments, Dr. Hoenerhoff said Table L-2 and Table L-3 would be amended to include additional genes from a figure in his presentation. This figure would also be added to demonstrate those overrepresented pathways and the genes within those pathways. He said NTP agrees with the value of RNASeq, and that those assays are being implemented in other studies.

Dr. Zacharewski asked whether the microarray data sets were submitted to public repositories such as GEO (Gene Expression Omnibus, NCBI). Dr. Hoenerhoff said they would be submitted to GEO, and that this particular data set is available in CEBS (Chemical Effects in Biological Systems, NIEHS). He added that once the final report is public, the data sets would be deposited into a public section of CEBS and would be available in GEO.

Dr. Wyde addressed Dr. Barlow’s comments regarding the dosing issue, stating that there was 100% mortality at 200 ppm, so there was hesitation about using any higher doses. There were liver and nasal lesions at the 100 ppm dose, so the dosing was appropriate. He said the call regarding C-cell tumors was primarily driven by the benign adenomas in the thyroid gland, and the significant increase in carcinomas was seen only at the low dose. Thus, this was supportive of some evidence, not clear evidence, of carcinogenicity. He agreed that the report would benefit from an expanded discussion of previous carcinogenicity studies.

Dr. D.E. Malarkey, NIEHS, addressed Dr. Cattley’s and Dr. Cullen’s comments about combining hemangiomas and hemangiosarcomas, noting that recent data suggest that hemangiomas can progress to hemangiosarcomas, providing evidence to support combining them for analysis. He said each of the tumor types was considered individually, along with which might be appropriate to combine. Anything that is of the same histogenesis was considered appropriate to combine. Dr. Malarkey acknowledged Dr. Cattley’s suggestion to include the rationale in the report.

Dr. Foster addressed Dr. Barlow’s comment regarding fixation of the testes. He said NTP no longer fixes testes in formalin, which has improved histological profiles. Dr. Barlow noted that the necropsies were performed 6 years earlier. He suggested that the information should be released to the public more quickly, and it was important to keep up with current technology.

Dr. Cattley moved to accept the conclusions as written. Dr. Cory-Slechta seconded the motion. The panel voted unanimously (7 in favor) to accept the conclusions as written.