# Appendix L Global Gene Profiling of Mesothelioma in Vinylidene Chloride-Exposed F344/N Rats

## L.1 Introduction

The 2-year National Toxicology Program (NTP) bioassay indicated that male F344/N rats exposed to vinylidene chloride had statistically significant increases in the incidences of malignant mesotheliomas arising from the tunica vaginalis of the testes. The goal of this study was to investigate global gene expression alterations in mesotheliomas from vinylidene chloride-exposed animals in order to elucidate their chemical-specific gene profiles compared to spontaneous mesotheliomas. We compared global gene expression profiles of mesotheliomas from vinylidene chloride-exposed male F344/N rats, spontaneous mesotheliomas in control male F344/N rats from three other NTP studies (codeine, riddelliine, cobalt metal),^157-159^ and the immortalized, nontransformed, F344/N rat peritoneal mesothelial cell line, Fred-PE, as a control.

## L.2 Materials and Methods

### L.2.1 Sample Collection

For collection of frozen tissues for molecular biology analysis in NTP studies, sections of background and treatment-related tumors or suspect tumors and corresponding tumors from untreated control male and female rats and mice are collected and frozen for animals sacrificed moribund and those sacrificed at study termination. When a tumor is at least 0.5 cm in diameter, one-half of that tumor is collected for fixation in 10% neutral buffered formalin (NBF), and the other corresponding half is flash frozen in liquid nitrogen. Sections of frozen tissue are then utilized for isolation of nucleic acids for quantitative PCR (qPCR) or microarray analysis (RNA), mutation analysis or methylation profiling (DNA), or western blotting or other protein measurements or analyses (protein). In this study, mesothelioma samples were collected from vinylidene chloride-exposed male F344/N rats and frozen sections were used for isolation of RNA for global gene expression profiling analysis and qPCR. Spontaneous mesotheliomas from control male F344/N or F344/NTac rats from other NTP studies (codeine, riddelliine, cobalt metal)^157-159^ were available in the NTP frozen tissue repository for analysis (Table L-1). A nontransformed, immortalized mesothelial cell line was used as a nontumor mesothelial control, as described in previous studies.^160,161^ Fred-PE cells were originally isolated by Dr. DeAngelo (Environmental Protection Agency) and were prepared from the peritoneal cavities of normal F344 male rats. The identity of these cells was previously confirmed by dual immunostaining with pan-cytokeratin and vimentin. RNA from Fred-PE control mesothelial cells was obtained as a generous gift from Dr. Yongbaek Kim, North Carolina State University. Mesothelioma samples for analysis were chosen based on the criteria of size and tumor viability. Tumor size and viability were chosen as criteria for tumor selection in order to maximize the amount and quality of RNA obtained for microarray analysis. Tumor viability was assessed by histopathology of adjacent NBF-fixed, paraffin-embedded samples matched with the frozen samples, in order to choose samples with minimal to no autolysis, necrosis, or hemorrhage.

### L.2.2 Extraction and Quantification of RNA

Extraction of RNA was performed using the Invitrogen PureLink^®^ Mini Kit (Invitrogen catalog no. 12183018A; Invitrogen Corporation, Carlsbad, CA). Frozen tissue samples were lysed and homogenized in TRIzol^®^ reagent (Invitrogen Corporation) using a rotor-stator homogenizer. Isolation of RNA was performed according to Mini Kit protocol. On-column DNase treatment was performed using the PureLink^®^ DNase kit (Invitrogen Corporation) to purify RNA samples. RNA quantification and RNA integrity number were measured on a bioanalyzer (Agilent Technologies, Santa Clara, CA). Samples were aliquoted and stored at −80°C until analyzed.

### L.2.3 RNA Labeling, Microarray Hybridization, and Data Processing

Gene expression analysis was conducted by the National Institute of Environmental Health Sciences, Microarray Core Laboratory using Affymetrix Rat Genome 230 2.0 GeneChip^®^ arrays (Affymetrix, Santa Clara, CA). One hundred ng of total RNA were amplified according to the Affymetrix 3′ IVT Express kit protocol. Amplified biotin-labeled RNA (12.5 μg) was fragmented and 10 μg of sample was hybridized to each array according to the Affymetrix Eukaryotic Target Hybridization protocol, using the provided control input RNA. Array slides were double stained with streptavidin and phycoerythrin and washed for antibody amplification according to the GeneChip^®^ Hybridization, Wash, and Stain Kit user manual. Arrays were scanned in an Affymetrix Scanner 3000, and data was obtained using the GeneChip^®^ Command Console Software (AGCC; Version 1.1) using the MAS5 algorithm to generate .CHP files.

Probe intensity data from all arrays were entered into the R software environment <http://www.R-project.org> directly from .cel files using the R/affy package.^162^ Image reconstruction, intensity histograms, and boxplots were used to evaluate data quality. During quality control procedures, image reconstruction indicated that one vinylidene chloride sample had a large smudge (animal 604), so this sample was removed from the analysis. The remaining 19 samples (six Fred-PE cell lines, five spontaneous mesotheliomas, eight vinylidene chloride-exposed mesotheliomas) were normalized using the robust multiarray average (RMA) method to form one expression measure for each gene on each array.^163^ The RMA method adjusts the background of perfect match (PM) probes, applies a quantile normalization of the corrected PM values, and calculates final expression measures using the Tukey median polish algorithm. Pairwise comparisons were made for each probeset between Fred-PE cells and each tumor group (spontaneous mesothelioma, vinylidene chloride-exposed mesothelioma) using a bootstrap t-test while controlling for the mixed directional false discovery rate (mdFDR) at 0.05 (5%). The mdFDR procedure controls the overall false discovery rate across multiple comparisons and takes into account directional errors corresponding to upregulated or downregulated genes.^164^ Statistical calculations were performed in the ORIOGEN software package using 10,000 bootstrap samples.^165^

A core analysis comparing the three experimental groups (Fred-PE mesothelial cells, spontaneous mesotheliomas, and vinylidene chloride-exposed mesotheliomas) was performed to identify differentially expressed genes in vinylidene chloride-exposed and spontaneous mesotheliomas compared to Fred-PE mesothelial cells. A comparison analysis of the significantly differentially expressed genes between spontaneous mesotheliomas and vinylidene chloride-exposed mesotheliomas was then performed to identify relevant biologic functions, canonical pathways, and transcription factor activation. Through testing for the association of gene products with a curated database of biological networks [Ingenuity Pathways Analysis™ (IPA) version 9.0; Ingenuity Systems, Inc., Redwood City, CA] <https://www.ingenuity.com/>, overrepresented gene categories were identified. Significantly differentially expressed genes (P < 0.001) in the IPA core analysis were then grouped by pathways to account for upstream and downstream effectors as well as overlapping pathways. Upstream activation was based on an IPA Z-score of greater than 2.0 with no bias. All .cel files are available in the Chemical Effects in Biological Systems database <https://www.niehs.nih.gov/research/resources/databases/cebs/index.cfm>.

## L.3 Results

Global gene expression analysis enabled the identification of distinct genomic signatures that differentiated between mesotheliomas in vinylidene chloride-exposed animals and spontaneous mesotheliomas in control animals. Using a principal components analysis, there was distinct clustering of samples within each experimental group, while there was clear separation of samples between each experimental group, based on significantly differentially expressed genes (Figure L-1). Using Fred-PE mesothelial cells as a baseline for gene expression, a comparison analysis between spontaneous mesotheliomas and mesotheliomas in vinylidene chloride-exposed animals showed that of the 31,099 probesets on the array, the two tumor groups shared 10,372 probesets, while 3,764 probesets were unique to vinylidene chloride-exposed mesotheliomas and 3,612 probesets were unique to spontaneous mesotheliomas. Of the 10,372 shared probesets, 9,568 were mapped to known genes in the IPA database and 7,454 were considered analysis ready according to IPA based on a threshold of P < 0.001 and filtering for duplicates. IPA core analysis was used to correlate the 7,454 probesets with relevant biological functions. Biological functions representative of the top up and downregulated genes in both tumor groups included cellular development, cell and tissue morphology, organismal injury, embryonic development, organ and tissue development, inflammatory response, cellular growth and proliferation, and cell cycle regulation, with many of the probesets showing overlapping biological functions in multiple categories, while overrepresentation of DNA replication, recombination, and repair was observed as statistically significant in mesotheliomas from vinylidene chloride-exposed animals and not in spontaneous mesotheliomas (Figure L-2).

There was significant differential expression of several oncogenes, growth factors, cell cycle regulators, embryonic genes, cell survival genes, and solute carrier molecules in both spontaneous and vinylidene chloride-exposed mesotheliomas compared to Fred-PE cells (P < 0.001) (Table L-2). There was significant overlap of genes associated with cell growth and tissue remodeling (Tgfβ2, Tgfβr1, Vegfc, Fgfr2, Igf1, Igfbp), cell cycle regulators (Cdkn1a, Cdkn1b), oncogenes and proto-oncogenes (Mafb, Fos, Junb, Lyn), RAS-Mapk pathway mediators (Rasd1, Rnd, Prkcb, Mapk12), tumor suppressor genes (Tp53, Lats2), adhesion molecules (Epcam, Cdh22, Ctnnb1, Itgb2), apoptosis genes (Gadd45b, Bcl2a1), developmental genes (Plac8, Wnt4, Plau, Gata5), transporters and solute carriers (Slc7, Slc28, Abc), mesothelial cell markers (Krt18/19, Des) and genes associated with oxidative stress (Duox, Gpx2), compared to Fred-PE cells. In many cases, the expression of these genes was fairly similar between spontaneous and vinylidene chloride-exposed mesotheliomas, with both tumor types showing overlapping of genes associated with multiple categories. However, there were noticeable differences in the expression of some genes from each tumor group.

Mesotheliomas from control animals and vinylidene chloride-exposed animals shared genes associated with the overrepresented biologic category inflammatory response as involved in tumorigenesis (Figure L-2). Genes associated with inflammatory response included chemokines (Ccl5/6/11/27, Cxcl9/11), cytokines and cytokine receptors (Il1rn, Il6r, Il10/18/24/34, Tnfrsf11b, Cd40, Il1b, Il7r), cell surface receptors (Fcer, Fcgr, S1pr1, Stab1, Cd163, Cd68, Cd53, Clec, Cd36), pattern recognition receptors (Tlr2/7/8, Mrc1), interferon pathway mediators (Ifngr1, Irf5, Irf9, Ifitm1), activated macrophage products (Chi3l1, Sparcl1, C1qa, C1qb, S100a9), complement factors (C1qa/b, Cfh, Serping1), and a variety of inflammatory mediators (Aif1, Ptgds1/2, Lyz2, Mcpt10, Tdo2, Ubd, Cybb, Pla2g2a, Lyve1, Ddx60) compared to Fred-PE cells (P < 0.001) (Table L-3). There was differential expression of several of these shared genes between tumor groups, including upregulation of proinflammatory chemokines (Ccl5, Ccl6, Cxcl9) and decreased expression of anti-inflammatory cytokines (Il10, Il18, Il24). There was higher upregulation of genes associated with tissue damage (Tlr2, Mrc1, Pla2g2a, Dpt) and damage-associated molecular pattern (DAMP) molecules (Mrc1, Lyve1, S100a8, S100a9), in vinylidene chloride-exposed mesotheliomas.

In contrast to the above shared overrepresented pathways, there were several canonical pathways associated with inflammation and immune response that were significantly overrepresented in mesotheliomas from vinylidene chloride-exposed animals compared to Fred-PE cell line control (P < 0.05), which were not significantly overrepresented in spontaneous tumors (Figure L-3). These included proinflammatory pathways such as PI3K/AKT signaling (Ccl5, Plac8, Gnai3, Nfkb2), the NF-kB signaling pathway (Il1r2, Il33, Egf, Ghr, Plcg2, Tlr4), IL-8 (Irak2, Myl2, Hmox1, Prkd3, Mmp2, Mmp9, Gnai3) and IL-12 (Prkd3, Apod, S100a8, Rbp4, Pik3r3, Prkce) interleukin responses, Fc receptor signaling (Vav3, Fcgr2b, Plcg2, Sos1, Cd79b, Pkpd1, Mapk9), and NK and DC signaling (Klrc2, Pak2, Acta1, Actc1, Camk2b, Cd69, Faslg, Tlr4, Pak4), among others (Table L-3 and Figure L-3). While spontaneous mesotheliomas and mesotheliomas from vinylidene chloride-exposed animals shared similar expression of a number of genes in these categories compared to Fred-PE cells, based on canonical pathway involvement, there was significant overrepresentation of pathways associated with a proinflammatory phenotype and immune dysfunction in mesotheliomas from vinylidene chloride-exposed animals. Select genes from these pathways were validated by qPCR (Table L-4).

## L.4 Discussion

Comparison of global gene expression profiling of mesotheliomas arising in male F344/N rats exposed to vinylidene chloride, spontaneous mesotheliomas in F344/N rats, and cultured rat mesothelial cells (Fred-PE cells) was performed in order to characterize the molecular features of these tumors and elucidate their chemical-specific gene expression profiles. Global gene expression profiling enabled the separation of these tumors based on their transcriptomic profiles, despite an indistinguishable morphologic difference between spontaneous and vinylidene chloride-exposed mesotheliomas. The principal component analysis (PCA) plot illustrating statistically significantly differentially expressed genes showed clear clustering of samples within groups, and separation of experimental groups. Furthermore, variations in site, vehicle, and dose did not significantly impact the global gene expression analysis in this study. Spontaneous mesotheliomas were obtained from control animals in three 2-year NTP bioassays that used different routes of administration (gavage, feed, and inhalation), and three of the five spontaneous tumors were collected from different sites within the same animal (cobalt metal study) (Table L-1). Regardless of these variables, the spontaneous tumors showed tight clustering and overlap on the PCA. In addition, the three spontaneous tumor samples obtained from the single animal overlapped and admixed with the tumor samples from the other studies (riddelliine and codeine), indicating that the tumor samples from the single animal did not cluster together. In terms of mesotheliomas from vinylidene chloride-exposed animals, samples did not cluster based on exposure concentration or site of collection. Finally, in terms of the Fred-PE cell line control, it is well known that variations in RNA collection, time in culture, cell passage, and other in vitro factors when using these cells may contribute to variation in gene expression. However, the Fred-PE samples clustered very tightly together, and neither passage number nor RNA isolation variables significantly impacted gene expression analysis in this study.

Similarities between spontaneous mesotheliomas and those from vinylidene chloride-exposed animals primarily involved genes associated with tumorigenesis. Commonly affected biologic functions involved a number of similarly expressed oncogenes, tumor suppressor genes, growth factors, embryonic genes, and apoptosis genes in both tumor groups (Table L-2). For example, there was consistent representation of the Tgfβ and Igf pathways in mesotheliomas from vinylidene chloride-exposed and control rats; these pathways are important in tissue remodeling of many organs during disease and tumorigenesis, including mesothelioma.^166^ However, differences in common pathways between tumors from control and vinylidene chloride-exposed animals were often noted; for example, overrepresentation of DNA replication, recombination, and repair was observed as a statistically significantly overrepresented biologic function only in mesotheliomas from vinylidene chloride-exposed animals, suggesting an association of these genes with vinylidene chloride exposure that may reflect differences in DNA repair between the two tumor groups. Furthermore, differences in the expression of individual genes from shared overrepresented biologic functions were also noted. For example, dermatopontin (Dpt), which is known to interact with Tgfβ to enhance its biologic activity,^167^ was markedly upregulated in mesotheliomas from vinylidene chloride-exposed animals compared to controls (Table L-4). Based on significantly overrepresented canonical pathways, vinylidene chloride-exposed mesotheliomas were distinguished from spontaneous mesotheliomas by a proinflammatory phenotype and immune dysfunction. While the exact effects of vinylidene chloride on mesothelial cells are not known, the increased incidence of mesotheliomas in the 2-year study resulting from vinylidene chloride exposure suggests that long-term exposure to vinylidene chloride directly or indirectly affects mesothelial cell function. It has been shown that exposure to vinylidene chloride results in saturation of the glutathione pathway and the generation of reactive vinylidene chloride metabolites (1,1-diethylene oxide, chloroacetyl chloride), which have potential to cause tissue damage.^142^ Inflammation is also a well-known contributor to mesotheliomagenesis,^139-141^ consistent with the overrepresentation of genes associated with immune dysregulation, inflammation, and tissue damage observed in this study associated with vinylidene chloride-exposed mesotheliomas. Several of the pathways that were significantly overrepresented in mesotheliomas from vinylidene chloride-exposed animals and not observed in spontaneous mesothelioma involved well-known proinflammatory pathways such as the NF_Ƙ_B pathway, and the IL-8/Il-12 proinflammatory pathways. The NF_Ƙ_B pathway is a key orchestrator between pathways mediating cell stress, inflammation, and cancer.^168^ IL-8 plays a major role in chemotaxis of inflammatory cells, phagocytosis, and angiogenesis,^169^ and IL-12 stimulates production of interferon-gamma (IFNɤ) and tumor necrosis factor alpha (TNFɑ) from cytotoxic T cells and natural killer (NK) cells.^170^ Activation of these cytotoxic pathways can play a role in cytotoxicity and apoptosis in the innate and adaptive immune response as well as in response to neoplastic disease. Direct damage to mesothelial cells from inflammation or reactive metabolites can lead to cell proliferation and/or innate immune response activation. Responses such as these have been associated with mesothelial cell proliferation.^143^ Chronic inflammation (primarily due to pulmonary asbestosis) is a well-known risk factor in human mesothelioma and is known to play a role in carcinogenic transformation and progression. Histologic evidence of inflammation is generally a component of human mesothelioma; in this study, minimal evidence of inflammation was present in mesotheliomas from control and vinylidene chloride-exposed animals, and there was not a significant difference in inflammation between the tumor groups. However, previous gene expression analysis in spontaneous mesothelioma has shown that inflammatory and immune response pathways are overrepresented, despite a relative lack of a significant histologically evident inflammation.^171^ This is consistent with what is being reported in the current study, with an increased representation of these proinflammatory pathways and immune dysfunction in mesotheliomas from vinylidene chloride-exposed animals.

Key differences in differential gene expression observed between spontaneous mesotheliomas and mesotheliomas occurring in vinylidene chloride-exposed animals differentiated these tumors from each other based on their global transcriptomic profiles, despite indistinguishable morphology. Furthermore, these data provide important mechanistic information regarding genomic alterations associated with chemical exposure. These genomic studies provide a better understanding of the molecular features of mesotheliomas arising in vinylidene chloride-exposed F344/N rats.

Table L-1 Spontaneous and Vinylidene Chloride-Exposed Malignant Mesotheliomas from Male F344/N Rats Used for Genomic Profiling

Dose | Study | Animal Number | Frozen ID | Weight (g) | Location
Control | Riddelliine | 5 | SO2130 | 0.5200 | Peritoneum
Control | Codeine | 19 | MB194 | 1.0000 | Peritoneum
Control | Cobalt metal | 34 | BW 4719 | 1.1050 | Peritoneum
Control | Cobalt metal | 34 | BW 4721 | 0.5179 | Peritoneum
Control | Cobalt metal | 34 | BW 4723 | 0.5406 | Testes, capsule
50 ppm | Vinylidene chloride | 401 | BW 2457 | 0.7086 | Peritoneum
50 ppm | Vinylidene chloride | 401 | BW 2447 | 0.3128 | Mesentery
50 ppm | Vinylidene chloride | 402 | BW 2304 | 1.1392 | Mesentery
100 ppm | Vinylidene chloride | 601 | BW 2287 | 1.2258 | Testes, capsule
100 ppm | Vinylidene chloride | 613 | BW 2353 | 0.3700 | Testes, capsule
100 ppm | Vinylidene chloride | 632 | BW 2259 | 0.9484 | Testes, capsule
100 ppm | Vinylidene chloride | 640 | BW 2281 | 0.9158 | Testes, capsule
100 ppm | Vinylidene chloride | 646 | BW 2276 | 0.9109 | Testes, capsule

Table L-2 Selected Significantly Expressed Pathways in Mesotheliomas from Vinylidene Chloride-Exposed and Control F344/N Rats Compared to Fred-PE Cells (P < 0.001)^a^

Gene Name | Gene Symbol | Spontaneous | Vinylidene Chloride-Exposed
Growth Factors
Transforming growth factor, beta 2 | Tgfâ2 | −18.77 | −18.94
Transforming growth factor, beta receptor 1 | Tgfâr1 | 2.07 | 1.80
Transforming growth factor, beta-induced, 68kDa | Tgfâi | 39.53 | 48.79
Vascular endothelial growth factor C | Vegfc | −7.26 | −8.00
Fibroblast growth factor receptor 2 | Fgfr2 | −1.79 | −1.53
Insulin-like growth factor 1 (somatomedin C) | Igf1 | 17.04 | 37.54
Insulin-like growth factor 2 binding protein 1 | Igf2bp1 | −2.80 | −2.70
Insulin-like growth factor binding protein 3 | Igfbp3 | 32.46 | 29.23
Insulin-like growth factor binding protein 6 | Igfbp6 | 9.96 | 8.42
Cell Cycle
Cyclin-dependent kinase inhibitor 1A (p21, Cip1) | Cdkn1a | −4.60 | −6.67
Cyclin-dependent kinase inhibitor 1B (p27, Kip1) | Cdkn1b | −5.68 | −4.95
Oncogenes/Proto-oncogenes
v-Maf musculoaponeurotic fibrosarcoma oncogene homolog B (avian) | Mafb | 23.48 | 26.02
FBJ murine osteosarcoma viral oncogene homolog | Fos | −9.09 | −7.02
Jun B proto-oncogene | Junb | −4.51 | −6.29
v-Yes-1 Yamaguchi sarcoma viral related oncogene homolog | Lyn (v-yes) | 5.02 | 5.44
RAS-Mapk Pathway
RAS, dexamethasone-induced 1 | Rasd1 | 38.52 | 14.18
Rho family GTPase 1 | Rnd1 | −13.26 | −8.60
Rho family GTPase 3 | Rnd3 | −11.37 | −28.00
Protein kinase C, beta | Prkcb | 68.52 | 53.86
Mitogen-activated protein kinase 9 | Mapk9 | −1.15 | 1.34
Mitogen-activated protein kinase 12 | Mapk12 | 5.53 | 8.21
Mitogen-activated protein kinase-activated protein kinase 3 | Mapkapk3 | 15.13 | 11.95
Tumor Suppressor Genes
Tumor protein p53 | Tp53 | −2.20 | −2.80
Large tumor suppressor homologue 2 | Lats2 | −1.82 | −1.87
Adhesion Molecules, Integrins, Catenins
Epithelial cell adhesion molecule | Epcam | 21.48 | 12.63
Cadherin 22, type 2 | Cdh22 | 128.56 | 22.82
Catenin (cadherin-associated protein), beta 1, 88kDa | Ctnnb1 | −1.41 | −2.09
Integrin, beta 2 (complement component 3 receptor 3 and 4 subunit) | Itgb2 | 23.11 | 33.51
Growth Arrest, Apoptosis
Growth arrest and DNA-damage-inducible, beta | Gadd45b | −10.34 | −8.88
BCL2-related protein A1 | Bcl2a1 | 14.42 | 13.86
Fas apoptotic inhibitory molecule 3 | Faim3 | 9.43 | 17.41
Embryonic/Cell Development (Cell Migration, Differentiation)
Placenta-specific 8 | Plac8 | 44.99 | 214.04
Wingless-type MMTV integration site family, member 4 | Wnt4 | 10.91 | 6.00
Plasminogen activator, urokinase | Plau | 18.08 | 21.11
GATA binding protein 5 | Gata5 | 14.53 | 7.91
Adhesion Molecules and Matrix Remodeling Genes
Collagen, type VI, alpha 1 | Col6a1 | 57.66 | 35.84
Collagen, type VI, alpha 2 | Col6a2 | 65.56 | 26.35
Integrin, beta 2 (complement component 3 receptor 3 and 4 subunit) | Itgb2 | 23.11 | 33.51
Transporters and Solute Carriers
Solute carrier family 7, member 7 | Slc7A7 | 14.24 | 11.70
Solute carrier family 7, member 9 | Slc7A9 | 12.44 | 9.67
Solute carrier family 28, member 2 | Slc28A2 | 14.32 | 26.94
ATP-binding cassette, subfamily A (ABC1), member 4 | Abca4 | 33.55 | 26.82
Mesothelial Cell Markers
Cytokeratin 18 | Krt18 | 145.17 | 75.19
Cytokeratin 19 | Krt19 | 440.67 | 299.57
Thrombomodulin | Thbd | 27.52 | 49.60
Desmin | Des | 22.17 | 26.26
Reactive Oxygen Species
Dual oxidase 2 | Duox2 | 87.37 | 44.62
Glutathione peroxidase 2 (gastrointestinal) | Gpx2 | 88.16 | 68.67

^a^ Numeric values expressed are fold changes in gene expression compared to Fred-PE mesothelial cells.

Table L-3 Selected Differentially Expressed Genes Associated with Inflammation and Immune Response in Vinylidene Chloride-Exposed and Spontaneous Mesotheliomas Compared to Fred-PE Cells (P < 0.001)^a^

Gene Name | Gene Symbol | Spontaneous | Vinylidene Chloride-Exposed
Chemokines
Chemokine (C-C motif) ligand 5 | Ccl5 | 19.0 | 35.6
Chemokine (C-C motif) ligand 6 | Ccl6 | 84.5 | 143.6
Chemokine (C-C motif) ligand 11 | Ccl11 | 742.5 | 457.6
Chemokine (C-C motif) ligand 27 | Ccl27 | 14.6 | 7.3
Chemokine (C-X-C motif) ligand 9 | Cxcl9 | 6.6 | 24.0
Chemokine (C-X-C motif) ligand 11 | Cxcl11 | 6.5 | 19.1
Interleukin Signaling
Interleukin 1 receptor, type 2 | Il1r2 | – | 3.2
Interleukin 1 receptor antagonist | Il1rn | 10.0 | 5.5
Interleukin 1 beta | Il1b | 2.04 | 3.03
Interleukin 6 receptor | Il6r | 7.4 | 6.0
Interleukin 7 receptor | Il7r | 6.687 | 6.11
Interleukin 10 | Il10 | 17.9 | 11.5
Interleukin 18 (interferon-gamma-inducing factor) | Il18 | 43.5 | 28.9
Interleukin 24 | Il24 | 25.5 | 10.6
Interleukin 33 | Il33 | – | 21.1
Interleukin 34 | Il34 | 9.0 | 5.5
Interleukin-1 receptor-associated kinase 2 | Irak2 | – | 2.3
Tumor necrosis factor receptor superfamily, member 11b | Tnfrsf11b | 42.4 | 65.7
CD40 molecule, TNF receptor superfamily member 5 | Cd40 | 9.1 | 3.0
Myosin, light chain 2, regulatory, cardiac, slow | Myl2 | – | 34.2
Heme oxygenase 1 | Hmox1 | – | 2.7
Epidermal growth factor | Egf | – | 2.4
Growth hormone receptor | Ghr | – | 7.4
CD74 molecule, major histocompatibility complex, class II | Cd74 | 440.5 | 398.0
Natural Killer Cell and Dendritic Cell Signaling
SH2 domain containing 1A | Sh2d1a | – | 3.8
Vav3 guanine nucleotide exchange factor | Vav3 | – | 2.6
Fc fragment of IgE, high affinity I, receptor for; alpha polypeptide | Fcer1a | 37.8 | 35.5
Fc fragment of IgE, high affinity I, receptor for; gamma polypeptide | Fcer1g | 104.6 | 93.9
Fc fragment of IgG, low affinity IIa, receptor | Fcgr2a | 46.1 | 70.4
Fc fragment of IgG, low affinity IIb, receptor (CD32) | Fcgr2b | 195.4 | 260.5
Fc fragment of IgG, low affinity IIIa, receptor (CD16a) | Fcgr3a | 54.9 | 24.7
Killer cell lectin-like receptor subfamily C, member 2 | Klrc2 | – | 2.1
Killer cell lectin-like receptor subfamily C, member 3 | Klrc3 | – | 2.1
Killer cell lectin-like receptor subfamily D, member 1 | Klrd1 | 6.5 | 9.3
P21-activated kinase 4 | Pak4 | – | −2.16
Phospholipase C, gamma 2 (phosphatidylinositol-specific) | Plcg2 | – | 2.1
Protein kinase D3 | Prkd3 | – | 1.7
Protein kinase C, theta | Prkcq | 5.2 | 8.7
P21 protein (Cdc42/Rac)-activated kinase 2 | Pak2 | – | 1.7
Actin, alpha 1, skeletal muscle | Acta1 | – | 77.6
Actin, alpha, cardiac muscle 1 | Actc1 | – | 8.4
Calcium/calmodulin-dependent protein kinase II alpha | Camk2a | −1.3 | 3.0
Calcium/calmodulin-dependent protein kinase II beta | Camk2b | – | 4.8
CD69 molecule | Cd69 | – | 4.5
Fas ligand (TNF superfamily, member 6) | Faslg | – | 2.2
Hematopoietic cell signal transducer | Hcst | 21.1 | 23.7
Pattern Recognition Receptors
Toll-like receptor 2 | Tlr2 | 8.3 | 10.1
Toll-like receptor 4 | Tlr4 | – | 1.8
Toll-like receptor 7 | Tlr7 | 10.7 | 14.0
Toll-like receptor 8 | Tlr8 | 25.7 | 31.7
Mannose receptor, c-type 1 | Mrc1 | 78.6 | 113.0
Interferon Pathway Mediators
Interferon gamma receptor 1 | Ifngr1 | 2.3 | 2.7
Interferon regulatory factor 5 | Irf5 | 2.2 | 2.1
Interferon regulatory factor 9 | Irf9 | 4.0 | 2.9
Interferon induced transmembrane protein 1 | Ifitm1 | 20.2 | 27.5
Inflammatory Mediators/Enzymes/Miscellaneous
Allograft inflammatory factor 1 | Aif1 | 171.6 | 115.8
Apolipoprotein D | Apod | – | 3.897
Phospholipase C, gamma 2 | Plcg2 | – | 2.1
Matrix metalloproteinase 2 | Mmp2 | – | 16.7
Matrix metalloproteinase 9 | Mmp9 | – | 2.7
Guanine nucleotide-binding protein, alpha subunit 3 | Gnai3 | – | 2.81
Nuclear factor of kappa light polypeptide gene enhancer in b-cells 2 | Nfkb2 | – | −1.52
Prostaglandin D2 synthase 21kDa | Ptgds | 270.0 | 144.6
Prostaglandin-endoperoxide synthase 1 | Ptgs1 | 25.6 | 23.7
Prostaglandin-endoperoxide synthase 2 | Ptgs2 | −91.0 | −58.1
Placenta-specific 8 | Plac8 | 44.99 | 214.04
Lysozyme 2 | lyz2 | 217.9 | 209.0
Mast cell protease 10 | Mcpt10 | 226.3 | 68.9
Tryptophan 2,3-dioxygenase | Tdo2 | 218.9 | 60.5
Ubiquitin D | Ubd | 173.2 | 274.0
Cytochrome b-245, beta polypeptide | Cybb | 21.3 | 30.6
Phospholipase A2, group IIA | Pla2g2a | 86.1 | 110.4
Dermatopontin | Dpt | 14.73 | 57.77
Protein kinase C, epsilon | Prkce | −2.18 | –
Phosphoinositide-3-kinase, regulatory subunit 3 | Pik3r3 | −1.8 | –
Lymphatic vessel endothelial hyaluronan receptor 1 | Lyve1 | 87.0 | 247.7
Chitinase 3-like 1 | Chi3l1 | 164.4 | 29.9
SPARC-like 1 (hevin) | Sparcl1 | 71.0 | 147.8
Complement component 1, q subcomponent, A chain | C1qa | 134.5 | 133.4
Complement component 1, q subcomponent, B chain | C1qb | 110.9 | 102.9
Complement factor H | Cfh | 285.37 | 223.67
S100 calcium binding protein A8 | S100a8 | 2.7 | 18.5
S100 calcium binding protein A9 | S100a9 | 4.0 | 19.2
Serpin peptidase inhibitor, clade G | Serping1 | 265.08 | 289.04
Protein phosphatase 1, regulatory subunit 3A | Ppp1r3a | – | 38.986
Retinol binding protein 4, plasma | Rbp4 | – | 15.544
Cell Surface Markers/Receptors
Sphingosine-1-phosphate receptor 1 | S1pr1 | 25.6 | 48.5
Son of sevenless homolog 1 | Sos1 | – | −1.2
CD79b molecule, immunoglobulin-associated beta | Cd79b | – | −1.2
Stabilin 1 | Stab1 | 55.0 | 36.2
3-phosphoinositide dependent protein kinase-1 | Pkpd1 | ‒ | −1.4
Fc fragment of IgG, high affinity Ia, receptor (CD64) | Fcgr1a | 29.3 | 29.3
Fc fragment of IgG, low affinity IIa, receptor (CD32) | Fcgr2a | 40.8 | 70.4
CD14 molecule | Cd14 | ‒ | 2.7
CD53 molecule | Cd53 | 137.2 | 139.8
CD68 molecule | Cd68 | 29.4 | 34.6
CD163 molecule | Cd163 | 46.7 | 132.3
C-type lectin domain family 4, member a3 | Clec4a3 | 92.1 | 73.3
C-type lectin domain family 4, member A | Clec4a | 35.3 | 32.6
C-type lectin domain family 7, member A | Clec7a | 29.1 | 22.8
C-type lectin domain family 10, member A | Clec10a | 48.1 | 54.3
CD36 molecule (thrombospondin receptor) | Cd36 | 139.7 | 236.3

^a^ Numeric values expressed are fold changes in gene expression compared to Fred-PE mesothelial cells.

‒Not differentially expressed on microarray.

Table L-4 Quantitative PCR (qPCR) Validation of Gene Expression Changes on Microarray of Spontaneous and Vinylidene Chloride-Exposed Mesotheliomas in F344/N Rats^a^

Gene Name | Gene Symbol | Spontaneous | | Vinylidene Chloride-Exposed
| | Microarray | qPCR | Microarray | qPCR
Cytokeratin 18 | Krt18 | 162.94 | 1,079.19 | 75.19 | 473.86
Epithelial cell adhesion molecule | Epcam | 21.48 | 481.96 | 12.63 | 860.43
Cyclin-dependent kinase Inhibitor 1A (p21) | Cdkn1a | −4.6 | −2.88 | −6.67 | −3.97
Fatty acid binding protein 4 | Fabp4 | 72.71 | 2,705.77 | 251.32 | 12,796.5
Placenta-specific 8 | Plac8 | 44.99 | 16,744.15 | 214.04 | 25,150.22
Synuclein, gamma | Sncg | 9.53 | 745.92 | 25.59 | 3,094.01
Dermatopontin | Dpt | 14.73 | 2,397.67 | 57.77 | 13,203.71
Tumor protein p53 | Tp53 | −2.2 | −1.11 | −2.8 | −1.67

^a^ Numeric values expressed are fold changes in gene expression compared to Fred-PE mesothelial cells.

Figure L-1

Principal Component Analysis Comparing Global Gene Profiles of Fred-PE Mesothelial Cells (Red), Spontaneous Mesotheliomas from Control Rats (Blue), and Mesotheliomas from Vinylidene Chloride-Exposed Rats (Green)

Principal component analysis shows significant intergroup similarities in global gene expression and clear separation of experimental groups in space, indicating significant differences between groups in terms of their global gene expression. Principal component analysis is a multivariate data analysis procedure that linearly transforms the original data set (N genes × P samples) so that each principal component (1 × P) becomes a variable that is a combination of the original variables and is orthogonal to all other principal components. The total variance explained by the principal component analysis is 69.6%. Each axis explains a certain percentage of the variance in the data; the x-axis explains the most variance (52.8%), the y-axis explains the second most variance (11.4%), and the z-axis explains the third most variance (5.4%) between the 19 samples.

Figure L-2

Top Overrepresented Biologic Functions Related to Tumorigenesis in Spontaneous Mesotheliomas and Mesotheliomas from Vinylidene Chloride-Exposed Male F344/N Rats (P ˂ 0.05)

Figure L-3

Significantly Overrepresented Canonical Pathways Related to Inflammation and Immune Dysfunction Not Overrepresented in Spontaneous Mesotheliomas (P ˂ 0.05)