# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected, allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and tested in-house or sent to BioReliance Corporation (Rockville, MD) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex at each time point except four female mice at 12 months and four male rats at 18 months in the 2-year studies. Fecal samples were collected from five male and five female mice during the 2-year study.

Table K-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Two-week Study
In-house Antibody Testing
Mycoplasma pulmonis | Study termination
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
RPV (rat parvovirus) | Study termination
Sendai | Study termination
Three-month Study
In-house Antibody Testing
M. pulmonis | 2 weeks
PVM | 2 weeks
RCV/SDA | 2 weeks
RPV | 2 weeks
Sendai | 2 weeks
ELISA
Mycoplasma arthritidis | Study termination
M. pulmonis | Study termination
PVM | Study termination
RCV/SDA | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
In-house Antibody Testing
M. pulmonis | 2 weeks
PVM | 2 weeks
RCV/SDA | 2 weeks
RPV | 2 weeks
Sendai | 2 weeks
ELISA
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | 6, 12, and 18 months, study termination
RCV/SDA | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
Immunofluorescence Assay
Parvovirus | 6, 12, and 18 months, study termination
Mice
Two-week Study
In-house Antibody Testing
GDVII (Theiler’s murine encephalomyelitis virus) | Study termination
MHV (mouse hepatitis virus) | Study termination
MPV (mouse parvovirus) | Study termination
M. pulmonis | Study termination
PVM | Study termination
Sendai | Study termination
Three-month Study
In-house Antibody Testing
GDVII | 2 weeks
MHV | 2 weeks
MPV | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
GDVII | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
MAd-FL (mouse adenovirus) | Study termination
MHV | Study termination
MMV VP2 (mouse minute virus) | Study termination
MPV VP2 (mouse parvovirus) | Study termination
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | Study termination
Reovirus | Study termination
Sendai | Study termination
Immunofluorescence Assay
MCMV (mouse cytomegalovirus) | Study termination
Two-year Study
In-house Antibody Testing
GDVII | 2 weeks
MHV | 2 weeks
MPV | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
ELISA
Ectromelia virus | 6, 12, and 18 months, study termination
EDIM | 6, 12, and 18 months, study termination
GDVII | 6, 12, and 18 months, study termination
LCM | 6, 12, and 18 months, study termination
MAd-1 | 6, 12, and 18 months, study termination
MHV | 6, 12, and 18 months, study termination
MMV VP2 | 6, 12, and 18 months, study termination
MPV VP2 | 6, 12, and 18 months, study termination
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | 6, 12, and 18 months, study termination
Reovirus | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
Immunofluorescence Assay
EDIM | 12 and 18 months
GDVII | 18 months
MCMV | Study termination
MMV | 12 and 18 months
MPV | 18 months
PVM | 18 months
Reovirus | 12 months
Polymerase Chain Reaction
Helicobacter species | 18 months

## K.2 Results

All test results were negative.