# Appendix I Chemical Characterization and Generation of Chamber Concentrations

## I.1 Procurement and Characterization of Vinylidene Chloride

Vinylidene chloride, manufactured by Dow Chemical Company (Freeport, TX), was obtained in one lot from Sigma-Aldrich and was used in the 2-week, 3-month, and 2-year studies. The material was identified as lot SB20019301. Identity and purity analyses were conducted by the analytical chemistry laboratory at Chemir Pharma Services (Maryland Heights, MO) and the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the vinylidene chloride studies are on file at the National Institute of Environmental Health Sciences.

Lot SB20019301, a colorless, low viscosity liquid with a sweet odor, was identified as vinylidene chloride by the analytical chemistry laboratory using Fourier transform infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with the literature spectra^155,156^ and the structure of vinylidene chloride. Representative IR and proton NMR spectra are presented in Figure I-1 and Figure I-2, respectively.

For lot SB20019301, the analytical chemistry laboratory determined the water content using Karl Fischer titration, conducted elemental analyses to determine the carbon and hydrogen content, and determined residual chloride content after extraction for free chloride using anion exchange chromatography by a system that included a Dionex DX-100 ion chromatograph (Dionex Corporation, Bannockburn, IL). Additional testing was performed on the bulk chemical by the study laboratory that included titration with potassium iodide (KI) to determine the amount of peroxide present; a turbidity assay to determine the polymer content using a Beckman DU-650 spectrophotometer (Beckman Coulter, Inc., Fullerton, CA) with ultraviolet detection at 420 nm; and gas chromatography (GC) with flame ionization detection (FID) by one system to measure the concentration of the stabilizer monomethyl ether hydroquinone (MEHQ) and by a second system to determine area percent purity.

For lot SB20019301, Karl Fischer titration indicated a water content of 74 ppm. Elemental analyses for carbon and hydrogen were consistent with theoretical values. KI titration indicated that peroxide was less than 1 ppm by weight as active oxygen compared to vinylidene chloride. Anion exchange chromatography indicated that residual chloride content was less than 2 ppm. A turbidity assay showed that the concentration of polymer was less than 9 ppm. GC/FID by system A (Table I-1) indicated that the test article was stabilized with approximately 300 ppm MEHQ. GC/FID by system B indicated an area percent purity greater than 99.9%. The overall purity of lot SB20019301 was determined to be greater than 99.9%.

To ensure stability, the bulk chemical was stored under a nitrogen headspace in the original shipping containers (400-L steel mini-Bulk^™^ containers) at a temperature of approximately 63°F. Periodic reanalyses of the bulk chemical were performed during the 2-week, 3-month, and 2-year studies by the study laboratory using the same turbidity and GC/FID (system B) assays used in the initial bulk chemical purity assays, and no degradation of the bulk chemical was detected.

## I.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure I-3. Vinylidene chloride was pumped from a disposable 4 liter amber glass generator reservoir into a heated glass flask. Nitrogen entered the flask and assisted in vaporizing the chemical while conveying it from the generator into a short vapor distribution manifold. Concentration in the manifold was determined by the chemical pump and nitrogen flow rates. Pressure in the distribution manifold was kept fixed to ensure constant flows through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Individual Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the vinylidene chloride vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI, Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that vinylidene chloride vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## I.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table I-2 through Table I-4. Chamber and room concentrations of vinylidene chloride were monitored by an on-line gas chromatograph (system C, Table I-1). Samples were drawn from each exposure chamber approximately three times (2-week and 3-month studies) or twice (2-year studies) per hour during each 6-hour exposure period using Hastelloy^®^-C stream-select and gas-sampling valves (VALCO Instruments Company, Houston, TX) in a separate, heated oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout each exposure day for instrument drift against an on-line standard vapor of methylene chloride in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples collected with activated coconut charcoal gas-sampling tubes (ORBO^™^-32; Supelco Inc., Bellefonte, PA), extracted with toluene containing an internal standard of methylene chloride and analyzed using an off-line gas chromatograph equipped with an electron capture detector (system D). Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standard solutions of the test chemical containing methylene chloride as an internal standard in toluene.

## I.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with (all studies) and without (3-month and 2-year studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. For rats and mice in the 2-week studies, T_90_ and T_10_ values ranged from 9 to 10 minutes with animals present. For rats and mice in the 3-month studies, T_90_ values ranged from 9 to 11 minutes without animals present and from 10 to 11 minutes with animals; T_10_ values were 9 to 10 minutes without animals present and 10 minutes with animals. For rats and mice in the 2-year studies, T_90_ values ranged from 8 to 10 minutes without animals present and from 9 to 12 minutes with animals; T_10_ values ranged from 9 to 10 minutes without animals present and from 9 to 11 minutes with animals. A T_90_ value of 12 minutes was selected for the 2-week studies and a T_90_ value of 10 minutes was selected for the 3-month and 2-year studies.

The uniformity of vinylidene chloride vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week studies, once during the 3-month studies, and approximately quarterly during the 2-year studies. The vapor concentration was measured using the on-line gas chromatograph (system C, Table I-1) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. During the 2-week studies and prior to the 3-month and 2-year studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. During the 3-month and 2-year studies, concentrations were measured at the regular monitoring port and from sample ports at levels where animals were present. Chamber concentration uniformity was maintained throughout the studies.

The persistence of vinylidene chloride in the chambers after vapor delivery ended was determined by monitoring the vapor concentration in the 400 ppm chambers in the 2-week studies, the 100 ppm chambers in the 3-month studies, and the 100 ppm rat and 25 ppm mouse chambers in the 2-year studies with (all studies) and without (3-month and 2-year studies) animals present in the chambers. In the 2-week studies, the concentration decreased to 1% of the target concentration within 21 minutes with animals present. In the 3-month studies, the concentration decreased to 1% of the target concentration within 21 minutes without animals present and within 23 minutes with animals present. For the 2-year rat studies, the concentration decreased to 1% of the target concentration within 22 minutes with and without animals present; for mice, the concentration decreased to 1% of the target concentration within 18 minutes without animals present and within 21 minutes with animals present.

Samples of the test atmosphere from the distribution lines and the low and high exposure concentration chambers for each species were collected prior to the study without animals present (3-month and 2-year studies) and at the beginning and end of one generation day with animals present during the 2-week, 3-month, and 2-year studies. The atmosphere samples were collected with adsorbent gas-sampling tubes containing activated coconut charcoal (ORBO^™^-32) followed by a tube containing silica gel (ORBO^™^-52; Supelco, Inc.), and extracted with carbon disulfide. Additional samples were collected from the generator reservoir, and all of the samples were analyzed using GC/FID by system B or a system similar to system B to measure the stability and purity of vinylidene chloride in the generation and delivery system. To assess whether impurities or degradation products co-eluted with vinylidene chloride or the solvent, a second GC/FID analysis of the samples was performed using a polar column capable of resolving compounds with similar boiling points and polarities (system E). Separate atmosphere samples were collected in these studies using toluene bubblers; MEHQ inhibitor was assayed in these distribution line samples using GC/FID by system A, and peroxide was assayed in these distribution line and low (except 2-week studies) and high exposure concentration chamber samples by KI titration. HCL, formaldehyde, and phosgene concentrations were measured in atmosphere samples collected during the last 2 hours of a 6-hour generation day. Fourier transform IR spectroscopy was used to measure the presence of HCL in samples collected prior to the 3-month studies and during the 2-week, 3-month, and 2-year studies; spectra were generated using a MIDAC I-1101 spectroscope (MIDAC Corporation, Irvine, CA) equipped with a 9.5 m pathlength gas cell held at approximately 25°C and were compared to those of prepared HCL standards. Formaldehyde and phosgene were measured in atmosphere samples collected on silica adsorbent sampling tubes coated with 2,4-dinitrophenylhydrazine (LpDNPH H10 or S10; Supelco, Inc.) prior to the 3-month and 2-year studies and during the 2-week, 3-month, and 2-year studies. These samples were analyzed using a liquid chromatography procedure conducted with a Hewlett-Packard liquid chromatograph (Hewlett-Packard, Palo Alto, CA) equipped with a Phenomenex C_18_ (250 mm × 4.6 mm, 5µm) column (Phenomenex, Torrance, CA). The mobile phase (1.2 mL/minute) consisted of acetonitrile:water:tetrahydrofuran:2-propanol [ A) 30:59:10:1; B) 65:35:0:0; and C) 100:0:0:0]; the analysis utilized a solvent program of a linear gradient from 100% A to 60% A:40% B in 20 minutes, held for 5 minutes, then a linear gradient to 100% B in 10 minutes followed by linear gradient to 100% C in 2 minutes, held for 10 minutes, and then a linear gradient to 100% A in 0.1 minutes. Absorbance was recorded at 355 nm. Samples were collected from the generator reservoir 3 to 14 days after the reservoir was placed in use in studies conducted without animals present prior to the 3-month and 2-year studies and at the same timepoints during the 2-week, 3-month, and 2-year studies. These samples were analyzed for area percent purity, polymer formation, peroxide content, and MEHQ concentration using the same methodologies employed for the initial bulk chemical characterization assays.

No evidence of degradation of vinylidene chloride was noted in any part of the exposure system in any of the samples collected prior to the 3-month and 2-year studies or during the 2-week, 3-month, and 2-year studies. No impurity peaks with areas greater than 0.1% of the total peak area were detected in atmosphere or generator reservoir samples and no additional impurities were found in any of the atmosphere or reservoir samples using the polar column. HCL concentrations in the atmosphere samples were consistently determined to be less than the detection limit. Formaldehyde and phosgene concentrations were less than 0.1% by weight compared to vinylidene chloride in all distribution line and chamber atmosphere samples. Acceptable, low concentrations of peroxide as active oxygen relative to vinylidene chloride were found in all atmosphere samples. All distribution line samples contained concentrations within the acceptable range for the inhibitor MEHQ relative to vinylidene chloride. No evidence of degradation, peroxide formation, or polymer formation was noted in any of the samples taken from the generator reservoir after multiple days of use.

Table I-1 Gas Chromatography Systems Used in the Inhalation Studies of Vinylidene Chloride^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-5, 30 m × 0.53 mm, 1.5 µm film (J&W Scientific, Folsom, CA) | Helium at 12 psi head pressure | 90°C for 1 minute, then 12°C/minute to 200°C
System B
Flame ionization | DB-624, 30 m × 0.53 mm, 3.0 µm film (J&W Scientific) | Helium at 2.5 psi head pressure | 35°C for 3 minutes, then 4°C/minute to 110°C, then 8°C/minute to 260°C
System C
Flame ionization | Rtx^®^-624, 30 m × 0.53 mm, 5.0 µm film (Restek, Bellefonte, PA) | Nitrogen at 25 mL/minute | Isothermal at 60°C
System D
Electron capture | Rtx^®^-624, 30 m × 0.53 mm, 5.0 µm film (Restek) | Nitrogen at 3.5 mL/minute | 45°C for 1 minute, then 3°C/minute to 70°C, then 15°C/minute to 160°C
System E
Flame ionization | DB WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific) | Helium at 12 psi head pressure | 90°C for 1 minute, then 12°C/minute to 200°C

^a^ The gas chromatographs were manufactured by Hewlett-Packard (Palo Alto, CA).

Table I-2 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Vinylidene Chloride

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 25 | 200 | 25.1 ± 0.5
| 50 | 201 | 50.1 ± 1.3
| 100 | 202 | 99.7 ± 4.3
| 200 | 16 | 200 ± 1
| 400 | 64 | 398 ± 34
Mouse Chambers
| 25 | 218 | 25.1 ± 0.5
| 50 | 219 | 50.1 ± 1.3
| 100 | 220 | 99.7 ± 4.1
| 200 | 16 | 200 ± 1
| 400 | 19 | 396 ± 2

^a^ Mean ± standard deviation.

Table I-3 Summary of Chamber Concentrations in the Three-month Inhalation Studies of Vinylidene Chloride

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 6.25 | 1,193 | 6.28 ± 0.12
| 12.5 | 1,183 | 12.6 ± 0.2
| 25 | 1,185 | 25.1 ± 0.5
| 50 | 1,210 | 50.4 ± 1.0
| 100 | 1,224 | 100.0 ± 2.2
Mouse Chambers
| 6.25 | 1,232 | 6.28 ± 0.12
| 12.5 | 1,220 | 12.6 ± 0.2
| 25 | 1,223 | 25.1 ± 0.5
| 50 | 1,249 | 50.4 ± 1.0
| 100 | 1,263 | 100.0 ± 2.2

^a^ Mean ± standard deviation.

Table I-4 Summary of Chamber Concentrations in the Two-year Inhalation Studies of Vinylidene Chloride

| Total Concentration (ppm) | Total Number of Readings | Average Concentration^a^(ppm)
Rat Chambers
| 25 | 7,938 | 25.0 ± 0.6
| 50 | 7,963 | 50.1 ± 1.1
| 100 | 7,968 | 100.0 ± 2.3
Mouse Chambers
| 6.25 | 8,315 | 6.22 ± 0.16
| 12.5 | 8,022 | 12.5 ± 0.3
| 25 | 7,917 | 25.0 ± 0.4

^a^ Mean ± standard deviation.

Figure I-1

Infrared Absorption Spectrum of Vinylidene Chloride

Figure I-2

Proton Nuclear Magnetic Resonance Spectrum of Vinylidene Chloride

Figure I-3

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of Vinylidene Chloride