# Appendix H Reproductive Tissue Evaluations

Table H-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 326 ± 7 | 319 ± 6 | 340 ± 6 | 322 ± 5
L. Cauda epididymis | 0.1745 ± 0.0043 | 0.1724 ± 0.0059 | 0.1703 ± 0.0049 | 0.1642 ± 0.0103
L. Epididymis | 0.5200 ± 0.0162 | 0.5138 ± 0.0158 | 0.4903 ± 0.0092 | 0.4932 ± 0.0165
L. Testis | 1.4096 ± 0.0229 | 1.3879 ± 0.0235 | 1.3749 ± 0.0301 | 1.3718 ± 0.0246
Spermatid measurements
Spermatid heads (10^6^/testis) | 188.4 ± 8.4 | 169.3 ± 8.2 | 177.8 ± 7.6 | 158.5 ± 5.2*
Spermatid heads (10^6^/g testis) | 150.3 ± 4.9 | 136.5 ± 6.6 | 148.4 ± 5.1 | 128.4 ± 3.9*
Epididymal spermatozoal measurements
Sperm motility (%) | 87.13 ± 1.13 | 84.90 ± 1.20 | 84.55 ± 0.90 | 82.55 ± 1.07**
Sperm (10^6^/cauda epididymis) | 106.4 ± 6.6 | 107.8 ± 5.8 | 107.5 ± 6.8 | 102.8 ± 6.4
Sperm (10^6^/g cauda epididymis) | 610 ± 37 | 632 ± 41 | 629 ± 33 | 655 ± 67

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s’test.

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (sperm per cauda epididymis and per g cauda epididymis).

Table H-2 Estrous Cycle Characterization for Female Rats in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 203 ± 3 | 201 ± 4 | 205 ± 4 | 195 ± 2
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 4.95 ± 0.05 | 4.85 ± 0.11 | 5.00 ± 0.00 | 5.10 ± 0.10
Estrous stages (% of cycle)
Diestrus | 49.2 | 45.0 | 50.8 | 48.3
Proestrus | 17.5 | 19.2 | 20.8 | 17.5
Estrus | 20.0 | 18.3 | 20.0 | 20.8
Metestrus | 13.3 | 16.7 | 8.3 | 13.3
Uncertain diagnoses | 0.0 | 0.8 | 0.0 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated exposed females did not have significantly more extended estrus or diestrus than the chamber control group.

^b^ Number of females with a regular cycle/number of females cycling.

Table H-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
n | 10 | 10 | 10 | 8
Weights (g)
Necropsy body wt | 39.4 ± 1.2 | 35.5 ± 0.6** | 33.5 ± 0.8** | 33.0 ± 0.5**
L. Cauda epididymis | 0.0221 ± 0.0011 | 0.0217 ± 0.0011 | 0.0182 ± 0.0010 | 0.0200 ± 0.0019
L. Epididymis | 0.0604 ± 0.0020 | 0.0646 ± 0.0032 | 0.0563 ± 0.0029 | 0.0567 ± 0.0020
L. Testis | 0.1096 ± 0.0027 | 0.1119 ± 0.0020 | 0.1092 ± 0.0021 | 0.1090 ± 0.0029
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.24 ± 1.45 | 21.63 ± 0.95 | 21.38 ± 1.08 | 20.74 ± 0.68
Spermatid heads (10^6^/g testis) | 242.7 ± 13.9 | 230.5 ± 7.5 | 231.8 ± 4.2 | 240.8 ± 9.0
Epididymal spermatozoal measurements
Sperm motility (%) | 82.7 ± 1.4 | 84.6 ± 0.9 | 84.8 ± 1.4 | 79.8 ± 2.0
Sperm (10^6^/cauda epididymis) | 21.4 ± 1.3 | 17.3 ± 0.5** | 15.7 ± 0.4** | 14.9 ± 0.6**
Sperm (10^6^/g cauda epididymis) | 751 ± 44 | 631 ± 35 | 736 ± 61 | 609 ± 75

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body weights) or by Shirley’s test (sperm per cauda epididymis).

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid measurements, sperm motility, and sperm per g cauda epididymis).

Table H-4 Estrous Cycle Characterization for Female Mice in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 35.2 ± 1.2 | 31.9 ± 0.9* | 30.9 ± 0.8** | 28.7 ± 0.6**
Proportion of regular cycling females^b^ | 9/10 | 9/9 | 10/10 | 9/10
Estrous cycle length (days) | 4.09 ± 0.12 | 3.98 ± 0.14^c^ | 3.88 ± 0.05 | 4.10 ± 0.10
Estrous stages (% of cycle)
Diestrus | 25.8 | 25.8 | 25.0 | 25.0
Proestrus | 1.7 | 0.0 | 0.8 | 0.8
Estrus | 48.3 | 48.3 | 48.3 | 50.0
Metestrus | 24.2 | 25.0 | 25.0 | 24.2
Uncertain diagnoses | 0.0 | 0.8 | 0.8 | 0.0

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated exposed females did not have significantly more extended estrus or diestrus than the chamber control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.