# Appendix G Organ Weights

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n | 5 | 4 | 5 | 5 | 0 | 0
Necropsy body wt | 158 ± 2 | 150 ± 3 | 159 ± 5 | 154 ± 2 | – | –
Heart
Absolute | 0.57 ± 0.01 | 0.55 ± 0.02 | 0.57 ± 0.02 | 0.56 ± 0.01 | – | –
Relative | 3.590 ± 0.042 | 3.640 ± 0.079 | 3.559 ± 0.046 | 3.655 ± 0.043 | – | –
R. Kidney
Absolute | 0.61 ± 0.01 | 0.70 ± 0.01** | 0.71 ± 0.02** | 0.71 ± 0.02** | – | –
Relative | 3.878 ± 0.045 | 4.641 ± 0.054** | 4.460 ± 0.124** | 4.625 ± 0.074** | – | –
Liver
Absolute | 7.06 ± 0.18 | 6.50 ± 0.16 | 6.84 ± 0.21 | 6.79 ± 0.13 | – | –
Relative | 44.561 ± 0.628 | 43.247 ± 0.147 | 43.045 ± 0.419 | 44.042 ± 0.578 | – | –
Lung
Absolute | 1.04 ± 0.02 | 1.14 ± 0.05 | 1.11 ± 0.07 | 1.20 ± 0.06 | – | –
Relative | 6.557 ± 0.110 | 7.548 ± 0.248 | 6.991 ± 0.263 | 7.776 ± 0.372* | – | –
R. Testis
Absolute | 0.904 ± 0.020 | 0.922 ± 0.029 | 0.965 ± 0.037 | 0.918 ± 0.022 | – | –
Relative | 5.712 ± 0.123 | 6.128 ± 0.077 | 6.065 ± 0.128 | 5.954 ± 0.115 | – | –
Thymus
Absolute | 0.401 ± 0.020 | 0.389 ± 0.021 | 0.417 ± 0.024 | 0.374 ± 0.011 | – | –
Relative | 2.533 ± 0.104 | 2.584 ± 0.103 | 2.622 ± 0.119 | 2.428 ± 0.080 | – | –
Female
n | 5 | 5 | 5 | 5 | 0 | 0
Necropsy body wt | 124 ± 2 | 125 ± 3 | 122 ± 1 | 117 ± 3 | – | –
Heart
Absolute | 0.45 ± 0.01 | 0.46 ± 0.01 | 0.47 ± 0.00 | 0.46 ± 0.01 | – | –
Relative | 3.633 ± 0.044 | 3.680 ± 0.059 | 3.874 ± 0.045** | 3.924 ± 0.068** | – | –
R. Kidney
Absolute | 0.53 ± 0.01 | 0.61 ± 0.01** | 0.59 ± 0.01* | 0.59 ± 0.02** | – | –
Relative | 4.299 ± 0.068 | 4.904 ± 0.083** | 4.826 ± 0.079** | 5.084 ± 0.079** | – | –
Liver
Absolute | 5.07 ± 0.13 | 4.96 ± 0.12 | 4.86 ± 0.08 | 4.87 ± 0.14 | – | –
Relative | 40.971 ± 0.433 | 39.867 ± 0.386 | 39.860 ± 0.846 | 41.676 ± 0.349 | – | –
Lung
Absolute | 0.88 ± 0.04 | 0.95 ± 0.05 | 0.95 ± 0.09 | 0.87 ± 0.04 | – | –
Relative | 7.066 ± 0.214 | 7.643 ± 0.350 | 7.844 ± 0.747 | 7.414 ± 0.277 | – | –
Thymus
Absolute | 0.330 ± 0.012 | 0.373 ± 0.014 | 0.353 ± 0.013 | 0.328 ± 0.013 | – | –
Relative | 2.667 ± 0.082 | 2.988 ± 0.046* | 2.900 ± 0.120 | 2.807 ± 0.052 | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data available for 200 ppm and 400 ppm males and females due to 100% mortality.

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 326 ± 7 | 332 ± 6 | 337 ± 5 | 319 ± 6 | 340 ± 6 | 322 ± 5
Heart
Absolute | 0.89 ± 0.02 | 0.93 ± 0.02 | 0.88 ± 0.02 | 0.86 ± 0.02 | 0.92 ± 0.02 | 0.89 ± 0.03
Relative | 2.713 ± 0.022 | 2.807 ± 0.068 | 2.628 ± 0.031 | 2.700 ± 0.023 | 2.694 ± 0.033 | 2.757 ± 0.055
R. Kidney
Absolute | 0.99 ± 0.02 | 1.07 ± 0.04 | 1.05 ± 0.03 | 1.01 ± 0.03 | 1.08 ± 0.02 | 1.05 ± 0.02
Relative | 3.026 ± 0.028 | 3.208 ± 0.091* | 3.129 ± 0.035* | 3.171 ± 0.039 | 3.167 ± 0.029 | 3.245 ± 0.038**
Liver
Absolute | 10.63 ± 0.32 | 10.61 ± 0.26 | 10.46 ± 0.27 | 9.77 ± 0.27 | 10.59 ± 0.32 | 10.23 ± 0.28
Relative | 32.562 ± 0.400 | 31.951 ± 0.510 | 31.034 ± 0.404 | 30.596 ± 0.376** | 31.062 ± 0.456 | 31.697 ± 0.412
Lung
Absolute | 1.66 ± 0.06 | 1.59 ± 0.06 | 1.60 ± 0.04 | 1.59 ± 0.06 | 1.71 ± 0.09 | 1.50 ± 0.05
Relative | 5.075 ± 0.148 | 4.781 ± 0.132 | 4.766 ± 0.115 | 4.986 ± 0.128 | 5.003 ± 0.194 | 4.665 ± 0.129
R. Testis
Absolute | 1.343 ± 0.026 | 1.353 ± 0.019 | 1.346 ± 0.022 | 1.316 ± 0.020 | 1.346 ± 0.017 | 1.314 ± 0.021
Relative | 4.122 ± 0.056 | 4.082 ± 0.073 | 4.004 ± 0.061 | 4.135 ± 0.083 | 3.963 ± 0.068 | 4.085 ± 0.077
Thymus
Absolute | 0.335 ± 0.014 | 0.358 ± 0.011 | 0.326 ± 0.012 | 0.314 ± 0.015 | 0.344 ± 0.13 | 0.328 ± 0.017
Relative | 1.025 ± 0.032 | 1.080 ± 0.033 | 0.969 ± 0.036 | 0.985 ± 0.047 | 1.014 ± 0.038 | 1.018 ± 0.052
Female
Necropsy body wt | 203 ± 3 | 205 ± 6 | 206 ± 4 | 201 ± 4 | 205 ± 4 | 195 ± 2
Heart
Absolute | 0.61 ± 0.01 | 0.60 ± 0.01 | 0.61 ± 0.01 | 0.61 ± 0.02 | 0.63 ± 0.02 | 0.60 ± 0.01
Relative | 2.978 ± 0.055 | 2.926 ± 0.039 | 2.980 ± 0.038 | 3.017 ± 0.048 | 3.077 ± 0.044 | 3.046 ± 0.042
R. Kidney
Absolute | 0.64 ± 0.01 | 0.67 ± 0.02 | 0.69 ± 0.02* | 0.68 ± 0.01* | 0.72 ± 0.01** | 0.71 ± 0.02**
Relative | 3.155 ± 0.041 | 3.280 ± 0.055 | 3.356 ± 0.043** | 3.393 ± 0.040** | 3.512 ± 0.025** | 3.645 ± 0.058**
Liver
Absolute | 5.84 ± 0.10 | 5.72 ± 0.24 | 5.87 ± 0.18 | 5.51 ± 0.14 | 5.97 ± 0.16 | 5.94 ± 0.16
Relative | 28.741 ± 0.345 | 27.921 ± 0.470 | 28.538 ± 0.588 | 27.452 ± 0.505 | 29.175 ± 0.598 | 30.393 ± 0.495
Lung
Absolute | 1.08 ± 0.02 | 1.11 ± 0.03 | 1.10 ± 0.02 | 1.09 ± 0.03 | 1.12 ± 0.05 | 1.07 ± 0.02
Relative | 5.303 ± 0.080 | 5.415 ± 0.100 | 5.338 ± 0.128 | 5.429 ± 0.125 | 5.451 ± 0.248 | 5.454 ± 0.070
Thymus
Absolute | 0.279 ± 0.010 | 0.265 ± 0.013 | 0.268 ± 0.011 | 0.255 ± 0.008 | 0.274 ± 0.009 | 0.266 ± 0.008
Relative | 1.372 ± 0.040 | 1.303 ± 0.069 | 1.301 ± 0.048 | 1.270 ± 0.032 | 1.342 ± 0.046 | 1.359 ± 0.037

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n | 5 | 4 | 5 | 5 | 0 | 0
Necropsy body wt | 26.6 ± 0.9 | 24.4 ± 0.9 | 24.9 ± 0.2 | – | – | –
Heart
Absolute | 0.13 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.00 | – | – | –
Relative | 4.952 ± 0.129 | 4.826 ± 0.059 | 4.728 ± 0.087 | – | – | –
R. Kidney
Absolute | 0.22 ± 0.02 | 0.23 ± 0.01 | 0.22 ± 0.01 | – | – | –
Relative | 8.309 ± 0.292 | 9.495 ± 0.137** | 8.851 ± 0.301 | – | – | –
Liver
Absolute | 1.42 ± 0.07 | 1.48 ± 0.07 | 1.56 ± 0.03 | – | – | –
Relative | 53.190 ± 0.796 | 60.483 ± 1.044** | 62.658 ± 0.713** | – | – | –
Lung
Absolute | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01 | – | – | –
Relative | 6.663 ± 0.215 | 7.682 ± 0.279* | 7.751 ± 0.237* | – | – | –
R. Testis
Absolute | 0.100 ± 0.004 | 0.102 ± 0.003 | 0.095 ± 0.002 | – | – | –
Relative | 3.749 ± 0.068 | 4.188 ± 0.107* | 3.816 ± 0.113 | – | – | –
Thymus
Absolute | 0.049 ± 0.003 | 0.055 ± 0.005 | 0.053 ± 0.004 | – | – | –
Relative | 1.845 ± 0.046 | 2.222 ± 0.156 | 2.113 ± 0.173 | – | – | –
Female
n | 5 | 5 | 5 | 4 | 0 | 0
Necropsy body wt | 22.2 ± 0.4 | 21.8 ± 0.5 | 21.4 ± 0.3 | 22.2 ± 0.7 | – | –
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.01 | 0.11 ± 0.00 | 0.10 ± 0.00* | – | –
Relative | 5.321 ± 0.125 | 5.580 ± 0.138 | 5.133 ± 0.111 | 4.633 ± 0.071** | – | –
R. Kidney
Absolute | 0.16 ± 0.01 | 0.18 ± 0.01* | 0.17 ± 0.00 | 0.16 ± 0.01 | – | –
Relative | 7.026 ± 0.241 | 8.340 ± 0.212** | 8.029 ± 0.134** | 7.224 ± 0.204 | – | –
Liver
Absolute | 1.14 ± 0.03 | 1.23 ± 0.04 | 1.30 ± 0.01* | 1.43 ± 0.07** | – | –
Relative | 51.248 ± 0.827 | 56.253 ± 0.396** | 60.528 ± 0.792** | 64.395 ± 1.497** | – | –
Lung
Absolute | 0.15 ± 0.01 | 0.21 ± 0.01** | 0.19 ± 0.01* | 0.21 ± 0.02** | – | –
Relative | 6.932 ± 0.514 | 9.460 ± 0.297** | 9.055 ± 0.315** | 9.567 ± 0.456** | – | –
Thymus
Absolute | 0.066 ± 0.003 | 0.074 ± 0.005 | 0.069 ± 0.002 | 0.059 ± 0.006 | – | –
Relative | 2.976 ± 0.105 | 3.375 ± 0.160 | 3.228 ± 0.075 | 2.649 ± 0.239 | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data available for 100 ppm males and 200 ppm and 400 ppm males and females due to 100% mortality.

Table G-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
n | 10 | 10 | 10 | 10 | 8 | –
Necropsy body wt | 39.4 ± 1.2 | 37.8 ± 0.5 | 35.5 ± 0.6** | 33.5 ± 0.8** | 33.0 ± 0.5** | –
Heart
Absolute | 0.16 ± 0.01 | 0.15 ± 0.00 | 0.15 ± 0.01 | 0.15 ± 0.00 | 0.15 ± 0.01 | –
Relative | 4.090 ± 0.083 | 3.950 ± 0.061 | 4.171 ± 0.104 | 4.516 ± 0.084** | 4.548 ± 0.121** | –
R. Kidney
Absolute | 0.32 ± 0.01 | 0.28 ± 0.01** | 0.26 ± 0.01** | 0.25 ± 0.01** | 0.25 ± 0.01** | –
Relative | 8.073 ± 0.180 | 7.390 ± 0.120* | 7.217 ± 0.199** | 7.607 ± 0.162 | 7.421 ± 0.234 | –
Liver
Absolute | 1.60 ± 0.05 | 1.52 ± 0.03 | 1.62 ± 0.04 | 1.65 ± 0.05 | 1.72 ± 0.08 | –
Relative | 40.528 ± 0.231 | 40.138 ± 0.502 | 45.631 ± 0.986** | 49.264 ± 0.948** | 51.978 ± 1.596** | –
Lung
Absolute | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.21 ± 0.01 | –
Relative | 5.271 ± 0.135 | 5.248 ± 0.123 | 5.878 ± 0.162* | 6.379 ± 0.194** | 6.390 ± 0.262** | –
R. Testis
Absolute | 0.113 ± 0.002 | 0.115 ± 0.002 | 0.111 ± 0.003 | 0.116 ± 0.002 | 0.110 ± 0.003 | –
Relative | 2.887 ± 0.072 | 3.033 ± 0.041 | 3.138 ± 0.067* | 3.471 ± 0.090** | 3.335 ± 0.102** | –
Thymus
Absolute | 0.050 ± 0.003 | 0.053 ± 0.002 | 0.047 ± 0.002 | 0.055 ± 0.002 | 0.052 ± 0.002 | –
Relative | 1.258 ± 0.073 | 1.395 ± 0.060 | 1.338 ± 0.045 | 1.638 ± 0.052** | 1.575 ± 0.050** | –
Female
n | 10 | 10 | 10 | 10 | 10 | 6
Necropsy body wt | 35.2 ± 1.2 | 30.8 ± 0.6** | 31.9 ± 0.9** | 30.9 ± 0.8** | 28.7 ± 0.6** | 29.9 ± 0.8**
Heart
Absolute | 0.15 ± 0.00 | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.01 | 0.16 ± 0.00
Relative | 4.176 ± 0.113 | 4.589 ± 0.127** | 4.630 ± 0.087** | 4.985 ± 0.061** | 5.123 ± 0.147** | 5.297 ± 0.096**
R. Kidney
Absolute | 0.21 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.23 ± 0.00 | 0.22 ± 0.00 | 0.24 ± 0.01**
Relative | 6.119 ± 0.175 | 6.791 ± 0.125** | 6.990 ± 0.149** | 7.308 ± 0.167** | 7.680 ± 0.161** | 8.114 ± 0.219**
Liver
Absolute | 1.43 ± 0.03 | 1.41 ± 0.03 | 1.55 ± 0.04* | 1.77 ± 0.04** | 1.63 ± 0.05** | 1.87 ± 0.08**
Relative | 40.788 ± 0.973 | 45.680 ± 0.880** | 48.769 ± 0.632** | 57.129 ± 0.447** | 56.632 ± 0.571** | 62.493 ± 1.149**
Lung
Absolute | 0.24 ± 0.01 | 0.22 ± 0.01 | 0.25 ± 0.01 | 0.23 ± 0.01 | 0.25 ± 0.02 | 0.29 ± 0.01**
Relative | 6.755 ± 0.325 | 7.009 ± 0.165 | 7.841 ± 0.333* | 7.602 ± 0.291* | 8.613 ± 0.493** | 9.631 ± 0.261**
Thymus
Absolute | 0.058 ± 0.003 | 0.057 ± 0.003 | 0.057 ± 0.002 | 0.067 ± 0.005 | 0.063 ± 0.002 | 0.060 ± 0.005

Relative

1.653 ± 0.091

1.835 ± 0.086

1.795 ± 0.080

2.162 ± 0.146**

2.191 ± 0.044**

2.003 ± 0.144**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test,

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).