# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-Month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Hematology
n
Day 3 | 10 | 10 | 9 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (manual) (%)
Day 3 | 46.5 ± 0.5 | 46.5 ± 0.4 | 45.7 ± 0.3 | 46.1 ± 0.2 | 47.4 ± 0.5 | 48.4 ± 0.4*
Day 23 | 48.5 ± 0.3 | 48.5 ± 0.3 | 47.7 ± 0.3 | 48.2 ± 0.6 | 48.1 ± 0.3 | 48.4 ± 0.4
Week 14 | 49.7 ± 0.3 | 49.5 ± 0.5 | 48.7 ± 0.4 | 49.9 ± 0.4 | 49.8 ± 0.3 | 49.6 ± 0.2
Packed cell volume (auto) (%)
Day 3 | 45.2 ± 0.5 | 45.0 ± 0.5 | 44.5 ± 0.5 | 44.6 ± 0.3 | 45.8 ± 0.6 | 46.9 ± 0.5
Day 23 | 47.7 ± 0.3 | 47.3 ± 0.3 | 46.4 ± 0.4 | 47.2 ± 0.5 | 47.5 ± 0.4 | 47.8 ± 0.4
Week 14 | 49.1 ± 0.2 | 48.3 ± 0.5 | 47.8 ± 0.4 | 49.0 ± 0.3 | 49.0 ± 0.3 | 48.9 ± 0.4
Hemoglobin (g/dL)
Day 3 | 13.9 ± 0.2 | 13.9 ± 0.2 | 13.8 ± 0.2 | 14.0 ± 0.2 | 14.3 ± 0.2 | 14.8 ± 0.1**
Day 23 | 15.2 ± 0.1 | 15.1 ± 0.1 | 14.8 ± 0.1 | 15.0 ± 0.2 | 15.2 ± 0.1 | 15.2 ± 0.1
Week 14 | 15.7 ± 0.1 | 15.6 ± 0.1 | 15.3 ± 0.1 | 15.6 ± 0.1 | 15.7 ± 0.1 | 15.5 ± 0.1
Erythrocytes (10^6^/µL)
Day 3 | 7.32 ± 0.08 | 7.27 ± 0.09 | 7.19 ± 0.07 | 7.34 ± 0.07 | 7.48 ± 0.09 | 7.79 ± 0.09**
Day 23 | 8.29 ± 0.06 | 8.16 ± 0.07 | 7.99 ± 0.07* | 8.12 ± 0.10 | 8.14 ± 0.07 | 8.19 ± 0.09
Week 14 | 9.21 ± 0.05 | 9.11 ± 0.06 | 9.01 ± 0.08 | 9.17 ± 0.05 | 9.25 ± 0.05 | 9.08 ± 0.07
Reticulocytes (10^6^/µL)
Day 3 | 0.32 ± 0.02 | 0.40 ± 0.03 | 0.34 ± 0.02 | 0.33 ± 0.02 | 0.33 ± 0.02 | 0.30 ± 0.02
Day 23 | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.30 ± 0.02^b^ | 0.30 ± 0.02^c^ | 0.33 ± 0.01** | 0.31 ± 0.02^b^**
Week 14 | 0.17 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.21 ± 0.01
Nucleated erythrocytes/100 leukocytes
Day 3 | 1.1 ± 0.4 | 0.8 ± 0.2 | 0.8 ± 0.3 | 0.6 ± 0.3 | 0.2 ± 0.1 | 0.4 ± 0.2
Day 23 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.1 | 0.2 ± 0.1
Week 14 | 0.2 ± 0.1 | 0.0 ± 0.0 | 0.5 ± 0.2 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.5 ± 0.2
Mean cell volume (fL)
Day 3 | 61.8 ± 0.4 | 61.9 ± 0.2 | 61.8 ± 0.3 | 60.9 ± 0.2 | 61.2 ± 0.4 | 60.2 ± 0.4**
Day 23 | 57.6 ± 0.3 | 58.0 ± 0.2 | 58.0 ± 0.2 | 58.2 ± 0.2 | 58.4 ± 0.2 | 58.4 ± 0.3
Week 14 | 53.3 ± 0.1 | 53.0 ± 0.2 | 53.1 ± 0.2 | 53.4 ± 0.2 | 53.0 ± 0.2 | 53.9 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.0 ± 0.1 | 19.2 ± 0.1 | 19.2 ± 0.1 | 19.0 ± 0.1 | 19.2 ± 0.1 | 18.9 ± 0.1
Day 23 | 18.4 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1
Week 14 | 17.0 ± 0.1 | 17.0 ± 0.1 | 17.1 ± 0.0 | 17.0 ± 0.1 | 17.0 ± 0.1 | 17.1 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 30.8 ± 0.1 | 30.9 ± 0.1 | 31.1 ± 0.2 | 31.3 ± 0.2 | 31.3 ± 0.2* | 31.5 ± 0.1**
Day 23 | 31.9 ± 0.1 | 31.9 ± 0.1 | 31.9 ± 0.1 | 31.9 ± 0.1 | 32.0 ± 0.1 | 31.8 ± 0.1
Week 14 | 32.0 ± 0.1 | 32.2 ± 0.2 | 32.1 ± 0.1 | 31.9 ± 0.1 | 32.1 ± 0.1 | 31.8 ± 0.1
Platelets (10^3/^ìL)
Day 3 | 855.5 ± 22.3 | 902.4 ± 19.2 | 852.7 ± 15.1 | 851.9 ± 9.8 | 869.6 ± 17.4 | 899.3 ± 18.3
Day 23 | 717.7 ± 24.5 | 743.1 ± 14.4 | 732.3 ± 20.0 | 706.2 ± 14.9 | 728.2 ± 16.9 | 757.9 ± 13.2
Week 14 | 623.1 ± 13.9 | 644.4 ± 8.8 | 618.2 ± 11.0 | 591.4 ± 10.6 | 617.2 ± 18.6 | 615.0 ± 9.8
Leukocytes (10^3^/µL)
Day 3 | 8.76 ± 0.47 | 9.27 ± 0.32 | 9.60 ± 0.32 | 9.36 ± 0.24 | 9.41 ± 0.44 | 9.11 ± 0.42
Day 23 | 8.30 ± 0.55 | 7.67 ± 0.55 | 8.35 ± 0.42 | 7.50 ± 0.45 | 8.58 ± 0.67 | 8.06 ± 0.59
Week 14 | 6.19 ± 0.35 | 6.92 ± 0.43 | 6.05 ± 0.44 | 6.02 ± 0.33 | 6.60 ± 0.45 | 6.17 ± 0.31
Segmented neutrophils (10^3^/µL)
Day 3 | 0.75 ± 0.03 | 0.95 ± 0.05 | 1.29 ± 0.08** | 1.12 ± 0.06** | 0.96 ± 0.04 | 0.79 ± 0.04
Day 23 | 0.94 ± 0.06 | 0.94 ± 0.03 | 0.92 ± 0.03 | 0.87 ± 0.07 | 0.94 ± 0.05 | 0.97 ± 0.08
Week 14 | 1.13 ± 0.06 | 1.17 ± 0.07 | 1.12 ± 0.07 | 1.06 ± 0.03 | 1.15 ± 0.06 | 1.05 ± 0.05
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 3 | 7.72 ± 0.45 | 8.08 ± 0.28 | 8.05 ± 0.30 | 8.00 ± 0.20 | 8.18 ± 0.42 | 7.99 ± 0.41
Day 23 | 7.11 ± 0.53 | 6.51 ± 0.51 | 7.14 ± 0.39 | 6.38 ± 0.47 | 7.21 ± 0.58 | 6.82 ± 0.53
Week 14 | 4.54 ± 0.34 | 5.30 ± 0.40 | 4.34 ± 0.38 | 4.47 ± 0.34 | 4.99 ± 0.40 | 4.69 ± 0.35
Monocytes (10^3^/µL)
Day 3 | 0.18 ± 0.03 | 0.14 ± 0.03 | 0.16 ± 0.07 | 0.11 ± 0.04 | 0.15 ± 0.03 | 0.20 ± 0.05
Day 23 | 0.16 ± 0.09 | 0.15 ± 0.04 | 0.20 ± 0.09 | 0.16 ± 0.07 | 0.34 ± 0.12 | 0.18 ± 0.06
Week 14 | 0.42 ± 0.09 | 0.32 ± 0.08 | 0.47 ± 0.07 | 0.38 ± 0.06 | 0.34 ± 0.10 | 0.34 ± 0.07
Basophils (10^3^/µL)
Day 3 | 0.015 ± 0.003 | 0.012 ± 0.003 | 0.010 ± 0.002 | 0.012 ± 0.003 | 0.012 ± 0.005 | 0.020 ± 0.005
Day 23 | 0.008 ± 0.005 | 0.005 ± 0.002 | 0.007 ± 0.003 | 0.009 ± 0.002 | 0.016 ± 0.005 | 0.006 ± 0.002
Week 14 | 0.010 ± 0.002 | 0.013 ± 0.003 | 0.014 ± 0.004 | 0.011 ± 0.002 | 0.012 ± 0.005 | 0.008 ± 0.001
Eosinophils (10^3^/µL)
Day 3 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.12 ± 0.03 | 0.11 ± 0.01 | 0.11 ± 0.02
Day 23 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
Week 14 | 0.09 ± 0.01 | 0.12 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.11 ± 0.01 | 0.09 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 8.9 ± 0.4 | 8.5 ± 0.4 | 9.0 ± 0.6 | 9.9 ± 0.4 | 10.7 ± 0.4* | 14.9 ± 0.6**
Day 23 | 10.5 ± 0.5 | 9.7 ± 0.3 | 9.9 ± 0.4 | 11.7 ± 0.5 | 12.2 ± 0.4* | 13.4 ± 0.3**
Week 14 | 15.6 ± 0.4 | 14.5 ± 0.2 | 13.9 ± 0.3** | 14.9 ± 0.3 | 15.6 ± 0.6 | 13.9 ± 0.2**
Creatinine (mg/dL)
Day 3 | 0.23 ± 0.02 | 0.23 ± 0.02 | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.27 ± 0.02
Day 23 | 0.27 ± 0.02 | 0.28 ± 0.01 | 0.27 ± 0.02 | 0.28 ± 0.02 | 0.30 ± 0.00 | 0.30 ± 0.02
Week 14 | 0.40 ± 0.00 | 0.41 ± 0.02 | 0.38 ± 0.01 | 0.43 ± 0.02 | 0.44 ± 0.02 | 0.44 ± 0.02
Glucose (mg/dL)
Day 3 | 141 ± 8 | 141 ± 2 | 138 ± 5 | 140 ± 4 | 127 ± 3 | 125 ± 3*
Day 23 | 119 ± 4 | 129 ± 4 | 128 ± 3 | 119 ± 6 | 120 ± 5 | 106 ± 3
Week 14 | 127 ± 2 | 123 ± 2 | 126 ± 3 | 135 ± 11 | 128 ± 6 | 121 ± 2
Total protein (g/dL)
Day 3 | 6.2 ± 0.1 | 6.2 ± 0.0 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1 | 6.5 ± 0.1**
Day 23 | 6.5 ± 0.0 | 6.6 ± 0.0 | 6.6 ± 0.1 | 6.5 ± 0.0 | 6.6 ± 0.1 | 6.8 ± 0.0**
Week 14 | 7.5 ± 0.1 | 7.5 ± 0.0 | 7.4 ± 0.1 | 7.4 ± 0.1 | 7.6 ± 0.1 | 7.6 ± 0.1
Albumin (g/dL)
Day 3 | 4.5 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.0 | 4.6 ± 0.1
Day 23 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.0*
Week 14 | 5.0 ± 0.0 | 4.9 ± 0.0 | 4.9 ± 0.0* | 4.9 ± 0.0 | 5.0 ± 0.0 | 5.0 ± 0.0
Globulin (g/dL)
Day 3 | 1.7 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.0* | 1.9 ± 0.0**
Day 23 | 1.9 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 1.9 ± 0.0 | 2.0 ± 0.0* | 2.1 ± 0.0**
Week 14 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0 | 2.6 ± 0.0 | 2.6 ± 0.0
A/G ratio (albumin/globulin ratio)
Day 3 | 2.6 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0* | 2.4 ± 0.0** | 2.4 ± 0.0**
Day 23 | 2.4 ± 0.0 | 2.4 ± 0.0 | 2.3 ± 0.0 | 2.4 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0
Week 14 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 54 ± 1 | 54 ± 1 | 53 ± 2 | 53 ± 1 | 61 ± 1** | 70 ± 4**
Day 23 | 44 ± 1 | 45 ± 1 | 42 ± 1 | 43 ± 1 | 45 ± 1 | 63 ± 4**
Week 14 | 129 ± 18 | 113 ± 5 | 97 ± 6 | 94 ± 4 | 96 ± 5 | 82 ± 2**
Alkaline phosphatase (IU/L)
Day 3 | 578 ± 11 | 580 ± 7 | 575 ± 9 | 587 ± 8 | 622 ± 9** | 625 ± 13**
Day 23 | 385 ± 8 | 404 ± 9 | 397 ± 8 | 382 ± 8 | 415 ± 9* | 434 ± 11**
Week 14 | 254 ± 4 | 238 ± 3 | 233 ± 5* | 239 ± 5 | 241 ± 6 | 263 ± 5
Creatine kinase (IU/L)
Day 3 | 532 ± 64 | 424 ± 30 | 426 ± 22^b^ | 450 ± 34 | 629 ± 96 | 563 ± 35
Day 23 | 244 ± 16 | 327 ± 58 | 330 ± 28* | 335 ± 15** | 397 ± 42** | 378 ± 50**
Week 14 | 189 ± 22 | 208 ± 32 | 237 ± 32 | 226 ± 25 | 283 ± 59 | 261 ± 33
Sorbitol dehydrogenase (IU/L)
Day 3 | 13 ± 1^b^ | 12 ± 1 | 13 ± 1 | 12 ± 1 | 12 ± 1 | 16 ± 1
Day 23 | 14 ± 1 | 14 ± 1 | 14 ± 1 | 13 ± 1 | 13 ± 1 | 27 ± 3**
Week 14 | 26 ± 3 | 25 ± 1 | 24 ± 1 | 23 ± 1 | 26 ± 1 | 25 ± 1
Bile acids (µmol/L)
Day 3 | 5.8 ± 0.8 | 4.5 ± 0.5 | 4.2 ± 0.4 | 6.7 ± 2.0 | 6.0 ± 0.8 | 6.9 ± 1.2
Day 23 | 4.3 ± 0.5 | 4.0 ± 0.2 | 3.7 ± 0.2 | 4.2 ± 0.4 | 5.1 ± 1.0 | 4.2 ± 0.3
Week 14 | 3.2 ± 0.2 | 3.0 ± 0.1 | 2.7 ± 0.1 | 3.3 ± 0.2 | 2.7 ± 0.2 | 2.7 ± 0.1
Female
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 9 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (manual) (%)
Day 3 | 49.7 ± 0.8 | 49.4 ± 0.5 | 48.8 ± 0.4 | 49.2 ± 0.8 | 49.3 ± 0.5 | 50.7 ± 0.4
Day 23 | 48.9 ± 0.5 | 48.6 ± 0.3 | 47.7 ± 0.2 | 48.7 ± 0.5 | 48.5 ± 0.2 | 49.1 ± 0.4
Week 14 | 48.4 ± 0.4 | 48.0 ± 0.3 | 47.3 ± 0.2 | 47.5 ± 0.2 | 47.8 ± 0.4 | 47.6 ± 0.3
Packed cell volume (auto) (%)
Day 3 | 48.5 ± 0.8 | 48.9 ± 0.4 | 47.8 ± 0.5 | 48.4 ± 0.8 | 48.4 ± 0.6 | 49.5 ± 0.3
Day 23 | 48.2 ± 0.4 | 48.3 ± 0.3 | 47.2 ± 0.3 | 48.2 ± 0.4 | 47.7 ± 0.2 | 48.5 ± 0.5
Week 14 | 48.0 ± 0.6 | 47.9 ± 0.3 | 47.2 ± 0.2 | 47.3 ± 0.2 | 47.3 ± 0.6 | 47.8 ± 0.3
Hemoglobin (g/dL)
Day 3 | 15.0 ± 0.2 | 15.3 ± 0.1 | 15.1 ± 0.1 | 15.3 ± 0.2 | 15.4 ± 0.1 | 15.7 ± 0.1**
Day 23 | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.7 ± 0.2
Week 14 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.2 | 15.2 ± 0.1
Erythrocytes (10^6^/µL)
Day 3 | 7.87 ± 0.12 | 8.03 ± 0.08 | 7.92 ± 0.08 | 7.99 ± 0.12 | 8.08 ± 0.09 | 8.31 ± 0.07**
Day 23 | 8.27 ± 0.07 | 8.26 ± 0.08 | 8.17 ± 0.08 | 8.30 ± 0.08 | 8.16 ± 0.04 | 8.40 ± 0.10
Week 14 | 8.46 ± 0.08 | 8.47 ± 0.06 | 8.39 ± 0.04 | 8.41 ± 0.04 | 8.36 ± 0.10 | 8.40 ± 0.07
Reticulocytes (10^6^/µL)
Day 3 | 0.37 ± 0.04 | 0.35 ± 0.01^c^ | 0.37 ± 0.03 | 0.36 ± 0.03^b^ | 0.36 ± 0.03 | 0.38 ± 0.02^b^
Day 23 | 0.21 ± 0.01 | 0.24 ± 0.01 | 0.22 ± 0.01 | 0.24 ± 0.01 | 0.25 ± 0.01 | 0.25 ± 0.01
Week 14 | 0.17 ± 0.01 | 0.15 ± 0.01 | 0.18 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.20 ± 0.01
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.4 ± 0.2 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.1 ± 0.1
Day 23 | 0.0 ± 0.0 | 0.1 ± 0.1 | 0.3 ± 0.2 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.3 ± 0.2
Week 14 | 0.4 ± 0.2 | 0.6 ± 0.2 | 0.5 ± 0.2 | 0.7 ± 0.3 | 0.7 ± 0.3 | 0.5 ± 0.2
Mean cell volume (fL)
Day 3 | 61.6 ± 0.3 | 60.9 ± 0.4 | 60.3 ± 0.4 | 60.7 ± 0.4 | 60.0 ± 0.5* | 59.6 ± 0.4**
Day 23 | 58.3 ± 0.3 | 58.5 ± 0.4 | 57.9 ± 0.3 | 58.2 ± 0.3 | 58.5 ± 0.1 | 57.7 ± 0.2
Week 14 | 56.7 ± 0.2 | 56.5 ± 0.2 | 56.2 ± 0.2 | 56.2 ± 0.2 | 56.6 ± 0.2 | 56.9 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.0 ± 0.0 | 19.0 ± 0.1 | 19.1 ± 0.1 | 19.1 ± 0.1 | 19.1 ± 0.1 | 19.0 ± 0.1
Day 23 | 18.8 ± 0.1 | 18.8 ± 0.1 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.9 ± 0.1 | 18.7 ± 0.1
Week 14 | 18.2 ± 0.1 | 18.2 ± 0.1 | 18.3 ± 0.0 | 18.1 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.0
Mean cell hemoglobin concentration (g/dL)
Day 3 | 30.8 ± 0.1 | 31.2 ± 0.2 | 31.7 ± 0.2** | 31.5 ± 0.2** | 31.9 ± 0.3** | 31.8 ± 0.2**
Day 23 | 32.3 ± 0.2 | 32.3 ± 0.1 | 32.4 ± 0.1 | 32.1 ± 0.1 | 32.2 ± 0.1 | 32.3 ± 0.2
Week 14 | 32.1 ± 0.2 | 32.1 ± 0.1 | 32.5 ± 0.1 | 32.2 ± 0.1 | 32.0 ± 0.1 | 31.8 ± 0.1
Platelets (10^3^/µL)
Day 3 | 844.0 ± 22.9 | 807.7 ± 31.8 | 831.1 ± 27.3 | 777.3 ± 14.4 | 879.0 ± 20.7 | 799.8 ± 23.6
Day 23 | 719.0 ± 20.6 | 709.5 ± 22.2 | 692.0 ± 19.0 | 701.0 ± 13.3 | 706.2 ± 12.5 | 725.0 ± 11.2
Week 14 | 630.0 ± 15.5 | 624.1 ± 13.2 | 597.4 ± 11.8 | 626.6 ± 11.9 | 607.3 ± 9.9 | 614.9 ± 12.3
Leukocytes (10^3^/µL)
Day 3 | 10.27 ± 0.39 | 11.19 ± 0.54 | 12.73 ± 0.31** | 13.41 ± 0.46** | 13.21 ± 0.49** | 12.48 ± 0.34**
Day 23 | 8.12 ± 0.29 | 7.16 ± 0.36 | 8.11 ± 0.61 | 8.46 ± 0.43 | 8.17 ± 0.74 | 8.00 ± 0.59
Week 14 | 6.69 ± 0.50 | 5.34 ± 0.25 | 6.52 ± 0.44 | 5.90 ± 0.34 | 6.19 ± 0.52 | 6.02 ± 0.47
Segmented neutrophils (10^3^/µL)
Day 3 | 0.82 ± 0.06 | 1.04 ± 0.13 | 1.85 ± 0.10** | 1.20 ± 0.07* | 0.94 ± 0.05 | 0.84 ± 0.04
Day 23 | 0.85 ± 0.07 | 0.97 ± 0.11 | 0.84 ± 0.04 | 0.79 ± 0.03 | 0.96 ± 0.14 | 0.68 ± 0.03
Week 14 | 1.06 ± 0.09 | 0.90 ± 0.08 | 0.95 ± 0.07 | 0.79 ± 0.05 | 1.08 ± 0.07 | 1.09 ± 0.10
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 3 | 9.16 ± 0.39 | 9.83 ± 0.43 | 10.62 ± 0.31* | 11.76 ± 0.40** | 11.80 ± 0.37** | 11.34 ± 0.35**
Day 23 | 7.04 ± 0.25 | 5.87 ± 0.27 | 7.03 ± 0.60 | 7.40 ± 0.45 | 6.87 ± 0.63 | 7.04 ± 0.56
Week 14 | 5.29 ± 0.45 | 4.21 ± 0.23 | 5.23 ± 0.48 | 4.85 ± 0.32 | 4.77 ± 0.47 | 4.53 ± 0.37
Monocytes (10^3^/µL)
Day 3 | 0.18 ± 0.05 | 0.19 ± 0.04 | 0.13 ± 0.05 | 0.31 ± 0.10 | 0.33 ± 0.10 | 0.17 ± 0.07
Day 23 | 0.11 ± 0.04 | 0.22 ± 0.12 | 0.14 ± 0.07 | 0.16 ± 0.06 | 0.23 ± 0.08 | 0.18 ± 0.06
Week 14 | 0.25 ± 0.07 | 0.14 ± 0.05 | 0.24 ± 0.07 | 0.16 ± 0.04 | 0.26 ± 0.06 | 0.32 ± 0.06
Basophils (10^3^/µL)
Day 3 | 0.015 ± 0.002 | 0.017 ± 0.002 | 0.012 ± 0.003 | 0.020 ± 0.004 | 0.026 ± 0.006 | 0.021 ± 0.005
Day 23 | 0.009 ± 0.002 | 0.006 ± 0.003 | 0.009 ± 0.004 | 0.010 ± 0.003 | 0.007 ± 0.003 | 0.006 ± 0.002
Week 14 | 0.005 ± 0.002 | 0.003 ± 0.002 | 0.005 ± 0.002 | 0.007 ± 0.006 | 0.005 ± 0.002 | 0.005 ± 0.002
Eosinophils (10^3^/µL)
Day 3 | 0.09 ± 0.01 | 0.12 ± 0.02 | 0.12 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.01 | 0.11 ± 0.01
Day 23 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.02
Week 14 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 10.5 ± 0.5 | 10.6 ± 0.5 | 10.4 ± 0.6 | 10.7 ± 0.5 | 12.7 ± 0.6* | 15.1 ± 0.6**
Day 23 | 10.9 ± 0.4 | 12.6 ± 0.7* | 12.2 ± 0.5* | 12.6 ± 0.5** | 13.2 ± 0.5** | 14.7 ± 0.6**
Week 14 | 14.6 ± 0.4 | 15.1 ± 0.6 | 15.1 ± 0.5 | 15.8 ± 0.4 | 15.9 ± 0.4 | 15.1 ± 0.4
Creatinine (mg/dL)
Day 3 | 0.29 ± 0.01 | 0.32 ± 0.01 | 0.30 ± 0.01 | 0.27 ± 0.02 | 0.31 ± 0.01 | 0.30 ± 0.00
Day 23 | 0.26 ± 0.02 | 0.28 ± 0.01 | 0.27 ± 0.02 | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.30 ± 0.00
Week 14 | 0.39 ± 0.01 | 0.39 ± 0.01 | 0.40 ± 0.00 | 0.43 ± 0.02 | 0.42 ± 0.02 | 0.45 ± 0.02**
Glucose (mg/dL)
Day 3 | 133 ± 6 | 152 ± 7 | 134 ± 6 | 135 ± 5 | 128 ± 4 | 111 ± 3**
Day 23 | 142 ± 10 | 107 ± 5** | 117 ± 6* | 113 ± 5* | 112 ± 3* | 99 ± 3**
Week 14 | 124 ± 3 | 134 ± 8 | 127 ± 6 | 132 ± 11 | 125 ± 4 | 130 ± 4
Total protein (g/dL)
Day 3 | 6.2 ± 0.1 | 6.0 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1 | 6.5 ± 0.1**
Day 23 | 6.2 ± 0.0 | 6.4 ± 0.1 | 6.3 ± 0.0 | 6.4 ± 0.1 | 6.5 ± 0.1** | 6.6 ± 0.1**
Week 14 | 7.2 ± 0.1 | 7.3 ± 0.1 | 7.5 ± 0.1 | 7.3 ± 0.1 | 7.4 ± 0.1 | 7.4 ± 0.1
Albumin (g/dL)
Day 3 | 4.6 ± 0.1 | 4.4 ± 0.1 | 4.5 ± 0.0 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.7 ± 0.0
Day 23 | 4.6 ± 0.0 | 4.8 ± 0.0 | 4.7 ± 0.0 | 4.8 ± 0.1* | 4.9 ± 0.1** | 4.9 ± 0.1**
Week 14 | 5.1 ± 0.1 | 5.2 ± 0.1 | 5.3 ± 0.1 | 5.2 ± 0.0 | 5.2 ± 0.1 | 5.1 ± 0.1
Globulin (g/dL)
Day 3 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.7 ± 0.0 | 1.7 ± 0.0* | 1.8 ± 0.0* | 1.8 ± 0.0**
Day 23 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.7 ± 0.1 | 1.7 ± 0.0
Week 14 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.2 ± 0.0 | 2.1 ± 0.0 | 2.2 ± 0.0 | 2.3 ± 0.1
A/G ratio (albumin/globulin ratio)
Day 3 | 2.8 ± 0.1 | 2.7 ± 0.0 | 2.7 ± 0.1 | 2.6 ± 0.0** | 2.6 ± 0.0** | 2.6 ± 0.0**
Day 23 | 2.9 ± 0.0 | 3.0 ± 0.1 | 2.9 ± 0.0 | 3.0 ± 0.0 | 2.9 ± 0.1 | 2.8 ± 0.0
Week 14 | 2.4 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0 | 2.3 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 48 ± 1 | 46 ± 3 | 43 ± 2 | 47 ± 1 | 43 ± 1 | 63 ± 2
Day 23 | 38 ± 1 | 39 ± 1 | 38 ± 1 | 37 ± 1 | 35 ± 1 | 49 ± 2
Week 14 | 75 ± 6 | 65 ± 5 | 58 ± 5** | 51 ± 2** | 52 ± 2** | 51 ± 2**
Alkaline phosphatase (IU/L)
Day 3 | 492 ± 9 | 467 ± 11 | 478 ± 5 | 508 ± 5 | 511 ± 9 | 512 ± 10
Day 23 | 300 ± 4 | 288 ± 5 | 293 ± 7 | 307 ± 7 | 320 ± 5* | 326 ± 6**
Week 14 | 204 ± 6 | 192 ± 4 | 186 ± 7 | 189 ± 4 | 200 ± 5 | 213 ± 4
Creatine kinase (IU/L)
Day 3 | 600 ± 77 | 1,147 ± 334 | 598 ± 73 | 509 ± 63 | 444 ± 42 | 702 ± 140
Day 23 | 289 ± 34 | 291 ± 35 | 305 ± 15 | 288 ± 32 | 267 ± 20 | 300 ± 36
Week 14 | 198 ± 13 | 209 ± 30 | 212 ± 27 | 176 ± 27 | 222 ± 20 | 254 ± 34
Sorbitol dehydrogenase (IU/L)
Day 3 | 11 ± 1 | 8 ± 1 | 9 ± 1 | 12 ± 0 | 11 ± 1 | 19 ± 1**
Day 23 | 12 ± 1 | 12 ± 1 | 12 ± 0 | 12 ± 1 | 14 ± 0* | 20 ± 1**
Week 14 | 18 ± 1 | 16 ± 1 | 15 ± 1 | 14 ± 0* | 15 ± 1 | 18 ± 1
Bile acids (µmol/L)
Day 3 | 5.1 ± 0.6 | 5.8 ± 0.5 | 6.9 ± 1.8 | 4.8 ± 0.3 | 5.8 ± 0.7 | 8.2 ± 2.1
Day 23 | 7.9 ± 1.8 | 5.7 ± 0.8 | 7.2 ± 2.2 | 5.2 ± 0.4 | 4.2 ± 0.3* | 4.6 ± 0.4
Week 14 | 4.7 ± 0.2 | 6.2 ± 1.4 | 4.6 ± 0.2 | 5.4 ± 1.0 | 4.3 ± 0.1 | 4.6 ± 0.7*

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

Table F-2 Hematology Data for Mice in the Three-Month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
n | 10 | 10 | 10 | 10 | 8 | –
Hematocrit (manual) (%) | 49.9 ± 0.5 | 48.6 ± 0.3 | 47.8 ± 0.4** | 46.5 ± 0.4** | 45.9 ± 0.4** | –
Packed cell volume (auto) (%) | 50.4 ± 0.4 | 49.2 ± 0.4 | 48.1 ± 0.3** | 47.2 ± 0.3** | 46.9 ± 0.4** | –
Hemoglobin (g/dL) | 15.5 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1** | 14.5 ± 0.1** | 14.2 ± 0.1** | –
Erythrocytes (10^6^/µL) | 10.18 ± 0.09 | 9.96 ± 0.09 | 9.74 ± 0.07** | 9.54 ± 0.07** | 9.40 ± 0.08** | –
Reticulocytes (10^6^/µL) | 0.25 ± 0.02 | 0.24 ± 0.01 | 0.24 ± 0.02 | 0.24 ± 0.01 | 0.24 ± 0.02 | –
Nucleated erythrocytes/100 leukocytes | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | –
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | –
Mean cell volume (fL) | 49.5 ± 0.2 | 49.4 ± 0.2 | 49.4 ± 0.2 | 49.5 ± 0.2 | 49.9 ± 0.2 | –
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.0 | 15.2 ± 0.0 | –
Mean cell hemoglobin concentration (g/dL) | 30.8 ± 0.2 | 30.8 ± 0.2 | 30.9 ± 0.1 | 30.6 ± 0.1 | 30.4 ± 0.1 | –
Platelets (10^3^/µL) | 866.7 ± 15.6 | 846.8 ± 15.9 | 898.2 ± 14.8 | 970.3 ± 10.7** | 993.4 ± 11.8** | –
Leukocytes (10^3^/µL) | 2.52 ± 0.27 | 2.45 ± 0.32 | 2.48 ± 0.28 | 2.24 ± 0.28 | 2.56 ± 0.43 | –
Segmented neutrophils (10^3^/µL) | 0.31 ± 0.03 | 0.26 ± 0.03 | 0.31 ± 0.06 | 0.28 ± 0.03 | 0.28 ± 0.04 | –
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | –
Lymphocytes (10^3^/µL) | 2.13 ± 0.24 | 2.07 ± 0.29 | 2.06 ± 0.25 | 1.87 ± 0.25 | 2.18 ± 0.40 | –
Monocytes (10^3^/µL) | 0.02 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.02 | 0.04 ± 0.01 | 0.04 ± 0.02 | –
Basophils (10^3^/µL) | 0.009 ± 0.002 | 0.012 ± 0.002 | 0.011 ± 0.002 | 0.012 ± 0.003 | 0.014 ± 0.003 | –
Eosinophils (10^3^/µL) | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.03 ± 0.00 | 0.04 ± 0.01 | 0.04 ± 0.01 | –
Female
n | 10 | 9 | 10 | 10 | 10 | 6
Hematocrit (manual) (%) | 50.2 ± 0.4 | 49.8 ± 0.4 | 49.8 ± 0.3 | 49.3 ± 0.4 | 48.3 ± 0.5** | 50.3 ± 0.4
Packed cell volume (auto) (%) | 50.7 ± 0.4 | 50.2 ± 0.3 | 50.4 ± 0.4 | 49.9 ± 0.4 | 48.7 ± 0.5* | 50.5 ± 0.4
Hemoglobin (g/dL) | 15.9 ± 0.1 | 15.7 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.2 | 15.3 ± 0.1* | 15.7 ± 0.1
Erythrocytes (10^6^/µL) | 10.19 ± 0.09 | 10.08 ± 0.06 | 10.02 ± 0.07 | 9.97 ± 0.11 | 9.73 ± 0.09** | 9.80 ± 0.08**
Reticulocytes (10^6^/µL) | 0.21 ± 0.01 | 0.20 ± 0.02 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.02 | 0.16 ± 0.02
Nucleated erythrocytes/100 leukocytes | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 49.8 ± 0.2 | 49.8 ± 0.1 | 50.3 ± 0.2 | 50.1 ± 0.3 | 50.0 ± 0.1 | 51.5 ± 0.2**
Mean cell hemoglobin (pg) | 15.6 ± 0.1 | 15.6 ± 0.1 | 15.7 ± 0.0 | 15.7 ± 0.1 | 15.7 ± 0.0 | 16.0 ± 0.0**
Mean cell hemoglobin concentration (g/dL) | 31.3 ± 0.1 | 31.3 ± 0.1 | 31.2 ± 0.1 | 31.3 ± 0.1 | 31.4 ± 0.1 | 31.2 ± 0.1
Platelets (10^3^/µL) | 751.2 ± 11.4 | 789.1 ± 17.1 | 801.8 ± 13.3* | 833.2 ± 13.4** | 853.0 ± 14.9** | 864.3 ± 28.3**
Leukocytes (10^3^/µL) | 2.90 ± 0.25 | 2.67 ± 0.11 | 2.48 ± 0.19 | 3.22 ± 0.39 | 3.19 ± 0.28 | 3.61 ± 0.40
Segmented neutrophils (10^3^/µL) | 0.37 ± 0.03 | 0.31 ± 0.03 | 0.26 ± 0.03 | 0.33 ± 0.06 | 0.41 ± 0.07 | 0.30 ± 0.04
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.45 ± 0.22 | 2.26 ± 0.09 | 2.14 ± 0.16 | 2.78 ± 0.33 | 2.67 ± 0.27 | 3.20 ± 0.38
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.06 ± 0.02 | 0.05 ± 0.01 | 0.07 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01
Basophils (10^3^/µL) | 0.013 ± 0.002 | 0.022 ± 0.004 | 0.012 ± 0.002 | 0.019 ± 0.004 | 0.019 ± 0.003 | 0.020 ± 0.005
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.