# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing was performed as reported by Mortelmans et al.^85^ Vinylidene chloride was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of vinylidene chloride. The high dose was limited by toxicity. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Lymphoma Mutagenicity Test Protocol

The experimental protocol is presented in detail by McGregor et al.^90^ Vinylidene chloride was supplied as a coded aliquot by Radian Corporation. The high dose of vinylidene chloride was determined by solubility and toxicity. L5178Y mouse lymphoma cells were maintained at 37°C as suspension cultures in supplemented Fischer’s medium; normal cycling time was approximately 10 hours. To reduce the number of spontaneously occurring cells resistant to trifluorothymidine (TFT), subcultures were exposed to medium containing thymidine, hypoxanthine, methotrexate, and glycine for 1 day; to medium containing thymidine, hypoxanthine, and glycine for 1 day; and to normal medium for 3 to 5 days. For cloning, the horse serum content was increased and Noble agar was added.

All treatment levels within an experiment, including concurrent positive and solvent controls, were replicated. Treated cultures contained 6 × 10^6^ cells in 10 mL medium. This volume included the S9 fraction in those experiments performed with metabolic activation. Incubation with vinylidene chloride continued for 4 hours, at which time the medium plus vinylidene chloride was removed, and the cells were resuspended in fresh medium and incubated for an additional 2 days to express the mutant phenotype. Cell density was monitored so that log phase growth was maintained. After the 48-hour expression period, cells were plated in medium and soft agar supplemented with TFT for selection of TFT-resistant cells, and cells were plated in nonselective medium and soft agar to determine cloning efficiency. Plates were incubated at 37°C in 5% CO_2_ for 10 to 12 days. The test was initially performed without S9. Because a clearly positive response was not obtained, the test was repeated using freshly prepared S9 from the livers of Aroclor 1254-induced male F344 rats.

Minimum criteria for accepting an experiment as valid and a detailed description of the statistical analysis and data evaluation are presented by Caspary et al.^151^ All data were evaluated statistically for trend and peak responses. Both responses had to be significant (P≤0.05) for vinylidene chloride to be considered positive, i.e., capable of inducing TFT resistance. A single significant response led to a call of “questionable,” and the absence of both a trend and peak response resulted in a “negative” call.

## E.3 Drosophila melanogaster Test Protocol

The assays for induction of sex-linked recessive lethal (SLRL) mutations were performed with adult flies as described by Foureman et al.^130^ Vinylidene chloride was supplied as a coded aliquot by Radian Corporation. Vinylidene chloride was assayed in the SLRL test by feeding for 3 days to adult Canton-S wild-type males no more than 24 hours old at the beginning of treatment. Because no response was obtained, vinylidene chloride was retested by injection into adult males.

To administer vinylidene chloride by injection, a glass Pasteur pipette was drawn out in a flame to a microfine filament, and the tip was broken off to allow delivery of the test solution. Injection was performed either manually, by attaching a rubber bulb to the other end of the pipette and forcing through sufficient solution (0.2 to 0.3 µL) to slightly distend the abdomen of the fly, or by attaching the pipette to a microinjector that automatically delivered a calibrated volume. Flies were anesthetized with ether and immobilized on a strip of tape. Injection into the thorax, under the wing, was performed with the aid of a dissecting microscope.

Toxicity tests were performed to set concentrations of vinylidene chloride at a level that would induce 30% mortality after 72 hours of feeding or 24 hours after injection, while keeping induced sterility at an acceptable level. Canton-S males were allowed to feed for 72 hours on a solution of vinylidene chloride in 5% sucrose. In the injection experiments, 24- to 72-hour-old Canton-S males were treated with a solution of vinylidene chloride dissolved in ethanol and allowed to recover for 24 hours. A concurrent ethanol control group was also included. In the adult exposures, treated males were mated to three Basc females for 3 days and were given fresh females at 2-day intervals to produce three matings of 3, 2, and 2 days (in each case, sample sperm from successive matings was treated at successively earlier postmeiotic stages). F_1_ heterozygous females were mated with their siblings and then placed in individual vials. F_1_ daughters from the same parental male were kept together to identify clusters. (A cluster occurs when a number of mutants from a given male result from a single spontaneous premeiotic mutation event and is identified when the number of mutants from that male exceeds the number predicted by a Poisson distribution.) If a cluster was identified, all data from the male in question were discarded. Presumptive lethal mutations were identified as vials containing fewer than 5% of the expected number of wild-type males after 17 days; these were retested to confirm the response.

SLRL data were analyzed by simultaneous comparison with the concurrent and historical controls^152^ using a normal approximation to the binomial test.^153^ A test result was considered positive if the P value was less than or equal to 0.01 and the mutation frequency in the tested group was greater than 0.10% or if the P value was less than or equal to 0.05 and the frequency in the treatment group was greater than 0.15%. A test was considered to be inconclusive if the P value was between 0.05 and 0.01 but the frequency in the treatment group was between 0.10% and 0.15% or if the P value was between 0.10 and 0.05 but the frequency in the treatment group was greater than 0.10%. A test was considered negative if the P value was greater than or equal to 0.10 or if the frequency in the treatment group was less than 0.10%.

## E.4 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^154^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female B6C3F1/N mice. Smears were immediately prepared and fixed in absolute methanol. Slides were sent to the genetic toxicity testing laboratory where they were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs; mature erythrocytes) per animal. In addition, the percentage of polychromatic erythrocytes (PCEs; reticulocytes) among the total erythrocyte population in the peripheral blood was scored for each dose group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month study were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.5 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## E.6 Results

Vinylidene chloride tested over a concentration range of 33.3 to 6,666 µg/plate was not mutagenic in S. typhimurium strains TA98, TA100, TA1535, or TA1537 when testing occurred with or without exogenous metabolic activation (10% induced hamster or rat liver S9 mix) using a preincubation protocol (Table E-1; Mortelmans et al.^85^). However, when tested in a closed system as a vapor, vinylidene chloride (0.16% to 2.5% in air) demonstrated clear mutagenic activity in mouse lymphoma L5178Y tk^+/−^ cells in trials conducted with 10% induced male rat liver S9 mix (Table E-2; McGregor et al.^90^); in the absence of S9, a positive response was seen at a concentration of 30% vinylidene chloride in one of three trials. In vivo, no increase in sex-linked recessive lethal mutations was seen in germ cells of adult male Drosophila melanogaster exposed via feeding (20,000 or 25,000 ppm) or injection (5,000 ppm) to vinylidene chloride^130^ (Table E-3). No increase in the frequency of micronucleated NCEs was observed in peripheral blood of male or female B6C3F1/N mice exposed to vinylidene chloride by inhalation for a period of 3 months, and no change in the percentage of immature PCEs (reticulocytes) was seen in these mice following exposure to vinylidene chloride, suggesting the absence of chemical-induced bone marrow toxicity (Table E-4).

Table E-1 Mutagenicity of Vinylidene Chloride in Salmonella typhimurium^a^

Strain | Dose (ìg/plate) | Without S9 | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 99 ± 10 | 81 ± 8 | 91 ± 3 | 96 ± 10 | 93 ± 6 | | 92 ± 4 | 107 ± 3 | 88 ± 7
| 33.3 | | | 95 ± 7 | | 97 ± 7 | | | | 97 ± 7
| 100 | 90 ± 9 | 85 ± 5 | 91 ± 6 | 92 ± 6 | 98 ± 7 | | 106 ± 7 | 98 ± 4 | 97 ± 6
| 333.3 | 87 ± 6 | 80 ± 12 | 97 ± 7 | 94 ± 9 | 104 ± 7 | | 115 ± 8 | 86 ± 11 | 104 ± 4
| 1,000 | 87 ± 4 | 63 ± 4 | 106 ± 2 | 112 ± 5 | 103 ± 10 | | 100 ± 12 | 105 ± 10 | 120 ± 9
| 3,333 | 81 ± 6 | 79 ± 3^b^ | 82 ± 4 | 85 ± 6^b^ | 51 ± 12^b^ | | 87 ± 2^b^ | 84 ± 3^b^ | 110 ± 4
| 6,666 | 89 ± 4 | 78 ± 3^b^ | | 41 ± 21^b^ | | | 71 ± 5^b^ | 81 ± 2^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | | Negative | Negative | Negative
Positive control^c^ | | 130 ± 30 | 376 ± 18 | 500 ± 11 | 1,238 ± 91 | 290 ± 21 | | 604 ± 40 | 826 ± 36 | 1,066 ± 12
TA98
| 0 | 17 ± 2 | 19 ± 1 | 14 ± 3 | 25 ± 1 | 29 ± 2 | 22 ± 2 | 27 ± 3 | 41 ± 2 | 22 ± 3
| 33.3 | | | 8 ± 2 | | | 20 ± 2 | | | 28 ± 5
| 100 | 15 ± 2 | 21 ± 4 | 15 ± 4 | 24 ± 3 | 28 ± 6 | 20 ± 2 | 25 ± 2 | 36 ± 2 | 31 ± 6
| 333.3 | 17 ± 4 | 22 ± 7 | 13 ± 0 | 28 ± 2 | 33 ± 3 | 20 ± 2 | 22 ± 3 | 35 ± 6 | 25 ± 4
| 1,000 | 21 ± 2 | 15 ± 2 | 17 ± 2 | 35 ± 6 | 36 ± 2 | 22 ± 2 | 23 ± 4 | 37 ± 5 | 24 ± 3
| 3,333 | 23 ± 4 | 12 ± 1 | 16 ± 6 | 37 ± 3 | 28 ± 1^b^ | 10 ± 5^b^ | 20 ± 2^b^ | 26 ± 3^b^ | 19 ± 1
| 6,666 | 13 ± 3 | 15 ± 5^b^ | | 44 ± 4 | 12 ± 4^b^ | | 20 ± 5^b^ | 23 ± 3^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 645 ± 7 | 655 ± 70 | 693 ± 39 | 1,292 ± 28 | 198 ± 10 | 199 ± 8 | 428 ± 24 | 542 ± 13 | 787 ± 53
TA1535
| 0 | 17 ± 2 | 18 ± 3 | 8 ± 1 | 10 ± 0 | 9 ± 1 | 12 ± 3 | 6 ± 1 | 11 ± 3 | 5 ± 2
| 33.3 | | | 10 ± 2 | | | 8 ± 0 | | | 6 ± 0
| 100 | 18 ± 1 | 17 ± 1 | 7 ± 1 | 14 ± 0 | 13 ± 3 | 7 ± 2 | 7 ± 1 | 7 ± 2 | 8 ± 1
| 333.3 | 19 ± 4 | 14 ± 3 | 6 ± 1 | 10 ± 3 | 11 ± 2 | 7 ± 1 | 10 ± 2 | 5 ± 0 | 10 ± 3
| 1,000 | 20 ± 6 | 15 ± 1 | 8 ± 3 | 16 ± 1 | 17 ± 1 | 6 ± 2 | 12 ± 1 | 11 ± 2 | 9 ± 2
| 3,333 | 20 ± 0 | 18 ± 1^b^ | 9 ± 0 | 22 ± 2 | 5 ± 0^b^ | 4 ± 2^b^ | 7 ± 1^b^ | 8 ± 1^b^ | 5 ± 1
| 6,666 | 19 ± 3 | 19 ± 3^b^ | | 23 ± 2 | 8 ± 3^b^ | | 8 ± 2^b^ | 6 ± 2^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 19 ± 1 | 300 ± 21 | 337 ± 23 | 374 ± 16 | 326 ± 21 | 186 ± 13 | 389 ± 11 | 355 ± 11 | 387 ± 26
TA1537
| 0 | 7 ± 1 | 6 ± 1 | 6 ± 0 | 16 ± 2 | 10 ± 2 | 5 ± 1 | 14 ± 1 | 15 ± 0 | 6 ± 1
| 33.3 | | | 7 ± 1 | | | 8 ± 1 | | | 12 ± 2
| 100 | 6 ± 1 | 8 ± 1 | 5 ± 1 | 19 ± 3 | 18 ± 3 | 9 ± 2 | 10 ± 1 | 13 ± 2 | 5 ± 2
| 333.3 | 9 ± 1 | 8 ± 1 | 4 ± 1 | 15 ± 1 | 19 ± 3 | 5 ± 1 | 6 ± 1 | 13 ± 1 | 6 ± 1
| 1,000 | 9 ± 1 | 5 ± 2 | 4 ± 1 | 18 ± 1 | 15 ± 0 | 7 ± 4 | 9 ± 1 | 11 ± 2 | 6 ± 1
| 3,333 | 9 ± 1 | 5 ± 1^b^ | 5 ± 2 | 20 ± 2 | 14 ± 4^b^ | 4 ± 0^b^ | 11 ± 1^b^ | 13 ± 6^b^ | 5 ± 1
| 6,666 | 6 ± 1 | 6 ± 1^b^ | | 14 ± 4 | 5 ± 2^b^ | | 10 ± 3^b^ | 8 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 227 ± 44 | 245 ± 42 | 258 ± 17 | 556 ± 24 | 487 ± 35 | 362 ± 20 | 365 ± 20 | 297 ± 29 | 461 ± 16

^a^ Study performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol and these data are presented by Mortelmans et al.^85^ 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Induction of Trifluorothymidine Resistance in L5178Y Mouse Lymphoma Cells by Vinylidene Chloride^a^

Compound | Concentration (%) | Cloning Efficiency (%) | Relative Total Growth (%) | Mutant Count | Mutant Fraction^b^ | Average Mutant Fraction
−S9
Trial 1
Trial call: Questionable
Air^c^ | | 81 | 101 | 41 | 17
| | 63 | 103 | 48 | 26
| | 52 | 80 | 20 | 13
| | 62 | 117 | 57 | 31 | 22
Vinylidene chloride | 1 | 78 | 127 | 72 | 31
| | 71^d^ | 134 | 38 | 18 | 24
| 2 | 0^e^ | 0 | 58 | 0
| | 65 | 108 | 64 | 33
| 4 | 69 | 98 | 70 | 34
| | 69 | 91 | 81 | 39 | 37*
| 6 | 70 | 117 | 53 | 25
| | 58 | 92 | 59 | 34 | 29
| 8 | 71 | 107 | 74 | 35
| | 76 | 128 | 76 | 33 | 34
Methyl methanesulfonate^f^ | 15 µg/mL | 27^d^ | 27 | 75 | 93
| | 24 | 23 | 57 | 81 | 87*
−S9
Trial 2
Trial call: Inconclusive
Air | | 85 | 100 | 63 | 25
| | 78 | 99 | 40 | 17
| | 79 | 109 | 68 | 29
| | 76 | 93 | 62 | 27 | 25
Vinylidene chloride | 3 | 68 | 94 | 32 | 16
| | 65 | 79 | 46 | 24 | 20
| 6 | 72 | 101 | 28 | 13
| | 74 | 92 | 39 | 18 | 15
| 9 | 61 | 88 | 30 | 16
| | 67 | 98 | 31 | 15 | 16
| 12 | 66 | 91 | 22 | 11
| | 68 | 83 | 28 | 14 | 12
| 15 | 67 | 59 | 27 | 13
| | 71 | 74 | 40 | 19 | 16
Methyl methanesulfonate | 15 µg/mL | 35 | 21 | 159 | 152
| | 33 | 21 | 154 | 158 | 155*
−S9
Trial 3
Trial cell: Positive
Air | | 73 | 130 | 31 | 14
| | 79 | 89 | 52 | 22
| | 71 | 78 | 133 | 62
| | 79 | 103 | 66 | 28 | 32
Vinylidene chloride | 10 | 60 | 77 | 61 | 34
| | 63 | 88 | 92 | 49 | 41
| 15 | 82 | 69 | 66 | 27
| | 60 | 60 | 60 | 33 | 30
| 20 | 65 | 94 | 47 | 24
| | 56 | 81 | 70 | 42 | 33
| 25 | 64 | 93 | 60 | 31
| | 63 | 66 | 53 | 28 | 30
| 30 | 43 | 22 | 63 | 49
| | 32 | 19 | 66 | 69 | 59*
Methyl methanesulfonate | 15 µg/mL | 16 | 18 | 137 | 282
| | 27 | 18 | 202 | 252 | 267*
+S9
Trial 1
Trial call: Positive
Air | | 68 | 88 | 92 | 45
| | 77 | 115 | 94 | 41
| | 67 | 97 | 97 | 48
| | 73 | 100 | 107 | 49 | 46
Vinylidene chloride | 0.16 | 68 | 69 | 201 | 99
| | 81 | 70 | 207 | 86 | 92*
| 0.31 | 46 | 42 | 210 | 153
| | 70 | 79 | 213 | 102 | 127*
| 0.63 | 52 | 37 | 292 | 188
| | 47 | 37 | 299 | 211 | 200*
| 1.25 | 31 | 22 | 308 | 337
| | 36 | 25 | 294 | 271 | 304*
| 2.5 | 45 | 22 | 305 | 227
| | 41 | 16 | 359 | 290 | 258*
Methyl cholanthrene^f^ | 2.5 µg/mL | 34 | 15 | 458 | 456
| | 33 | 20 | 393 | 399 | 427*
+S9
Trial 2
Trial call: Positive
Air | | 79 | 127 | 124 | 52
| | 60 | 86 | 118 | 66
| | 81 | 87 | 115 | 48
| | 83^d^ | 100 | 140 | 56 | 56
Vinylidene chloride | 1 | 57 | 25 | 293 | 171
| | 35 | 13 | 251 | 237 | 204*
| 1.5 | 23 | 6 | 174 | 249
| | 44 | 12 | 297 | 227 | 238*
| 2 | 46 | 11 | 264 | 193
| | 33 | 10 | 226 | 228 | 211*
| 2.5 | 22 | 8 | 134 | 205
| | 43 | 13 | 251 | 195 | 200*
| 3.5 | 8^e^ | 1 | 184 | 783
| | 4^e^ | 1 | 87 | 757
Methyl cholanthrene | 2.5 µg/mL | 24 | 9 | 495 | 697
| | 28 | 11 | 422 | 502 | 600*

* Positive response (P ≤ 0.05) versus the chamber control.

^a^ Study was performed at Inveresk Research International. The detailed protocol and these data are presented by McGregor et al.^90^

^b^ Mutant fraction = mutant cells/106 clonable cells.

^c^ Chamber control.

^d^ Reduced sample size due to contamination and loss of one culture.

^e^ Rejected due to failure to meet quality control criteria.

^f^ Positive control.

Table E-3 Induction of Sex-Linked Recessive Lethal Mutations in Drosophila melanogaster by Vinylidene Chloride^a^

Route of Exposure | Dose (ppm) | Incidence of Death (%) | Incidence of Sterility (%) | No. Lethals Mating 1 | No. Lethals Mating 2 | No. Lethals Mating 3 | Total^b^
Feeding | 25,000 | 13 | 8 | 0/724 | 0/471 | 1/372 | 1/1,567 (0.06%)
| 0 | – | – | 0/854 | 0/694 | 0/449 | 0/1,997 (0.00%)
Feeding | 20,000 | 17 | 4 | 1/1,356 | 1/1,215 | 2/1,146 | 4/3,717 (0.11%)
| 0 | – | – | 1/1,247 | 0/1,014 | 1/1,020 | 2/3,281 (0.06%)
| | | | | | | P = 0.129
Injection | 5,000 | 1 | 15 | 0/2,204 | 1/1653 | 0/1,179 | 1/5,036 (0.02%)
| 0 | – | – | 1/2,132 | 1/2023 | 0/1,104 | 2/5,259 (0.04%)
| | | | | | | P = 0.705^c^

^a^ Study was performed at the University of Wisconsin-Madison. The detailed protocol and these data are presented by Foureman et al.^130^ The mean mutant frequency from 518 negative control experiments is 0.074%.^152^

^b^ Total number of lethal mutations/total number of X chromosomes tested for three mating trials.

^c^ Significance of total number of lethal mutations/total number of X chromosomes tested by a normal approximation to the binomial test.^153^

Table E-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with Vinylidene Chloride by Inhalation for Three Months^a^

| Dose (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^(%)
Male
Air^d^ | | 5 | 2.40 ± 0.33 | | 2.90 ± 0.34
Vinylidene chloride | 6.25 | 5 | 2.00 ± 0.32 | 0.7270 | 2.84 ± 0.45
| 12.5 | 5 | 1.40 ± 0.40 | 0.9478 | 2.58 ± 0.32
| 25 | 5 | 3.20 ± 0.70 | 0.1422 | 3.08 ± 0.14
| 50 | 5 | 2.10 ± 0.58 | 0.6728 | 2.96 ± 0.22
| | | P = 0.363^e^
Female
Air | | 5 | 1.20 ± 0.30 | | 3.10 ± 0.38
Vinylidene chloride | 6.25 | 5 | 0.90 ± 0.43 | 0.6917 | 2.88 ± 0.41
| 12.5 | 5 | 1.40 ± 0.56 | 0.3821 | 2.74 ± 0.31
| 25 | 5 | 1.10 ± 0.43 | 0.5634 | 2.56 ± 0.46
| 50 | 5 | 1.80 ± 0.44 | 0.2010 | 3.14 ± 0.49
| 100 | 5 | 1.00 ± 0.50 | 0.6278 | 2.80 ± 0.31
| | | P = 0.481

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^154^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.006 for males and P ≤ 0.005 for females.

^d^ Chamber control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.