# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of Vinylidene Chloride

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 11 | 20 | 14 | 17
Natural deaths | 3 | 5 | 6 | 9
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 36 | 25 | 30 | 23
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (43) | (45) | (43)
Intestine large, cecum | (49) | (48) | (45) | (45)
Carcinoma | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Intestine large, colon | (49) | (47) | (46) | (46)
Intestine large, rectum | (49) | (47) | (47) | (46)
Intestine small, duodenum | (49) | (47) | (45) | (46)
Adenoma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Intestine small, ileum | (49) | (48) | (45) | (45)
Adenoma | 1 (2%) | – | – | 1 (2%)
Carcinoma | 1 (2%) | 1 (2%) | 1 (2%) | 3 (7%)
Intestine small, jejunum | (48) | (47) | (45) | (45)
Liver | (50) | (50) | (50) | (50)
Fibrosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Hemangioma | – | 1 (2%) | – | 2 (4%)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 1 (2%) | 6 (12%)
Hepatocellular adenoma | 13 (26%) | 12 (24%) | 10 (20%) | 12 (24%)
Hepatocellular adenoma, multiple | 12 (24%) | 9 (18%) | 26 (52%) | 17 (34%)
Hepatocellular carcinoma | 7 (14%) | 12 (24%) | 10 (20%) | 14 (28%)
Hepatocellular carcinoma, multiple | 1 (2%) | 2 (4%) | 2 (4%) | 3 (6%)
Hepatocholangiocarcinoma | – | 1 (2%) | 1 (2%) | 2 (4%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Mesentery | (10) | (16) | (19) | (37)
Hemangiosarcoma | – | – | 1 (5%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (6%) | – | –
Sarcoma | – | 1 (6%) | 1 (5%) | 1 (3%)
Sarcoma, metastatic, skeletal muscle | – | – | 1 (5%) | 1 (3%)
Sarcoma, metastatic, uterus | – | – | – | 1 (3%)
Pancreas | (50) | (49) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, mesentery | – | 1 (2%) | 1 (2%) | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Duct, carcinoma | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Myxoma | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (49) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Squamous cell papilloma | – | 3 (6%) | 1 (2%) | –
Stomach, glandular | (49) | (48) | (49) | (49)
Carcinoma | 1 (2%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | 1 (2%)
Tooth | (0) | (1) | (0) | (0)
Cardiovascular System
Blood vessel | (0) | (1) | (0) | (0)
Heart | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (49)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Subcapsular, adenoma | 1 (2%) | – | – | –
Adrenal medulla | (50) | (48) | (50) | (49)
Pheochromocytoma benign | 1 (2%) | – | – | –
Pheochromocytoma malignant | 1 (2%) | 1 (2%) | – | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Adenoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Parathyroid gland | (24) | (22) | (21) | (31)
Pituitary gland | (50) | (50) | (48) | (47)
Pars distalis, adenoma | 8 (16%) | 5 (10%) | 8 (17%) | 4 (9%)
Pars distalis, carcinoma | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (45) | (46) | (45) | (45)
Ovary | (50) | (49) | (49) | (49)
Cystadenoma | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Hemangioma | – | – | 2 (4%) | –
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Luteoma | 1 (2%) | – | – | –
Uterus | (50) | (49) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%)
Polyp stromal | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Sarcoma | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (50)
Lymph node | (8) | (11) | (1) | (8)
Lumbar, sarcoma, metastatic, skeletal muscle | – | – | – | 1 (13%)
Lumbar, sarcoma, metastatic, skin | – | – | – | 1 (13%)
Lymph node, bronchial | (25) | (38) | (38) | (38)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (3%) | 1 (3%) | 2 (5%)
Myxosarcoma, metastatic, skin | – | 1 (3%) | – | –
Lymph node, mandibular | (31) | (35) | (30) | (37)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (3%)
Lymph node, mediastinal | (42) | (45) | (45) | (47)
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | 1 (2%) | 1 (2%)
Myxosarcoma, metastatic, skin | – | 1 (2%) | – | –
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Lymph node, mesenteric | (47) | (48) | (47) | (45)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Spleen | (50) | (49) | (50) | (49)
Hemangiosarcoma | 3 (6%) | 3 (6%) | 1 (2%) | 1 (2%)
Thymus | (47) | (44) | (46) | (40)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Fibrous histiocytoma | – | 2 (4%) | 2 (4%) | 3 (6%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | 1 (2%)
Subcutaneous tissue, myxosarcoma | – | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, sarcoma | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Subcutaneous tissue, schwannoma malignant | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | – | – | – | 1 (2%)
Skeletal muscle | (3) | (3) | (2) | (4)
Fibrosarcoma | – | – | – | 1 (25%)
Hemangiosarcoma | – | 1 (33%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (33%) | 1 (50%) | 1 (25%)
Sarcoma | 1 (33%) | – | 1 (50%) | 1 (25%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pituitary gland | – | – | 1 (2%) | –
Peripheral nerve | (2) | (2) | (0) | (0)
Spinal cord | (2) | (2) | (0) | (1)
Respiratory System
Larynx | (50) | (50) | (49) | (49)
Lung | (50) | (50) | (50) | (49)
Alveolar/bronchiolar adenoma | 2 (4%) | 4 (8%) | 2 (4%) | 2 (4%)
Alveolar/bronchiolar adenoma, multiple | 1 (2%) | – | – | –
Alveolar/bronchiolar carcinoma | 1 (2%) | 2 (4%) | 6 (12%) | 5 (10%)
Alveolar/bronchiolar carcinoma, multiple | – | – | 1 (2%) | –
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 5 (10%) | 9 (18%) | 3 (6%) | 4 (8%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | 1 (2%) | 2 (4%)
Myxosarcoma, metastatic, skin | – | 1 (2%) | – | –
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Sarcoma, metastatic, skin | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | 1 (2%) | 1 (2%)
Trachea | (50) | (50) | (50) | (49)
Special Senses System
Eye | (50) | (49) | (50) | (49)
Harderian gland | (50) | (50) | (50) | (48)
Adenoma | 1 (2%) | 5 (10%) | 4 (8%) | 1 (2%)
Carcinoma | 3 (6%) | 2 (4%) | 2 (4%) | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Renal tubule, adenoma | – | – | – | 1 (2%)
Urinary bladder | (49) | (49) | (48) | (48)
Hemangiosarcoma | – | – | – | 1 (2%)
Sarcoma, metastatic, uterus | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 2 (4%) | 2 (4%) | –
Lymphoma malignant | 14 (28%) | 20 (40%) | 13 (26%) | 11 (22%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 45 | 46 | 47 | 47
Total primary neoplasms | 88 | 101 | 109 | 110
Total animals with benign neoplasms | 32 | 34 | 38 | 34
Total benign neoplasms | 46 | 46 | 58 | 45
Total animals with malignant neoplasms | 33 | 39 | 36 | 41
Total malignant neoplasms | 42 | 55 | 51 | 65
Total animals with metastatic neoplasms | 5 | 14 | 8 | 11
Total metastatic neoplasms | 5 | 29 | 17 | 26

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Harderian Gland: Adenoma
Overall rate^a^ | 1/50 (2%) | 5/50 (10%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate^b^ | 2.3% | 12.6% | 9.4% | 2.6%
Terminal rate^c^ | 1/36 (3%) | 4/25 (16%) | 4/30 (13%) | 1/24 (4%)
First incidence (days) | 731 (T) | 705 | 731 (T) | 731 (T)
Poly-3 test^d^ | P = 0.480N | P = 0.081 | P = 0.174 | P = 0.732
Harderian Gland: Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 6.9% | 5.0% | 4.6% | 5.1%
Terminal rate | 3/36 (8%) | 0/25 (0%) | 1/30 (3%) | 0/24 (0%)
First incidence (days) | 731 (T) | 590 | 599 | 443
Poly-3 test | P = 0.453N | P = 0.532N | P = 0.501N | P = 0.542N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 7/50 (14%) | 6/50 (12%) | 3/50 (6%)
Adjusted rate | 9.2% | 17.3% | 13.9% | 7.6%
Terminal rate | 4/36 (11%) | 4/25 (16%) | 5/30 (17%) | 1/24 (4%)
First incidence (days) | 731 (T) | 590 | 599 | 443
Poly-3 test | P = 0.374N | P = 0.221 | P = 0.367 | P = 0.550N
Small Intestine (Ileum): Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.3% | 2.5% | 2.3% | 7.8%
Terminal rate | 0/36 (0%) | 0/25 (0%) | 0/30 (0%) | 2/24 (8%)
First incidence (days) | 599 | 584 | 536 | 640
Poly-3 test | P = 0.144 | P = 0.740 | P = 0.759 | P = 0.260
Small Intestine (Duodenum or Ileum): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 4.6% | 2.5% | 4.6% | 10.4%
Terminal rate | 1/36 (3%) | 0/25 (0%) | 1/30 (3%) | 3/24 (13%)
First incidence (days) | 599 | 584 | 536 | 640
Poly-3 test | P = 0.141 | P = 0.531N | P = 0.691 | P = 0.279
Liver: Hemangiosarcoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 6/50 (12%)
Adjusted rate | 2.3% | 2.5% | 2.3% | 15.2%
Terminal rate | 1/36 (3%) | 1/25 (4%) | 1/30 (3%) | 3/24 (13%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | 508
Poly-3 test | P = 0.007 | P = 0.740 | P = 0.758 | P = 0.041
Liver: Hepatocellular Adenoma
Overall rate | 25/50 (50%) | 21/50 (42%) | 36/50 (72%) | 29/50 (58%)
Adjusted rate | 55.3% | 49.0% | 77.6% | 69.0%
Terminal rate | 20/36 (56%) | 13/25 (52%) | 25/30 (83%) | 19/24 (79%)
First incidence (days) | 509 | 471 | 524 | 443
Poly-3 test | P = 0.026 | P = 0.347N | P = 0.015 | P = 0.126
Liver: Hepatocellular Carcinoma
Overall rate | 8/50 (16%) | 14/50 (28%) | 12/50 (24%) | 17/50 (34%)
Adjusted rate | 18.2% | 32.4% | 27.2% | 41.3%
Terminal rate | 6/36 (17%) | 4/25 (16%) | 8/30 (27%) | 9/24 (38%)
First incidence (days) | 611 | 478 | 611 | 415
Poly-3 test | P = 0.022 | P = 0.097 | P = 0.223 | P = 0.015
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 28/50 (56%) | 30/50 (60%) | 37/50 (74%) | 38/50 (76%)
Adjusted rate | 61.5% | 65.4% | 79.3% | 84.4%
Terminal rate | 22/36 (61%) | 14/25 (56%) | 25/30 (83%) | 21/24 (88%)
First incidence (days) | 509 | 471 | 524 | 415
Poly-3 test | P = 0.003 | P = 0.434 | P = 0.041 | P = 0.009
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 2/50 (4%) | 2/49 (4%)
Adjusted rate | 6.9% | 9.8% | 4.7% | 5.3%
Terminal rate | 3/36 (8%) | 1/25 (4%) | 2/30 (7%) | 1/24 (4%)
First incidence (days) | 731 (T) | 478 | 731 (T) | 508
Poly-3 test | P = 0.369N | P = 0.468 | P = 0.506N | P = 0.561N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate | 2.3% | 4.9% | 16.1% | 12.7%
Terminal rate | 1/36 (3%) | 0/25 (0%) | 6/30 (20%) | 1/24 (4%)
First incidence (days) | 731 (T) | 558 | 392 | 502
Poly-3 test | P = 0.038 | P = 0.477 | P = 0.030 | P = 0.080
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 9/50 (18%) | 7/49 (14%)
Adjusted rate | 9.2% | 12.1% | 20.6% | 17.5%
Terminal rate | 4/36 (11%) | 1/25 (4%) | 8/30 (27%) | 2/24 (8%)
First incidence (days) | 731 (T) | 478 | 392 | 502
Poly-3 test | P = 0.141 | P = 0.472 | P = 0.115 | P = 0.216
Ovary: Cystadenoma
Overall rate | 1/50 (2%) | 3/49 (6%) | 1/49 (2%) | 1/49 (2%)
Adjusted rate | 2.3% | 7.6% | 2.4% | 2.6%
Terminal rate | 1/36 (3%) | 2/25 (8%) | 0/30 (0%) | 0/24 (0%)
First incidence (days) | 731 (T) | 673 | 668 | 502
Poly-3 test | P = 0.488N | P = 0.270 | P = 0.756 | P = 0.730
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 8/50 (16%) | 5/50 (10%) | 8/48 (17%) | 4/47 (9%)
Adjusted rate | 18.5% | 12.4% | 19.6% | 10.7%
Terminal rate | 8/36 (22%) | 3/25 (12%) | 8/28 (29%) | 2/24 (8%)
First incidence (days) | 731 (T) | 584 | 731 (T) | 556
Poly-3 test | P = 0.277N | P = 0.319N | P = 0.557 | P = 0.252N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 5/50 (10%) | 9/48 (19%) | 4/47 (9%)
Adjusted rate | 18.5% | 12.4% | 22.0% | 10.7%
Terminal rate | 8/36 (22%) | 3/25 (12%) | 8/28 (29%) | 2/24 (8%)
First incidence (days) | 731 (T) | 584 | 670 | 556
Poly-3 test | P = 0.298N | P = 0.319N | P = 0.450 | P = 0.252N
Skin: Fibrous Histiocytoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 0.0% | 5.0% | 4.7% | 7.9%
Terminal rate | 0/36 (0%) | 0/25 (0%) | 1/30 (3%) | 3/24 (13%)
First incidence (days) | —^e^ | 563 | 668 | 731 (T)
Poly-3 test | P = 0.083 | P = 0.221 | P = 0.235 | P = 0.097
Skin (Subcutaneous Tissue): Sarcoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.3% | 2.5% | 2.3% | 7.7%
Terminal rate | 1/36 (3%) | 0/25 (0%) | 1/30 (3%) | 0/24 (0%)
First incidence (days) | 731 (T) | 606 | 731 (T) | 592
Poly-3 test | P = 0.148 | P = 0.743 | P = 0.758 | P = 0.269
Skin: Fibrous Histiocytoma, Fibrosarcoma, Myxosarcoma, or Sarcoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate | 4.6% | 9.8% | 9.2% | 15.4%
Terminal rate | 1/36 (3%) | 1/25 (4%) | 2/30 (7%) | 3/24 (13%)
First incidence (days) | 605 | 563 | 653 | 592
Poly-3 test | P = 0.080 | P = 0.303 | P = 0.332 | P = 0.098
Spleen: Hemangiosarcoma
Overall rate | 3/50 (6%) | 3/49 (6%) | 1/50 (2%) | 1/49 (2%)
Adjusted rate | 6.9% | 7.5% | 2.3% | 2.7%
Terminal rate | 3/36 (8%) | 2/25 (8%) | 1/30 (3%) | 1/24 (4%)
First incidence (days) | 731 (T) | 471 | 731 (T) | 731 (T)
Poly-3 test | P = 0.188N | P = 0.624 | P = 0.309N | P = 0.356N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.6% | 2.3% | 0.0%
Terminal rate | 0/36 (0%) | 3/25 (12%) | 0/30 (0%) | 0/24 (0%)
First incidence (days) | — | 731 (T) | 653 | —
Poly-3 test | P = 0.420N | P = 0.102 | P = 0.499 | —^f^
Uterus: Stromal Polyp
Overall rate | 2/50 (4%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 4.6% | 5.0% | 2.3% | 7.7%
Terminal rate | 2/36 (6%) | 1/25 (4%) | 1/30 (3%) | 0/24 (0%)
First incidence (days) | 731 (T) | 603 | 731 (T) | 626
Poly-3 test | P = 0.376 | P = 0.665 | P = 0.504N | P = 0.453
All Organs: Hemangiosarcoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 4/50 (8%) | 9/50 (18%)
Adjusted rate | 9.2% | 9.9% | 9.2% | 22.5%
Terminal rate | 4/36 (11%) | 3/25 (12%) | 2/30 (7%) | 5/24 (21%)
First incidence (days) | 731 (T) | 471 | 620 | 508
Poly-3 test | P = 0.044 | P = 0.603 | P = 0.643 | P = 0.084
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 6/50 (12%) | 6/50 (12%) | 11/50 (22%)
Adjusted rate | 9.2% | 14.9% | 13.9% | 27.5%
Terminal rate | 4/36 (11%) | 4/25 (16%) | 4/30 (13%) | 7/24 (29%)
First incidence (days) | 731 (T) | 471 | 620 | 508
Poly-3 test | P = 0.018 | P = 0.324 | P = 0.368 | P = 0.027
All Organs: Malignant Lymphoma
Overall rate | 14/50 (28%) | 20/50 (40%) | 13/50 (26%) | 11/50 (22%)
Adjusted rate | 31.5% | 47.0% | 30.1% | 28.1%
Terminal rate | 11/36 (31%) | 11/25 (44%) | 11/30 (37%) | 8/24 (33%)
First incidence (days) | 509 | 563 | 668 | 440
Poly-3 test | P = 0.231N | P = 0.098 | P = 0.538N | P = 0.460N
All Organs: Benign Neoplasms
Overall rate | 32/50 (64%) | 34/50 (68%) | 38/50 (76%) | 34/50 (68%)
Adjusted rate | 70.8% | 74.1% | 81.9% | 77.8%
Terminal rate | 27/36 (75%) | 19/25 (76%) | 27/30 (90%) | 21/24 (88%)
First incidence (days) | 509 | 471 | 524 | 443
Poly-3 test | P = 0.210 | P = 0.452 | P = 0.142 | P = 0.292
All Organs: Malignant Neoplasms
Overall rate | 33/50 (66%) | 39/50 (78%) | 36/50 (72%) | 41/50 (82%)
Adjusted rate | 69.2% | 80.9% | 74.9% | 83.7%
Terminal rate | 23/36 (64%) | 17/25 (68%) | 21/30 (70%) | 18/24 (75%)
First incidence (days) | 440 | 471 | 392 | 413
Poly-3 test | P = 0.091 | P = 0.132 | P = 0.342 | P = 0.069
All Organs: Benign or Malignant Neoplasms
Overall rate | 45/50 (90%) | 46/50 (92%) | 47/50 (94%) | 47/50 (94%)
Adjusted rate | 94.3% | 94.0% | 94.9% | 95.7%
Terminal rate | 35/36 (97%) | 23/25 (92%) | 29/30 (97%) | 23/24 (96%)
First incidence (days) | 440 | 471 | 392 | 413
Poly-3 test | P = 0.434 | P = 0.660N | P = 0.637 | P = 0.566

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, pituitary gland, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Liver Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatocellular Adenoma or Carcinoma | Hepatocholangiocarcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 19/50 | 5/50 | 24/50 | 0/50
CIMSTAR 3800 (May 2008) | 19/50 | 10/50 | 25/50 | 0/50
Cobalt (May 2006) | 14/50 | 4/50 | 16/50 | 0/50
Diethylamine (August 2003) | 14/50 | 10/50 | 20/50 | 0/50
Tetralin (June 2003) | 14/50 | 7/50 | 20/50 | 0/50
Vinylidene chloride (June 2005) | 25/50 | 8/50 | 28/50 | 0/50
Total (%) | 105/300 (35.0%) | 44/300 (14.7%) | 133/300 (44.3%) | 0/300
Mean ± standard deviation | 35.0% ± 8.8% | 14.7% ± 5.0% | 44.3% ± 8.6% | –
Range | 28%–50% | 8%–20% | 32%–56% | –
Overall Historical Incidence: All Routes
Total (%) | 378/948 (39.9%) | 152/948 (16.0%) | 448/948 (47.3%) | 0/948
Mean ± standard deviation | 39.9% ± 18.7% | 16.0% ± 10.6% | 47.3% ± 19.3% | –
Range | 14%–78% | 4%–46% | 20%–82% | –

^a^ Data as of June 2013.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 11 | 20 | 14 | 17
Natural deaths | 3 | 5 | 6 | 9
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 36 | 25 | 30 | 23
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (43) | (45) | (43)
Degeneration, hyaline | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | – | – | –
Intestine large, cecum | (49) | (48) | (45) | (45)
Infiltration cellular, mast cell | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | –
Necrosis | – | – | 2 (4%) | –
Intestine large, colon | (49) | (47) | (46) | (46)
Intestine large, rectum | (49) | (47) | (47) | (46)
Intestine small, duodenum | (49) | (47) | (45) | (46)
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Intestine small, ileum | (49) | (48) | (45) | (45)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia | – | 1 (2%) | 2 (4%) | –
Inflammation, chronic active | – | – | 1 (2%) | –
Ulcer | 1 (2%) | – | – | –
Intestine small, jejunum | (48) | (47) | (45) | (45)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | 2 (4%)
Basophilic focus | 1 (2%) | 4 (8%) | – | 3 (6%)
Clear cell focus | 5 (10%) | 2 (4%) | 6 (12%) | 3 (6%)
Cyst | – | – | 1 (2%) | –
Eosinophilic focus | 9 (18%) | 10 (20%) | 9 (18%) | 4 (8%)
Fatty change | 2 (4%) | – | 2 (4%) | –
Hemorrhage | 1 (2%) | – | – | –
Infarct | 1 (2%) | – | 1 (2%) | –
Inflammation, suppurative | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic active | – | – | 2 (4%) | –
Mixed cell focus | – | – | – | 1 (2%)
Necrosis | 2 (4%) | 3 (6%) | 6 (12%) | 3 (6%)
Vacuolization cytoplasmic | – | – | – | 1 (2%)
Mesentery | (10) | (16) | (19) | (37)
Angiectasis | – | – | 1 (5%) | –
Infiltration cellular, mononuclear cell | – | – | – | 1 (3%)
Artery, inflammation | 1 (10%) | – | – | –
Fat, necrosis | 8 (80%) | 14 (88%) | 15 (79%) | 33 (89%)
Pancreas | (50) | (49) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Cyst | – | 1 (2%) | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | 1 (2%)
Artery, inflammation, chronic active | 2 (4%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | 1 (2%) | –
Necrosis | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (49) | (50) | (50)
Hyperplasia, squamous | 2 (4%) | 2 (4%) | – | 2 (4%)
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | – | 1 (2%) | 1 (2%) | 4 (8%)
Ulcer | 1 (2%) | – | – | 1 (2%)
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Stomach, glandular | (49) | (48) | (49) | (49)
Mineralization | 2 (4%) | 2 (4%) | 2 (4%) | –
Necrosis | – | 1 (2%) | 3 (6%) | 1 (2%)
Artery, inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Tooth | (0) | (1) | (0) | (0)
Dysplasia | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (0) | (1) | (0) | (0)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 9 (18%) | 12 (24%) | 12 (24%) | 9 (18%)
Inflammation, suppurative | – | – | 1 (2%) | –
Mineralization | 2 (4%) | 1 (2%) | – | –
Necrosis, chronic | – | 1 (2%) | – | –
Thrombosis | – | 2 (4%) | 1 (2%) | 3 (6%)
Artery, inflammation, chronic active | 2 (4%) | 2 (4%) | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (49)
Angiectasis | 1 (2%) | 1 (2%) | – | –
Hyperplasia | 6 (12%) | 6 (12%) | 8 (16%) | 8 (16%)
Hypertrophy | 4 (8%) | – | 5 (10%) | 3 (6%)
Inflammation, suppurative | – | 1 (2%) | – | –
Vacuolization cytoplasmic | – | – | 1 (2%) | –
Subcapsular, hyperplasia | – | 1 (2%) | – | –
Adrenal medulla | (50) | (48) | (50) | (49)
Hyperplasia | 1 (2%) | 3 (6%) | 1 (2%) | 4 (8%)
Inflammation, suppurative | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Parathyroid gland | (24) | (22) | (21) | (31)
Pituitary gland | (50) | (50) | (48) | (47)
Pars distalis, angiectasis | – | – | 2 (4%) | 1 (2%)
Pars distalis, cyst | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 6 (12%) | 9 (18%) | 8 (17%) | 8 (17%)
Thyroid gland | (50) | (50) | (50) | (50)
Follicular cell, hyperplasia | – | 2 (4%) | 2 (4%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (45) | (46) | (45) | (45)
Hyperplasia | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Ovary | (50) | (49) | (49) | (49)
Angiectasis | – | – | 2 (4%) | –
Cyst | 6 (12%) | 6 (12%) | 12 (24%) | 2 (4%)
Thrombosis | – | 2 (4%) | 2 (4%) | 1 (2%)
Uterus | (50) | (49) | (50) | (50)
Adenomyosis | – | – | 1 (2%) | –
Angiectasis | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, suppurative | – | 1 (2%) | 1 (2%) | –
Inflammation, histiocytic, chronic active | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Necrosis | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | 2 (4%) | 1 (2%)
Ulcer | – | 1 (2%) | – | –
Endometrium, hyperplasia, cystic | 36 (72%) | 41 (84%) | 46 (92%) | 46 (92%)
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (50)
Thrombosis | – | – | – | 1 (2%)
Myeloid cell hyperplasia | – | 1 (2%) | 2 (4%) | 1 (2%)
Lymph node | (8) | (11) | (1) | (8)
Hyperplasia, lymphoid | – | – | – | 1 (13%)
Iliac, ectasia | – | 1 (9%) | – | –
Lumbar, renal, angiectasis | 1 (13%) | – | – | –
Lumbar, renal, inflammation, granulomatous | 1 (13%) | – | – | –
Renal, angiectasis | 1 (13%) | – | – | –
Renal, ectasia | – | – | – | 1 (13%)
Lymph node, bronchial | (25) | (38) | (38) | (38)
Lymph node, mandibular | (31) | (35) | (30) | (37)
Angiectasis | – | 1 (3%) | – | 1 (3%)
Lymph node, mediastinal | (42) | (45) | (45) | (47)
Lymph node, mesenteric | (47) | (48) | (47) | (45)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Spleen | (50) | (49) | (50) | (49)
Hematopoietic cell proliferation | 3 (6%) | 6 (12%) | 7 (14%) | 9 (18%)
Necrosis | – | 1 (2%) | – | –
Thymus | (47) | (44) | (46) | (40)
Cyst | – | – | – | 1 (3%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | 3 (6%)
Skin | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | 3 (6%) | 2 (4%) | 2 (4%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Degeneration | – | – | – | 1 (2%)
Hyperostosis | – | 1 (2%) | – | –
Skeletal muscle | (3) | (3) | (2) | (4)
Nervous System
Brain | (50) | (50) | (50) | (50)
Artery, meninges, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Peripheral nerve | (2) | (2) | (0) | (0)
Spinal cord | (2) | (2) | (0) | (1)
Respiratory System
Larynx | (50) | (50) | (49) | (49)
Degeneration, hyaline | 1 (2%) | – | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Metaplasia, squamous | 2 (4%) | – | 1 (2%) | 1 (2%)
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Squamous epithelium, necrosis | – | – | 1 (2%) | –
Lung | (50) | (50) | (50) | (49)
Degeneration, hyaline | 1 (2%) | – | – | –
Fibrosis | – | – | – | 1 (2%)
Hemorrhage | – | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | 2 (4%) | 5 (10%) | 3 (6%) | 4 (8%)
Alveolar epithelium, hyperplasia | 3 (6%) | 1 (2%) | 4 (8%) | 3 (6%)
Alveolus, infiltration cellular, histiocyte | 3 (6%) | 1 (2%) | 3 (6%) | 3 (6%)
Perivascular, inflammation, chronic active | – | – | – | 2 (4%)
Vein, necrosis | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | – | 1 (2%) | 1 (2%) | 2 (4%)
Hyperostosis | – | 13 (26%) | 45 (90%) | 48 (96%)
Inflammation, suppurative | – | 1 (2%) | 3 (6%) | 5 (10%)
Inflammation, chronic active | 2 (4%) | 1 (2%) | – | 2 (4%)
Olfactory epithelium, accumulation, hyaline droplet | 18 (36%) | 18 (36%) | 13 (26%) | 32 (64%)
Olfactory epithelium, metaplasia, respiratory | 3 (6%) | 29 (58%) | 49 (98%) | 50 (100%)
Olfactory epithelium, necrosis | – | – | 2 (4%) | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 38 (76%) | 33 (66%) | 29 (58%) | 42 (84%)
Respiratory epithelium, hyperplasia | 33 (66%) | 41 (82%) | 39 (78%) | 43 (86%)
Respiratory epithelium, metaplasia, squamous | 3 (6%) | 2 (4%) | 3 (6%) | 7 (14%)
Respiratory epithelium, necrosis | 1 (2%) | 3 (6%) | 5 (10%) | 4 (8%)
Turbinate, atrophy | – | 46 (92%) | 50 (100%) | 49 (98%)
Trachea | (50) | (50) | (50) | (49)
Degeneration, hyaline | 1 (2%) | – | – | –
Foreign body | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Special Senses System
Eye | (50) | (49) | (50) | (49)
Cataract | – | 1 (2%) | 1 (2%) | –
Degeneration | – | – | 1 (2%) | –
Cornea, inflammation, suppurative | – | – | – | 1 (2%)
Cornea, necrosis | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (48)
Hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | 2 (4%) | 1 (2%) | –
Hydronephrosis | 2 (4%) | – | 1 (2%) | 3 (6%)
Infarct | 5 (10%) | 5 (10%) | 2 (4%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Metaplasia, osseous | 3 (6%) | – | 2 (4%) | 3 (6%)
Nephropathy | 26 (52%) | 28 (56%) | 38 (76%) | 35 (70%)
Artery, inflammation, chronic active | 2 (4%) | 3 (6%) | – | 1 (2%)
Glomerulus, amyloid deposition | – | 1 (2%) | – | 1 (2%)
Papilla, inflammation, suppurative | – | – | 1 (2%) | –
Renal tubule, necrosis | – | 1 (2%) | – | –
Renal tubule, pigmentation | – | – | 1 (2%) | –
Urinary bladder | (49) | (49) | (48) | (48)
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Transitional epithelium, hyperplasia | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.