# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of Vinylidene Chloride

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 12 | 5 | 14 | 19
Natural deaths | 9 | 5 | 4 | 12
Survivors
Died last week of study | – | 1 | – | 1
Terminal kill | 29 | 39 | 32 | 18
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (42) | (45) | (47) | (41)
Intestine large, cecum | (47) | (48) | (48) | (40)
Carcinoma | 1 (2%) | – | – | –
Intestine large, colon | (47) | (48) | (48) | (42)
Intestine large, rectum | (48) | (48) | (48) | (42)
Intestine small, duodenum | (44) | (47) | (47) | (38)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | – | – | 2 (5%)
Intestine small, ileum | (44) | (47) | (47) | (39)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | 1 (2%) | – | –
Intestine small, jejunum | (43) | (47) | (47) | (39)
Carcinoma | – | 2 (4%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, testes | – | – | 1 (2%) | –
Hemangioma | – | 1 (2%) | 2 (4%) | –
Hemangiosarcoma | 2 (4%) | 2 (4%) | 3 (6%) | 3 (6%)
Hepatoblastoma | 1 (2%) | – | – | –
Hepatocellular adenoma | 17 (34%) | 16 (32%) | 16 (32%) | 12 (24%)
Hepatocellular adenoma, multiple | 20 (40%) | 19 (38%) | 17 (34%) | 13 (26%)
Hepatocellular carcinoma | 18 (36%) | 18 (36%) | 11 (22%) | 21 (42%)
Hepatocellular carcinoma, multiple | 8 (16%) | 1 (2%) | 4 (8%) | 8 (16%)
Hepatocholangiocarcinoma | 1 (2%) | 2 (4%) | 2 (4%) | 3 (6%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Sarcoma, metastatic, stomach, glandular | – | – | – | 1 (2%)
Mesentery | (6) | (9) | (6) | (3)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (33%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (11%) | – | 1 (33%)
Pancreas | (50) | (49) | (50) | (48)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | 1 (2%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Sarcoma, metastatic, stomach, glandular | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (49) | (50) | (50) | (49)
Squamous cell papilloma | 1 (2%) | – | – | 1 (2%)
Stomach, glandular | (48) | (49) | (49) | (48)
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | 1 (2%)
Sarcoma | – | – | – | 1 (2%)
Tongue | (0) | (0) | (1) | (0)
Tooth | (2) | (2) | (0) | (1)
Cardiovascular System
Blood vessel | (0) | (0) | (1) | (3)
Heart | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | 1 (2%) | – | –
Sarcoma, metastatic, stomach, glandular | – | – | – | 1 (2%)
Capsule, hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Subcapsular, adenoma | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | – | 1 (2%)
Pheochromocytoma malignant | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (49) | (49) | (49)
Adenoma | 2 (4%) | 1 (2%) | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | 1 (2%)
Parathyroid gland | (26) | (22) | (26) | (24)
Pituitary gland | (49) | (49) | (50) | (46)
Pars intermedia, adenoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (50) | (49)
Follicular cell, adenoma | – | – | 1 (2%) | –
Follicular cell, carcinoma | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | 1 (2%)
Seminal vesicle | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Testes | (50) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | – | 1 (2%)
Interstitial cell, adenoma | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Interstitial cell, carcinoma | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | 1 (2%) | – | 1 (2%) | 2 (4%)
Lymph node | (2) | (2) | (0) | (2)
Pancreatic, sarcoma, metastatic, stomach, glandular | – | – | – | 1 (50%)
Renal, hepatocholangiocarcinoma, metastatic, liver | – | 1 (50%) | – | –
Lymph node, bronchial | (33) | (34) | (31) | (19)
Hepatocholangiocarcinoma, metastatic, liver | 1 (3%) | 1 (3%) | – | –
Lymph node, mandibular | (17) | (29) | (19) | (25)
Lymph node, mediastinal | (43) | (29) | (43) | (38)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (3%)
Carcinoma, metastatic, Harderian gland | – | 1 (3%) | – | –
Hemangiosarcoma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | 1 (3%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Lymph node, mesenteric | (46) | (48) | (48) | (47)
Carcinoma, metastatic, intestine large, cecum | 1 (2%) | – | – | –
Carcinoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | 1 (2%)
Spleen | (50) | (49) | (50) | (50)
Hemangiosarcoma | 2 4%) | 3 (6%) | 1 (2%) | 4 (8%)
Thymus | (39) | (37) | (38) | (26)
Hemangiosarcoma | – | 1 (3%) | – | –
Integumentary System
Mammary gland | (1) | (2) | (0) | (1)
Skin | (50) | (50) | (50) | (50)
Fibrous histiocytoma | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Keratoacanthoma | 1 (2%) | – | – | –
Subcutaneous tissue, liposarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (1) | (1) | (2) | (2)
Hemangiosarcoma | 1 (100%) | – | – | 1 (50%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (100%) | 1 (50%) | 1 (50%)
Rhabdomyosarcoma | – | – | 1 (50%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (49)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 7 (14%) | 7 (14%) | 8 (16%) | 7 (14%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | –
Alveolar/bronchiolar carcinoma | 8 (16%) | 8 (16%) | 8 (16%) | 6 (12%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | 1 (2%) | – | –
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Carcinoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 10 (20%) | 11 (22%) | 8 (16%) | 4 (8%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Nose | (50) | (50) | (49) | (49)
Pleura | (1) | (1) | (0) | (0)
Carcinoma, metastatic, Harderian gland | – | 1 (100%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (100%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (48)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 7 (14%) | 6 (12%) | 8 (16%) | 8 (16%)
Carcinoma | – | 2 (4%) | 1 (2%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Bilateral, renal tubule, adenoma | – | – | 1 (2%) | –
Bilateral, renal tubule, carcinoma | – | 1 (2%) | 7 (14%) | 6 (12%)
Bilateral, renal tubule, carcinoma, multiple | – | – | 4 (8%) | –
Capsule, sarcoma, metastatic, stomach, glandular | – | – | – | 1 (2%)
Renal tubule, adenoma | – | 5 (10%) | 15 (30%) | 10 (20%)
Renal tubule, adenoma, multiple | – | – | 3 (6%) | –
Renal tubule, carcinoma | – | 6 (12%) | 17 (34%) | 12 (24%)
Renal tubule, carcinoma, multiple | – | – | 3 (6%) | –
Urinary bladder | (50) | (50) | (50) | (49)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Lymphoma malignant | 2 (4%) | 2 (4%) | 4 (8%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 49 | 49 | 49 | 48
Total primary neoplasms | 114 | 114 | 151 | 130
Total animals with benign neoplasms | 43 | 41 | 43 | 35
Total benign neoplasms | 61 | 60 | 79 | 57
Total animals with malignant neoplasms | 37 | 38 | 42 | 43
Total malignant neoplasms | 53 | 54 | 72 | 73
Total animals with metastatic neoplasms | 11 | 13 | 11 | 7
Total metastatic neoplasms | 19 | 28 | 20 | 25

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Adrenal Cortex: Adenoma
Overall rate^a^ | 1/50 (2%) | 1/50 (2%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate^b^ | 2.4% | 2.1% | 9.6% | 5.5%
Terminal rate^c^ | 1/29 (3%) | 1/40 (3%) | 4/32 (13%) | 1/19 (5%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 705
Poly-3 test^d^ | P = 0.218 | P = 0.734N | P = 0.173 | P = 0.451
Harderian Gland: Adenoma
Overall rate | 7/50 (14%) | 6/50 (12%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 16.5% | 12.7% | 18.9% | 21.2%
Terminal rate | 5/29 (17%) | 6/40 (15%) | 5/32 (16%) | 4/19 (21%)
First incidence (days) | 694 | 729 (T) | 599 | 575
Poly-3 test | P = 0.252 | P = 0.416N | P = 0.498 | P = 0.401
Harderian Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 16.5% | 16.9% | 21.3% | 21.2%
Terminal rate | 5/29 (17%) | 7/40 (18%) | 6/32 (19%) | 4/19 (21%)
First incidence (days) | 694 | 680 | 599 | 575
Poly-3 test | P = 0.302 | P = 0.594 | P = 0.389 | P = 0.401
Small Intestine (Duodenum, Jejunum, or Ileum): Carcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 0.0% | 6.4% | 0.0% | 5.4%
Terminal rate | 0/29 (0%) | 3/40 (8%) | 0/32 (0%) | 1/19 (5%)
First incidence (days) | –^e^ | 729 (T) | – | 563
Poly-3 test | P = 0.311 | P = 0.141 | –^f^ | P = 0.209
Small Intestine (Duodenum, Jejunum, or Ileum): Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 2.4% | 6.4% | 2.4% | 5.4%
Terminal rate | 1/29 (3%) | 3/40 (8%) | 1/32 (3%) | 1/19 (5%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 563
Poly-3 test | P = 0.463 | P = 0.348 | P = 0.758 | P = 0.455
Kidney (Renal Tubule): Adenoma
Overall rate | 0/50 (0%) | 5/50 (10%) | 19/50 (38%) | 10/50 (20%)
Adjusted rate | 0.0% | 10.6% | 44.2% | 26.7%
Terminal rate | 0/29 (0%) | 5/40 (13%) | 15/32 (47%) | 8/19 (42%)
First incidence (days) | – | 729 (T) | 600 | 525
Poly-3 test | P < 0.001 | P = 0.041 | P < 0.001 | P < 0.001
Kidney (Renal Tubule): Carcinoma
Overall rate | 0/50 (0%) | 7/50 (14%) | 31/50 (62%) | 18/50 (36%)
Adjusted rate | 0.0% | 14.7% | 70.5% | 45.8%
Terminal rate | 0/29 (0%) | 5/40 (13%) | 24/32 (75%) | 10/19 (53%)
First incidence (days) | – | 619 | 429 | 537
Poly-3 test | P < 0.001 | P = 0.012 | P < 0.001 | P < 0.001
Kidney (Renal Tubule): Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 11/50 (22%) | 37/50 (74%) | 27/50 (54%)
Adjusted rate | 0.0% | 23.1% | 81.9% | 67.0%
Terminal rate | 0/29 (0%) | 9/40 (23%) | 27/32 (84%) | 17/19 (90%)
First incidence (days) | – | 619 | 429 | 525
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Liver: Hemangiosarcoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 4.7% | 4.2% | 7.2% | 7.9%
Terminal rate | 0/29 (0%) | 2/40 (5%) | 3/32 (9%) | 0/19 (0%)
First incidence (days) | 596 | 729 (T) | 729 (T) | 470
Poly-3 test | P = 0.292 | P = 0.659N | P = 0.484 | P = 0.443
Liver: Hepatocellular Adenoma
Overall rate | 37/50 (74%) | 35/50 (70%) | 33/50 (66%) | 25/50 (50%)
Adjusted rate | 77.6% | 72.5% | 73.8% | 60.0%
Terminal rate | 21/29 (72%) | 31/40 (78%) | 25/32 (78%) | 12/19 (63%)
First incidence (days) | 443 | 619 | 429 | 471
Poly-3 test | P = 0.040N | P = 0.361N | P = 0.422N | P = 0.046N
Liver: Hepatocellular Carcinoma
Overall rate | 26/50 (52%) | 19/50 (38%) | 15/50 (30%) | 29/50 (58%)
Adjusted rate | 55.0% | 38.1% | 33.2% | 64.4%
Terminal rate | 11/29 (38%) | 11/40 (28%) | 7/32 (22%) | 10/19 (53%)
First incidence (days) | 443 | 521 | 508 | 425
Poly-3 test | P = 0.118 | P = 0.070N | P = 0.026N | P = 0.234
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 44/50 (88%) | 41/50 (82%) | 41/50 (82%) | 42/50 (84%)
Adjusted rate | 89.2% | 82.1% | 86.8% | 89.2%
Terminal rate | 24/29 (83%) | 32/40 (80%) | 28/32 (88%) | 17/19 (90%)
First incidence (days) | 443 | 521 | 429 | 425
Poly-3 test | P = 0.425 | P = 0.233N | P = 0.481N | P = 0.634
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 27/50 (54%) | 19/50 (38%) | 15/50 (30%) | 29/50 (58%)
Adjusted rate | 57.1% | 38.1% | 33.2% | 64.4%
Terminal rate | 12/29 (41%) | 11/40 (28%) | 7/32 (22%) | 10/19 (53%)
First incidence (days) | 443 | 521 | 508 | 425
Poly-3 test | P = 0.156 | P = 0.045N | P = 0.015N | P = 0.302
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 45/50 (90%) | 41/50 (82%) | 41/50 (82%) | 42/50 (84%)
Adjusted rate | 91.2% | 82.1% | 86.8% | 89.2%
Terminal rate | 25/29 (86%) | 32/40 (80%) | 28/32 (88%) | 17/19 (90%)
First incidence (days) | 443 | 521 | 429 | 425
Poly-3 test | P = 0.529 | P = 0.146N | P = 0.350N | P = 0.506N
Liver: Hepatocholangiocarcinoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 2.4% | 4.2% | 4.7% | 8.0%
Terminal rate | 0/29 (0%) | 1/40 (3%) | 0/32 (0%) | 1/19 (5%)
First incidence (days) | 704 | 701 | 429 | 563
Poly-3 test | P = 0.181 | P = 0.540 | P = 0.503 | P = 0.262
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 8/50 (16%) | 7/50 (14%)
Adjusted rate | 16.6% | 16.9% | 18.4% | 18.8%
Terminal rate | 6/29 (21%) | 7/40 (18%) | 5/32 (16%) | 5/19 (26%)
First incidence (days) | 694 | 658 | 404 | 548
Poly-3 test | P = 0.430 | P = 0.597 | P = 0.524 | P = 0.512
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 9/50 (18%) | 9/50 (18%) | 8/50 (16%) | 6/50 (12%)
Adjusted rate | 21.1% | 19.0% | 18.6% | 16.3%
Terminal rate | 8/29 (28%) | 8/40 (20%) | 5/32 (16%) | 5/19 (26%)
First incidence (days) | 512 | 664 | 508 | 633
Poly-3 test | P = 0.350N | P = 0.506N | P = 0.497N | P = 0.400N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 13/50 (26%) | 16/50 (32%) | 14/50 (28%) | 12/50 (24%)
Adjusted rate | 30.3% | 33.5% | 31.4% | 32.0%
Terminal rate | 11/29 (38%) | 14/40 (35%) | 9/32 (28%) | 9/19 (47%)
First incidence (days) | 512 | 658 | 404 | 548
Poly-3 test | P = 0.513 | P = 0.459 | P = 0.547 | P = 0.531
Spleen: Hemangiosarcoma
Overall rate | 2/50 (4%) | 3/49 (6%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 4.7% | 6.5% | 2.4% | 10.8%
Terminal rate | 0/29 (0%) | 3/40 (8%) | 0/32 (0%) | 2/19 (11%)
First incidence (days) | 596 | 729 (T) | 648 | 548
Poly-3 test | P = 0.236 | P = 0.537 | P = 0.509N | P = 0.272
All Organs: Hemangioma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.4% | 2.1% | 7.2% | 2.7%
Terminal rate | 1/29 (3%) | 1/40 (3%) | 2/32 (6%) | 1/19 (5%)
First incidence (days) | 729 (T) | 729 (T) | 726 | 729 (T)
Poly-3 test | P = 0.452 | P = 0.734N | P = 0.300 | P = 0.728
All Organs: Hemangiosarcoma
Overall rate | 2/50 (4%) | 5/50 (10%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 4.7% | 10.6% | 12.0% | 15.6%
Terminal rate | 0/29 (0%) | 5/40 (13%) | 4/32 (13%) | 2/19 (11%)
First incidence (days) | 596 | 729 (T) | 648 | 470
Poly-3 test | P = 0.088 | P = 0.257 | P = 0.204 | P = 0.098
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 8/50 (16%) | 6/50 (12%)
Adjusted rate | 7.0% | 12.7% | 19.1% | 15.6%
Terminal rate | 1/29 (3%) | 6/40 (15%) | 6/32 (19%) | 2/19 (11%)
First incidence (days) | 596 | 729 (T) | 648 | 470
Poly-3 test | P = 0.148 | P = 0.291 | P = 0.088 | P = 0.188
All Organs: Malignant Lymphoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 4.7% | 4.2% | 9.6% | 0.0%
Terminal rate | 1/29 (3%) | 0/40 (0%) | 4/32 (13%) | 0/19 (0%)
First incidence (days) | 661 | 639 | 729 (T) | –
Poly-3 test | P = 0.321N | P = 0.651N | P = 0.327 | P = 0.272N
All Organs: Benign Neoplasms
Overall rate | 43/50 (86%) | 41/50 (82%) | 43/50 (86%) | 35/50 (70%)
Adjusted rate | 90.2% | 84.4% | 89.8% | 81.4%
Terminal rate | 27/29 (93%) | 36/40 (90%) | 29/32 (91%) | 18/19 (95%)
First incidence (days) | 443 | 619 | 404 | 471
Poly-3 test | P = 0.176N | P = 0.280N | P = 0.621N | P = 0.144N
All Organs: Malignant Neoplasms
Overall rate | 37/50 (74%) | 38/50 (76%) | 42/50 (84%) | 43/50 (86%)
Adjusted rate | 76.6% | 76.0% | 89.0% | 90.0%
Terminal rate | 19/29 (66%) | 28/40 (70%) | 28/32 (88%) | 17/19 (90%)
First incidence (days) | 443 | 521 | 429 | 425
Poly-3 test | P = 0.020 | P = 0.567N | P = 0.082 | P = 0.058
All Organs: Benign or Malignant Neoplasms
Overall rate | 49/50 (98%) | 49/50 (98%) | 49/50 (98%) | 48/50 (96%)
Adjusted rate | 99.3% | 98.0% | 99.0% | 98.2%
Terminal rate | 29/29 (100%) | 39/40 (98%) | 32/32 (100%) | 19/19 (100%)
First incidence (days) | 443 | 521 | 404 | 425
Poly-3 test | P = 0.541N | P = 0.624N | P = 0.927N | P = 0.732N

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, kidney, liver, lung, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Renal Tubule Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 0/49 | 0/49 | 0/49
CIMSTAR 3800 (May 2008) | 0/50 | 0/50 | 0/50
Cobalt (May 2006) | 0/50 | 0/50 | 0/50
Diethylamine (August 2003) | 0/50 | 0/50 | 0/50
Tetralin (June 2003) | 0/49 | 0/49 | 0/49
Vinylidene chloride (June 2005) | 0/50 | 0/50 | 0/50
Total (%) | 0/298 | 0/298 | 0/298
Overall Historical Incidence: All Routes
Total (%) | 8/944 (0.9%) | 3/944 (0.3%) | 11/944 (1.2%)
Mean ± standard deviation | 0.9% ± 1.4% | 0.3% ± 1.0% | 1.2% ± 1.8%
Range | 0%-4% | 0%-4% | 0%-6%

^a^ Data as of June 2013.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 12 | 5 | 14 | 19
Natural deaths | 9 | 5 | 4 | 12
Survivors
Died last week of study | – | 1 | – | 1
Terminal kill | 29 | 39 | 32 | 18
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (42) | (45) | (47) | (41)
Intestine large, cecum | (47) | (48) | (48) | (40)
Artery, inflammation | – | – | – | 1 (3%)
Intestine large, colon | (47) | (48) | (48) | (42)
Intestine large, rectum | (48) | (48) | (48) | (42)
Intestine small, duodenum | (44) | (47) | (47) | (38)
Necrosis | 1 (2%) | – | 1 (2%) | –
Intestine small, ileum | (44) | (47) | (47) | (39)
Hyperplasia | – | – | 1 (2%) | –
Intestine small, jejunum | (43) | (47) | (47) | (39)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | –
Basophilic focus | 2 (4%) | 4 (8%) | 2 (4%) | 7 (14%)
Clear cell focus | 16 (32%) | 11 (22%) | 10 (20%) | 8 (16%)
Cyst | – | – | 2 (4%) | 2 (4%)
Degeneration, cystic | – | – | 1 (2%) | 1 (2%)
Eosinophilic focus | 9 (18%) | 7 (14%) | 4 (8%) | 6 (12%)
Fatty change | 1 (2%) | – | – | –
Infarct | – | 1 (2%) | – | –
Mineralization | – | – | – | 1 (2%)
Mixed cell focus | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Necrosis | 5 (10%) | 1 (2%) | 2 (4%) | 6 (12%)
Thrombosis | – | 1 (2%) | – | –
Mesentery | (6) | (9) | (6) | (3)
Fat, necrosis | 6 (100%) | 8 (89%) | 6 (100%) | 1 (33%)
Pancreas | (50) | (49) | (50) | (48)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (49) | (50) | (50) | (49)
Hyperplasia, squamous | 4 (8%) | 1 (2%) | 7 (14%) | 10 (20%)
Inflammation, chronic active | 2 (4%) | 2 (4%) | 3 (6%) | 7 (14%)
Mineralization | – | 1 (2%) | – | –
Necrosis | 1 (2%) | 2 (4%) | 2 (4%) | 4 (8%)
Ulcer | 1 (2%) | 1 (2%) | – | 2 (4%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Submucosa, necrosis | – | – | 1 (2%) | –
Stomach, glandular | (48) | (49) | (49) | (48)
Inflammation, acute | – | 1 (2%) | – | –
Mineralization | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis | 4 (8%) | 3 (6%) | 3 (6%) | 5 (10%)
Tongue | (0) | (0) | (1) | (0)
Angiectasis | – | – | 1 (100%) | –
Tooth | (2) | (2) | (0) | (1)
Dysplasia | 2 (100%) | 2 (100%) | – | 1 (100%)
Cardiovascular System
Blood vessel | (0) | (0) | (1) | (3)
Thrombosis | – | – | – | 1 (33%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 11 (22%) | 10 (20%) | 12 (24%) | 13 (26%)
Thrombosis | – | – | 2 (4%) | 1 (2%)
Artery, inflammation, chronic active | – | – | 1 (2%) | 2 (4%)
Endothelium, hyperplasia | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 6 (12%) | 5 (10%) | 3 (6%)
Hypertrophy | 18 (36%) | 11 (22%) | 12 (24%) | 10 (20%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | – | 3 (6%) | 2 (4%) | 3 (6%)
Islets, pancreatic | (50) | (49) | (49) | (49)
Hyperplasia | 3 (6%) | 4 (8%) | 4 (8%) | 2 (4%)
Parathyroid gland | (26) | (22) | (26) | (24)
Cyst | – | – | 2 (8%) | 1 (4%)
Pituitary gland | (49) | (49) | (50) | (46)
Pars distalis, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Thyroid gland | (50) | (49) | (50) | (49)
Follicular cell, hyperplasia | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | 1 (2%) | –
Spermatocele | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Ectasia | 1 (2%) | 1 (2%) | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | 3 (6%) | 5 (10%) | 3 (6%) | 2 (4%)
Prostate | (50) | (50) | (50) | (50)
Inflammation, suppurative | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | – | – | 2 (4%) | 1 (2%)
Artery, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | – | – | 1 (2%)
Inflammation, suppurative | – | 1 (2%) | – | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Atrophy | – | 2 (4%) | – | –
Germinal epithelium, degeneration | 2 (4%) | 5 (10%) | 3 (6%) | 1 (2%)
Interstitial cell, hyperplasia | – | 1 (2%) | – | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Erythroid cell, depletion cellular | – | – | 1 (2%) | –
Lymph node | (2) | (2) | (0) | (2)
Lumbar, hyperplasia, lymphoid | – | – | – | 1 (50%)
Lymph node, bronchial | (33) | (34) | (31) | (19)
Lymph node, mandibular | (17) | (29) | (19) | (25)
Hyperplasia | 1 (6%) | – | – | –
Lymph node, mediastinal | (43) | (29) | (43) | (38)
Lymph node, mesenteric | (46) | (48) | (48) | (47)
Angiectasis | – | – | – | 2 (4%)
Inflammation, granulomatous | – | – | – | 2 (2%)
Necrosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Spleen | (50) | (49) | (50) | (50)
Hematopoietic cell proliferation | 1 (2%) | 4 (8%) | 2 (4%) | 5 (10%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Lymphoid follicle, hyperplasia | – | – | – | 1 (2%)
Thymus | (39) | (37) | (38) | (26)
Cyst | 1 (3%) | – | – | –
Necrosis | 1 (3%) | – | – | –
Integumentary System
Mammary gland | (1) | (2) | (0) | (1)
Skin | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | – | –
Necrosis | 4 (8%) | 5 (10%) | 3 (6%) | 3 (6%)
Epidermis, hyperplasia, squamous | – | – | 1 (2%) | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | – | – | – | 1 (2%)
Hyperostosis | 1 (2%) | – | – | –
Cartilage, degeneration | – | 1 (2%) | – | –
Skeletal muscle | (1) | (1) | (2) | (2)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Respiratory System
Larynx | (50) | (50) | (50) | (49)
Foreign body | 1 (2%) | – | – | 2 (4%)
Inflammation | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | 1 (2%) | – | 2 (4%)
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Metaplasia, squamous | 1 (2%) | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Squamous epithelium, necrosis | – | 1 (2%) | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | – | 1 (2%) | –
Inflammation, chronic active | 2 (4%) | 1 (2%) | 3 (6%) | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | 3 (6%) | 7 (14%) | 4 (8%) | 6 (12%)
Alveolus, infiltration cellular, histiocyte | 4 (8%) | – | 3 (6%) | 4 (8%)
Serosa, hyperplasia | – | – | – | 1 (2%)
Nose | (50) | (50) | (49) | (49)
Foreign body | 2 (4%) | – | 2 (4%) | 4 (8%)
Hemorrhage | – | – | 1 (2%) | –
Hyperostosis | 1 (2%) | 27 (54%) | 45 (92%) | 48 (98%)
Inflammation, suppurative | 3 (6%) | 2 (4%) | 4 (8%) | 7 (14%)
Inflammation, chronic active | – | 1 (2%) | – | –
Polyp, inflammatory | – | – | – | 1 (2%)
Olfactory epithelium, accumulation, hyaline droplet | 2 (4%) | 5 (10%) | 13 (27%) | 11 (22%)
Olfactory epithelium, atrophy | 1 (2%) | 2 (4%) | 1 (2%) | –
Olfactory epithelium, metaplasia, respiratory | 17 (34%) | 39 (78%) | 47 (96%) | 48 (98%)
Olfactory epithelium, necrosis | 4 (8%) | 1 (2%) | 2 (4%) | 4 (8%)
Respiratory epithelium, accumulation, hyaline droplet | 17 (34%) | 21 (42%) | 24 (49%) | 16 (33%)
Respiratory epithelium, hyperplasia | 37 (74%) | 36 (72%) | 35 (71%) | 39 (80%)
Respiratory epithelium, metaplasia, squamous | 2 (4%) | – | 3 (6%) | –
Respiratory epithelium, necrosis | 2 (4%) | – | 2 (4%) | 3 (6%)
Turbinate, atrophy | – | 46 (92%) | 46 (94%) | 47 (96%)
Turbinate, necrosis | – | – | 1 (2%) | –
Pleura | (1) | (1) | (0) | (0)
Trachea | (50) | (50) | (50) | (50)
Inflammation, suppurative | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | – | – | – | 1 (2%)
Epithelium, necrosis | – | – | – | 1 (2%)
Special Senses System
Eye | (50) | (50) | (50) | (48)
Cataract | – | – | – | 1 (2%)
Degeneration | – | – | 1 (2%) | –
Necrosis | – | – | – | 1 (2%)
Cornea, hyperplasia, squamous | – | 1 (2%) | – | –
Cornea, inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | – | 2 (4%) | 3 (6%) | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | 1 (2%) | 5 (10%) | 7 (14%)
Hydronephrosis | 2 (4%) | – | 1 (2%) | 3 (6%)
Infarct | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Metaplasia, osseous | 2 (4%) | 1 (2%) | 1 (2%) | –
Mineralization | 1 (2%) | – | – | –
Nephropathy | 44 (88%) | 46 (92%) | 37 (74%) | 44 (88%)
Papilla, necrosis | 1 (2%) | – | – | –
Pelvis, inflammation, chronic active | – | – | 1 (2%) | –
Renal tubule, hyperplasia | – | 8 (16%) | 22 (44%) | 16 (32%)
Renal tubule, pigmentation | – | 1 (2%) | – | –
Transitional epithelium, hyperplasia | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (49)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Necrosis | – | 1 (2%) | – | 1 (2%)
Transitional epithelium, hyperplasia | – | 2 (4%) | 3 (6%) | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.