# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 19 | 22 | 18 | 28
Natural deaths | 1 | 2 | 2 | 3
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 30 | 26 | 29 | 19
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (49) | (48) | (48) | (48)
Intestine large, colon | (50) | (49) | (48) | (50)
Intestine large, rectum | (49) | (50) | (49) | (49)
Adenoma | – | – | 1 (2%) | –
Leiomyosarcoma, metastatic, vagina | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (49) | (50)
Intestine small, ileum | (50) | (48) | (49) | (49)
Intestine small, jejunum | (50) | (48) | (49) | (49)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Hepatocellular adenoma, multiple | – | – | – | 1 (2%)
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Mesentery | (13) | (20) | (23) | (24)
Oral mucosa | (0) | (1) | (0) | (1)
Squamous cell papilloma | – | 1 (100%) | – | –
Pancreas | (50) | (50) | (50) | (50)
Acinus, adenoma | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (1) | (0) | (0) | (0)
Squamous cell papilloma | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (1) | (1) | (0) | (0)
Leiomyosarcoma | 1 (100%) | – | – | –
Aorta, schwannoma malignant, metastatic, heart | – | 1 (100%) | – | –
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Carcinoma | 1 (2%) | 1 (2%) | – | –
Bilateral, adenoma | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (49)
Pheochromocytoma benign | – | 5 (10%) | 1 (2%) | 1 (2%)
Pheochromocytoma malignant | 1 (2%) | – | 2 (4%) | –
Bilateral, pheochromocytoma benign | – | – | 1 (2%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | 1 (2%)
Carcinoma | – | 1 (2%) | 1 (2%) | –
Parathyroid gland | (49) | (46) | (45) | (47)
Adenoma | – | 1 (2%) | – | –
Pituitary gland | (50) | (49) | (49) | (49)
Pars distalis, adenoma | 32 (64%) | 36 (73%) | 25 (51%) | 28 (57%)
Pars distalis, carcinoma | 1 (2%) | 2 (4%) | – | 1 (2%)
Thyroid gland | (50) | (50) | (48) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
C-cell, adenoma | 3 (6%) | 4 (8%) | 6 (13%) | 11 (22%)
C-cell, carcinoma | – | 6 (12%) | 2 (4%) | 2 (4%)
Follicular cell, adenoma | – | 2 (4%) | – | 1 (2%)
General Body System
Peritoneum | (0) | (1) | (1) | (1)
Genital System
Clitoral gland | (47) | (48) | (45) | (48)
Adenoma | 4 (9%) | 8 (17%) | 3 (7%) | 4 (8%)
Carcinoma | 1 (2%) | – | – | 5 (10%)
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor benign | – | 1 (2%) | – | –
Granulosa cell tumor malignant | – | – | 1 (2%) | –
Granulosa-theca tumor benign | – | 1 (2%) | – | –
Granulosa-theca tumor malignant | 1 (2%) | – | – | –
Sertoli cell tumor malignant | 1 (2%) | – | – | –
Yolk sac carcinoma | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Polyp stromal | 10 (20%) | 9 (18%) | 4 (8%) | 8 (16%)
Sarcoma stromal | – | – | 2 (4%) | –
Bilateral, polyp stromal | 1 (2%) | – | – | –
Endometrium, carcinoma | – | – | 1 (2%) | 1 (2%)
Vagina | (0) | (2) | (0) | (1)
Granulosa cell tumor benign | – | 1 (50%) | – | –
Leiomyosarcoma | – | 1 (50%) | – | –
Polyp | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (2) | (4) | (9)
Lymph node, bronchial | (4) | (7) | (4) | (10)
Lymph node, mandibular | (2) | (0) | (1) | (4)
Lymph node, mediastinal | (33) | (26) | (29) | (38)
Carcinoma, metastatic, thyroid gland | – | 1 (4%) | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Thymus | (46) | (45) | (42) | (42)
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Thymoma benign | – | 1 (2%) | – | –
Thymoma malignant | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Carcinoma | 4 (8%) | – | 2 (4%) | 4 (8%)
Carcinoma, multiple | 1 (2%) | 1 (2%) | – | –
Fibroadenoma | 26 (52%) | 18 (36%) | 21 (42%) | 25 (50%)
Fibroadenoma, multiple | 11 (22%) | 16 (32%) | 10 (20%) | 14 (28%)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell, adenoma | 1 (2%) | 1 (2%) | – | –
Keratoacanthoma | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, fibroma | 1 (2%) | 2 (4%) | 2 (4%) | –
Subcutaneous tissue, neural crest tumor | – | 1 (2%) | – | –
Subcutaneous tissue, sarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Chondroma | – | – | 1 (2%) | –
Osteoma | – | 1 (2%) | – | –
Osteosarcoma | 1 (2%) | – | – | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Skeletal muscle | (1) | (2) | (3) | (0)
Sarcoma | – | – | 1 (33%) | –
Sarcoma, metastatic, uncertain primary site | 1 (100%) | – | – | –
Schwannoma malignant, metastatic, heart | – | 1 (50%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pituitary gland | 1 (2%) | 2 (4%) | – | 1 (2%)
Oligodendroglioma benign | – | 1 (2%) | – | –
Oligodendroglioma malignant | – | – | – | 1 (2%)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | – | 4 (8%) | –
Alveolar/bronchiolar carcinoma, multiple | – | – | – | 1 (2%)
Mesenchymal tumor malignant, metastatic, kidney | – | 1 (2%) | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | 1 (2%) | – | 1 (2%) | –
Sarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Chondroma | – | – | – | 1 (2%)
Respiratory epithelium, adenoma | – | – | – | 12%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Special Senses System
Eye | (50) | (49) | (50) | (49)
Harderian gland | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Lacrimal gland | (0) | (0) | (1) | (1)
Zymbal’s gland | (0) | (0) | (1) | (0)
Carcinoma | – | – | 1 (100%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Mesenchymal tumor malignant | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Renal tubule, adenoma | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, vagina | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | – | 1 (2%)
Leukemia mononuclear | 10 (20%) | 11 (22%) | 13 (26%) | 25 (50%)
Lymphoma malignant | 1 (2%) | – | – | 1 (2%)
Mesothelioma malignant | – | 1 (2%) | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 49 | 49 | 47 | 49
Total primary neoplasms | 119 | 141 | 114 | 142
Total animals with benign neoplasms | 47 | 47 | 44 | 45
Total benign neoplasms | 94 | 113 | 84 | 100
Total animals with malignant neoplasms | 23 | 25 | 26 | 38
Total malignant neoplasms | 25 | 27 | 30 | 42
Total animals with metastatic neoplasms | 3 | 6 | 2 | 1
Total metastatic neoplasms | 7 | 17 | 2 | 1
Total animals with malignant neoplasms of uncertain primary site | 1 | – | – | –
Total animals with uncertain neoplasms– benign or malignant | – | 1 | – | –
Total uncertain neoplasms | – | 1 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Adrenal Cortex: Adenoma
Overall rate^a^ | 2/50 (4%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate^b^ | 4.4% | 7.2% | 2.4% | 2.4%
Terminal rate^c^ | 2/30 (7%) | 3/26 (12%) | 1/29 (3%) | 0/19 (0%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | 670
Poly-3 test^d^ | P = 0.307N | P = 0.462 | P = 0.531N | P = 0.530N
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 0/50 (0%) | 5/50 (10%) | 2/50 (4%) | 2/49 (4%)
Adjusted rate | 0.0% | 12.0% | 4.8% | 4.9%
Terminal rate | 0/30 (0%) | 5/26 (19%) | 2/29 (7%) | 2/19 (11%)
First incidence (days) | –^e^ | 731 (T) | 731 (T) | 731 (T
Poly-3 test | P = 0.411 | P = 0.024 | P = 0.218 | P = 0.216
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 1/50 (2%) | 5/50 (10%) | 3/50 (6%) | 2/49 (4%)
Adjusted rate | 2.2% | 12.0% | 7.2% | 4.9%
Terminal rate | 1/30 (3%) | 5/26 (19%) | 2/29 (7%) | 2/19 (11%)
First incidence (days) | 731 (T) | 731 (T) | 715 | 731 (T)
Poly-3 test | P = 0.541 | P = 0.083 | P = 0.275 | P = 0.467
Clitoral Gland: Adenoma
Overall rate | 4/47 (9%) | 8/48 (17%) | 3/45 (7%) | 4/48 (8%)
Adjusted rate | 9.4% | 19.8% | 7.9% | 10.0%
Terminal rate | 3/28 (11%) | 6/24 (25%) | 3/26 (12%) | 0/18 (0%)
First incidence (days) | 724 | 535 | 731 (T) | 670
Poly-3 test | P = 0.401N | P = 0.151 | P = 0.564N | P = 0.613
Clitoral Gland: Carcinoma
Overall rate | 1/47 (2%) | 0/48 (0%) | 0/45 (0%) | 5/48 (10%)
Adjusted rate | 2.4% | 0.0% | 0.0% | 12.4%
Terminal rate | 1/28 (4%) | 0/24 (0%) | 0/26 (0%) | 3/18 (17%)
First incidence (days) | 731 (T) | – | – | 579
Poly-3 test | P = 0.008 | P = 0.513N | P = 0.523N | P = 0.088
Clitoral Gland: Adenoma or Carcinoma
Overall rate | 5/47 (11%) | 8/48 (17%) | 3/45 (7%) | 8/48 (17%)
Adjusted rate | 11.8% | 19.8% | 7.9% | 19.7%
Terminal rate | 4/28 (14%) | 6/24 (25%) | 3/26 (12%) | 3/18 (17%)
First incidence (days) | 724 | 535 | 731 (T) | 579
Poly-3 test | P = 0.294 | P = 0.243 | P = 0.422N | P = 0.245
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 2.2% | 0.0% | 9.4% | 0.0%
Terminal rate | 1/30 (3%) | 0/26 (0%) | 2/29 (7%) | 0/19 (0%)
First incidence (days) | 731 (T) | – | 526 | –
Poly-3 test | P = 0.564N | P = 0.516N | P = 0.159 | P = 0.518N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 2.2% | 0.0% | 9.4% | 2.4%
Terminal rate | 1/30 (3%) | 0/26 (0%) | 2/29 (7%) | 1/19 (5%)
First incidence (days) | 731 (T) | – | 526 | 731 (T)
Poly-3 test | P = 0.405 | P = 0.516N | P = 0.159 | P = 0.740
Mammary Gland: Fibroadenoma
Overall rate | 37/50 (74%) | 34/50 (68%) | 31/50 (62%) | 39/50 (78%)
Adjusted rate | 76.6% | 73.8% | 68.7% | 85.2%
Terminal rate | 22/30 (73%) | 19/26 (73%) | 20/29 (69%) | 17/19 (90%)
First incidence (days) | 547 | 541 | 423 | 607
Poly-3 test | P = 0.167 | P = 0.469N | P = 0.260N | P = 0.198
Mammary Gland: Carcinoma
Overall rate | 5/50 (10%) | 1/50 (2%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 10.9% | 2.4% | 4.8% | 9.7%
Terminal rate | 2/30 (7%) | 1/26 (4%) | 1/29 (3%) | 3/19 (16%)
First incidence (days) | 592 | 731 (T) | 726 | 712
Poly-3 test | P = 0.558 | P = 0.124N | P = 0.258N | P = 0.564N
Mammary Gland: Fibroadenoma or Carcinoma
Overall rate | 38/50 (76%) | 34/50 (68%) | 31/50 (62%) | 40/50 (80%)
Adjusted rate | 77.9% | 73.8% | 68.7% | 87.3%
Terminal rate | 22/30 (73%) | 19/26 (73%) | 20/29 (69%) | 17/19 (90%)
First incidence (days) | 547 | 541 | 423 | 607
Poly-3 test | P = 0.135 | P = 0.408N | P = 0.212N | P = 0.163
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 32/50 (64%) | 36/49 (73%) | 25/49 (51%) | 28/49 (57%)
Adjusted rate | 66.1% | 79.4% | 57.3% | 63.3%
Terminal rate | 18/30 (60%) | 20/25 (80%) | 16/29 (55%) | 11/19 (58%)
First incidence (days) | 551 | 535 | 514 | 642
Poly-3 test | P = 0.215N | P = 0.105 | P = 0.252N | P = 0.473N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 33/50 (66%) | 38/49 (78%) | 25/49 (51%) | 29/49 (59%)
Adjusted rate | 68.1% | 83.0% | 57.3% | 65.5%
Terminal rate | 18/30 (60%) | 20/25 (80%) | 16/29 (55%) | 12/19 (63%)
First incidence (days) | 551 | 535 | 514 | 642
Poly-3 test | P = 0.191N | P = 0.067 | P = 0.189N | P = 0.482N
Skin (Subcutaneous Tissue): Fibroma or Sarcoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.2% | 4.7% | 7.2% | 0.0%
Terminal rate | 1/30 (3%) | 1/26 (4%) | 3/29 (10%) | 0/19 (0%)
First incidence (days) | 731 (T) | 613 | 731 (T) | –
Poly-3 test | P = 0.378N | P = 0.475 | P = 0.274 | P = 0.518N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/48 (13%) | 11/50 (22%)
Adjusted rate | 6.6% | 9.5% | 14.6% | 26.2%
Terminal rate | 3/30 (10%) | 2/26 (8%) | 4/28 (14%) | 6/19 (32%)
First incidence (days) | 731 (T) | 625 | 579 | 669
Poly-3 test | P = 0.004 | P = 0.461 | P = 0.195 | P = 0.012
Thyroid Gland (C-Cell): Carcinoma
Overall rate | 0/50 (0%) | 6/50 (12%) | 2/48 (4%) | 2/50 (4%)
Adjusted rate | 0.0% | 14.4% | 4.9% | 4.8%
Terminal rate | 0/30 (0%) | 6/26 (23%) | 1/28 (4%) | 1/19 (5%)
First incidence (days) | – | 731 (T) | 670 | 670
Poly-3 test | P = 0.474 | P = 0.011 | P = 0.213 | P = 0.218
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 10/50 (20%) | 8/48 (17%) | 13/50 (26%)
Adjusted rate | 6.6% | 23.7% | 19.3% | 30.8%
Terminal rate | 3/30 (10%) | 8/26 (31%) | 5/28 (18%) | 7/19 (37%)
First incidence (days) | 731 (T) | 625 | 579 | 669
Poly-3 test | P = 0.006 | P = 0.023 | P = 0.071 | P = 0.003
Uterus: Stromal Polyp
Overall rate | 11/50 (22%) | 9/50 (18%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate | 23.7% | 20.9% | 9.4% | 18.9%
Terminal rate | 8/30 (27%) | 5/26 (19%) | 2/29 (7%) | 5/19 (26%)
First incidence (days) | 579 | 610 | 514 | 567
Poly-3 test | P = 0.258N | P = 0.475N | P = 0.062N | P = 0.385N
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 11/50 (22%) | 9/50 (18%) | 6/50 (12%) | 8/50 (16%)
Adjusted rate | 23.7% | 20.9% | 13.9% | 18.9%
Terminal rate | 8/30 (27%) | 5/26 (19%) | 3/29 (10%) | 5/19 (26%)
First incidence (days) | 579 | 610 | 514 | 567
Poly-3 test | P = 0.290N | P = 0.475N | P = 0.179N | P = 0.385N
All Organs: Mononuclear Cell Leukemia
Overall rate | 10/50 (20%) | 11/50 (22%) | 13/50 (26%) | 25/50 (50%)
Adjusted rate | 21.4% | 24.6% | 28.3% | 54.6%
Terminal rate | 3/30 (10%) | 4/26 (15%) | 3/29 (10%) | 8/19 (42%)
First incidence (days) | 631 | 451 | 421 | 395
Poly-3 test | P < 0.001 | P = 0.457 | P = 0.300 | P < 0.001
All Organs: Benign Neoplasms
Overall rate | 47/50 (94%) | 47/50 (94%) | 44/50 (88%) | 45/50 (90%)
Adjusted rate | 94.9% | 98.0% | 90.7% | 96.0%
Terminal rate | 29/30 (97%) | 26/26 (100%) | 26/29 (90%) | 19/19 (100%)
First incidence (days) | 547 | 535 | 423 | 567
Poly-3 test | P = 0.541N | P = 0.380 | P = 0.325N | P = 0.612
All Organs: Malignant Neoplasms
Overall rate | 24/50 (48%) | 25/50 (50%) | 26/50 (52%) | 38/50 (76%)
Adjusted rate | 49.3% | 53.7% | 55.1% | 80.3%
Terminal rate | 8/30 (27%) | 13/26 (50%) | 12/29 (41%) | 15/19 (79%)
First incidence (days) | 547 | 451 | 421 | 395
Poly-3 test | P < 0.001 | P = 0.413 | P = 0.361 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 49/50 (98%) | 49/50 (98%) | 47/50 (94%) | 49/50 (98%)
Adjusted rate | 98.0% | 99.0% | 94.4% | 100.0%
Terminal rate | 29/30 (97%) | 26/26 (100%) | 27/29 (93%) | 19/19 (100%)
First incidence (days) | 547 | 451 | 421 | 395
Poly-3 test | P = 0.452 | P = 0.669 | P = 0.338N | P = 0.506

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, clitoral gland, lung, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table B-3 Historical Incidence of Thyroid Gland (C-Cell) Neoplasms in Control Female F344/N Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 3/50 | 1/50 | 4/50
Diethylamine (August 2003) | 4/50 | 0/50 | 4/50
Tetralin (June 2003) | 3/50 | 0/50 | 3/50
Vinylidene chloride (June 2005) | 3/50 | 0/50 | 3/50
Total (%) | 13/200 (6.5%) | 1/200 (0.5%) | 14/200 (7.0%)
Mean ± standard deviation | 6.5% ±1.0% | 0.5% ± 1.0% | 7.0% ±1.2%
Range | 6%–8% | 0%–2% | 6%–8%
Overall Historical Incidence: All Routes
Total (%) | 81/690 (11.7%) | 6/690 (0.9%) | 87/690 (12.6%)
Mean ± standard deviation | 11.7% ± 5.5% | 0.9% ± 2.0% | 12.7% ± 5.8%
Range | 6%–22% | 0%–7% | 6%–22%

^a^ Data as of June 2013.

Table B-4 Historical Incidence of Mononuclear Cell Leukemia in Control Female F344/N Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 16/50
Diethylamine (August 2003) | 15/50
Tetralin (June 2003) | 17/50
Vinylidene chloride (June 2005) | 10/50
Total (%) | 58/200 (29.0%)
Mean ± standard deviation | 29.0% ± 6.2%
Range | 20%–34%
Overall Historical Incidence: All Routes
Total (%) | 165/700 (23.6%)
Mean ± standard deviation | 23.6% ± 8.2%
Range | 10%–36%

^a^ Data as of June 2013.

Table B-5 Historical Incidence of Adenoma of the Nose in Control Female F344/N Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 0/50
Diethylamine (August 2003) | 0/50
Tetralin (June 2003) | 0/50
Vinylidene chloride (June 2005) | 0/50
Total (%) | 0/200
Overall Historical Incidence: All Routes
Total (%) | 1/697 (0.1%)
Mean ± standard deviation | 0.1% ± 0.5%
Range | 0%–2%

^a^ Data as of June 2013.

Table B-6 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 19 | 22 | 18 | 28
Natural deaths | 1 | 2 | 2 | 3
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 30 | 26 | 29 | 19
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (49) | (48) | (48) | (48)
Intestine large, colon | (50) | (49) | (48) | (50)
Cyst | – | – | 1 (2%) | –
Intestine large, rectum | (49) | (50) | (49) | (49)
Intestine small, duodenum | (50) | (50) | (49) | (50)
Intestine small, ileum | (50) | (48) | (49) | (49)
Intestine small, jejunum | (50) | (48) | (49) | (49)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | 4 (8%) | 4 (8%) | 5 (10%)
Basophilic focus | 46 (92%) | 41 (82%) | 32 (64%) | 29 (58%)
Clear cell focus | 15 (30%) | 19 (38%) | 22 (44%) | 18 (36%)
Degeneration, cystic | – | 2 (4%) | 4 (8%) | 7 (14%)
Eosinophilic focus | 6 (12%) | 11 (22%) | 7 (14%) | 16 (32%)
Fatty change | 1 (2%) | – | – | –
Fatty change, focal | 2 (4%) | 1 (2%) | 3 (6%) | –
Fatty change, diffuse | 19 (38%) | 30 (60%) | 26 (52%) | 30 (60%)
Fibrosis, focal | – | 1 (2%) | – | –
Hepatodiaphragmatic nodule | 3 (6%) | 6 (12%) | 4 (8%) | 5 (10%)
Inflammation, chronic | 42 (84%) | 48 (96%) | 49 (98%) | 48 (96%)
Mixed cell focus | 4 (8%) | 16 (32%) | 12 (24%) | 13 (26%)
Necrosis | – | 3 (6%) | 5 (10%) | 11 (22%)
Bile duct, hyperplasia | 7 (14%) | – | 1 (2%) | 6 (12%)
Mesentery | (13) | (20) | (23) | (24)
Inflammation, chronic active | – | 1 (5%) | – | –
Fat, hemorrhage | – | – | 1 (4%) | –
Fat, necrosis | 13 (100%) | 19 (95%) | 22 (96%) | 23 (96%)
Oral mucosa | (0) | (1) | (0) | (1)
Pharyngeal, hyperplasia, squamous | – | – | – | 1 (100%)
Pancreas | (50) | (50) | (50) | (50)
Basophilic focus | 1 (2%) | – | – | –
Inflammation, granulomatous | – | – | 1 (2%) | –
Acinus, atrophy | 9 (18%) | 13 (26%) | 11 (22%) | 11 (22%)
Acinus, hyperplasia | – | 1 (2%) | 3 (6%) | 3 (6%)
Salivary glands | (50) | (50) | (50) | (50)
Atropy | – | – | – | 1 (2%)
Basophilic focus | – | – | 2 (4%) | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | 1 (2%) | 2 (4%) | 2 (4%)
Necrosis | – | 1 (2%) | – | –
Ulcer | 3 (6%) | 1 (2%) | 1 (2%) | 3 (6%)
Stomach, glandular | (50) | (50) | (50) | (50)
Mineralization | – | 1 (2%) | – | –
Necrosis | 1 (2%) | 4 (8%) | 1 (2%) | 6 (12%)
Tongue | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (1) | (1) | (0) | (0)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 33 (66%) | 34 (68%) | 32 (64%) | 27 (54%)
Thrombosis | – | 1 (2%) | – | 1 (2%)
Pericardium, fibrosis | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Degeneration, cystic | – | – | – | 1 (2%)
Hematopoietic cell proliferation | – | 2 (4%) | – | –
Hyperplasia | 30 (60%) | 28 (56%) | 20 (40%) | 25 (50%)
Hypertrophy | 7 (14%) | 3 (6%) | 1 (2%) | 4 (8%)
Metaplasia, osseous | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (49)
Hyperplasia | 7 (14%) | 10 (20%) | 9 (18%) | 12 (24%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | –
Parathyroid gland | (49) | (46) | (45) | (47)
Angiectasis | – | – | 1 (2%) | –
Hyperplasia | 1 (2%) | – | – | –
Pituitary gland | (50) | (49) | (49) | (49)
Pars distalis, angiectasis | 4 (8%) | 4 (8%) | 4 (8%) | 1 (2%)
Pars distalis, hyperplasia | 12 (24%) | 6 (12%) | 12 (24%) | 11 (22%)
Thyroid gland | (50) | (50) | (48) | (50)
C-cell, hyperplasia | 35 (70%) | 30 (60%) | 32 (67%) | 27 (54%)
Follicular cell, hyperplasia | – | 1 (2%) | – | 1 (2%)
General Body System
Peritoneum | (0) | (1) | (1) | (1)
Inflammation, acute | – | 1 (100%) | – | –
Mesothelium, hyperplasia | – | – | – | 1 (100%)
Genital System
Clitoral gland | (47) | (48) | (45) | (48)
Hyperplasia | – | 4 (8%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | – | 1 (2%) | – | –
Ovary | (50) | (50) | (50) | (50)
Cyst | – | – | 1 (2%) | 1 (2%)
Bursa, dilatation | 5 (10%) | 11 (22%) | 17 (34%) | 24 (48%)
Follicle, cyst | – | – | 1 (2%) | –
Interstitial cell, hyperplasia | 1 (2%) | – | – | –
Periovarian tissue, cyst | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Vagina | (0) | (2) | (0) | (1)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia, reticulum cell | 1 (2%) | – | – | –
Lymph node | (2) | (2) | (4) | (9)
Deep cervical, hemorrhage | – | – | 1 (25%) | –
Deep cervical, hyperplasia, lymphoid | – | – | 1 (25%) | –
Lymph node, bronchial | (4) | (7) | (4) | (10)
Congestion | 1 (25%) | – | – | –
Hyperplasia, lymphoid | – | 1 (14%) | – | 1 (10%)
Infiltration cellular, histiocyte | – | – | – | 1 (10%)
Lymph node, mandibular | (2) | (0) | (1) | (4)
Lymph node, mediastinal | (33) | (26) | (29) | (38)
Ectasia | 1 (3%) | – | – | 1 (3%)
Hemorrhage | 1 (3%) | – | 1 (3%) | –
Hyperplasia, lymphoid | 1 (3%) | 1 (4%) | – | –
Hyperplasia, plasma cell | – | 1 (4%) | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | – | 1 (2%)
Inflammation, granulomatous | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Fibrosis | 2 (4%) | 1 (2%) | 2 (4%) | 4 (8%)
Hematopoietic cell proliferation | – | – | 2 (4%) | 1 (2%)
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation, granulomatous | – | 1 (2%) | – | –
Inflammation, acute | – | 1 (2%) | – | –
Necrosis | – | – | – | 3 (6%)
Thymus | (46) | (45) | (42) | (42)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 1 (2%) | 2 (4%) | 2 (4%) | –
Hyperplasia | 1 (2%) | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | – | –
Hyperkeratosis | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | – | – | 1 (2%) | –
Skeletal muscle | (1) | (2) | (3) | (0)
Fibrosis | – | – | 1 (33%) | –
Nervous System | | | | –
Brain | (50) | (50) | (50) | (50)
Hydrocephalus | – | 1 (2%) | – | –
Necrosis | – | – | – | 1 (2%)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Inflammation, chronic active | 2 (4%) | 2 (4%) | 1 (2%) | –
Metaplasia, squamous | 1 (2%) | 3 (6%) | – | –
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | –
Thrombosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 12 (24%) | 13 (26%) | 13 (26%) | 8 (16%)
Alveolar epithelium, metaplasia, squamous | 1 (2%) | – | 2 (4%) | 2 (4%)
Alveolus, infiltration cellular, histiocyte | – | – | 2 (4%) | 1 (2%)
Bronchiole, hyperplasia | – | 2 (4%) | 1 (2%) | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Foreign body | 2 (4%) | 4 (8%) | – | 5 (10%)
Inflammation, acute | 1 (2%) | – | – | –
Inflammation, chronic active | 7 (14%) | 45 (90%) | 46 (92%) | 46 (92%)
Polyp, inflammatory | – | – | – | 3 (6%)
Thrombosis | – | 3 (6%) | 2 (4%) | 7 (14%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | 50 (100%) | 50 (100%) | 50 (100%)
Olfactory epithelium, metaplasia, squamous | – | – | 1 (2%) | 1 (2%)
Respiratory epithelium, hyperplasia | 4 (8%) | 12 (24%) | 14 (28%) | 27 (54%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 3 (6%)
Turbinate, atrophy | – | 50 (100%) | 50 (100%) | 50 (100%)
Turbinate, hyperostosis | – | 50 (100%) | 50 (100%) | 50 (100%)
Pleura | (0) | (1) | (0) | (1)
Hyperplasia | – | – | – | 1 (100%)
Infiltration cellular, mononuclear cell | – | – | – | 1 (100%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (49) | (50) | (49)
Cataract | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Degeneration | 1 (2%) | 3 (6%) | 1 (2%) | –
Cornea, inflammation, chronic active | 1 (2%) | – | – | –
Retina, atrophy | 1 (2%) | 4 (8%) | 3 (6%) | 2 (4%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | – | –
Lacrimal gland | (0) | (0) | (1) | (1)
Cytoplasmic alteration | – | – | 1 (100%) | –
Degeneration | – | – | – | 1 (100%)
Zymbal’s gland | (0) | (0) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Fibrosis | – | 1 (2%) | – | –
Hydronephrosis | 1 (2%) | 1 (2%) | – | –
Hyperplasia, oncocytic | 1 (2%) | – | 1 (2%) | –
Infarct | 1 (2%) | 1 (2%) | – | 2 (4%)
Mineralization | – | 1 (2%) | – | –
Nephropathy | 45 (90%) | 40 (80%) | 43 (86%) | 42 (84%)
Papilla, necrosis | – | 1 (2%) | – | –
Renal tubule, hyperplasia | 1 (2%) | 2 (4%) | – | 2 (4%)
Renal tubule, necrosis | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.