# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of Vinylidene Chloride

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 21 | 15 | 23 | 27
Natural deaths | 4 | 8 | 5 | 4
Survivors
Terminal kill | 25 | 27 | 22 | 19
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | –
Intestine large, cecum | (48) | (44) | (45) | (46)
Intestine large, colon | (47) | (46) | (47) | (48)
Adenoma | – | – | – | 1 (2%)
Intestine large, rectum | (46) | (47) | (46) | (49)
Intestine small, duodenum | (47) | (45) | (45) | (49)
Intestine small, ileum | (47) | (45) | (45) | (47)
Intestine small, jejunum | (47) | (43) | (45) | (47)
Sarcoma, stromal | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, urinary bladder | – | 1 (2%) | – | –
Cholangiocarcinoma | – | – | – | 1 (2%)
Hepatocellular adenoma | 1 (2%) | 1 (2%) | – | –
Mesentery | (16) | (15) | (21) | (23)
Carcinoma, metastatic, urinary bladder | – | 1 (7%) | – | –
Pancreas | (50) | (50) | (50) | (49)
Carcinoma, metastatic, urinary bladder | – | 1 (2%) | – | –
Acinus, adenoma | – | – | 1 (2%) | –
Acinus, carcinoma | – | – | – | 1 (2%)
Duct, carcinoma | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (49) | (50) | (49) | (50)
Tongue | (0) | (1) | (0) | (2)
Squamous cell papilloma | – | 1 (100%) | – | –
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (1) | (0) | (1) | (0)
Heart | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Pericardium, osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (49) | (50)
Adenoma | 4 (8%) | 4 (8%) | 1 (2%) | –
Adrenal medulla | (49) | (50) | (48) | (50)
Pheochromocytoma benign | 5 (10%) | 9 (18%) | 5 (10%) | 7 (14%)
Pheochromocytoma malignant | 2 (4%) | 1 (2%) | – | 1 (2%)
Bilateral, pheochromocytoma benign | – | 2 (4%) | 3 (6%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (49)
Adenoma | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%)
Carcinoma | 2 (4%) | 2 (4%) | 4 (8%) | 4 (8%)
Parathyroid gland | (50) | (49) | (47) | (45)
Adenoma | – | – | 1 (2%) | –
Pituitary gland | (50) | (49) | (49) | (50)
Pars distalis, adenoma | 34 (68%) | 28 (57%) | 26 (53%) | 33 (66%)
Thyroid gland | (50) | (49) | (49) | (48)
C-cell, adenoma | 4 (8%) | 5 (10%) | 4 (8%) | 1 (2%)
C-cell, carcinoma | 3 (6%) | 3 (6%) | 3 (6%) | 3 (6%)
Follicular cell, carcinoma | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (2) | (4) | (3)
Osteosarcoma, metastatic, uncertain primary site | – | – | – | 1 (33%)
Tissue, NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (0) | (0) | (0) | (3)
Epididymis | (50) | (50) | (50) | (50)
Penis | (0) | (0) | (1) | (0)
Preputial gland | (50) | (49) | (49) | (50)
Adenoma | 2 (4%) | – | 2 (4%) | –
Carcinoma | 2 (4%) | 1 (2%) | 3 (6%) | –
Prostate | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Carcinoma, metastatic, urinary bladder | – | 1 (2%) | – | –
Seminal vesicle | (48) | (50) | (48) | (48)
Adenoma | – | – | 1 (2%) | 1 (2%)
Carcinoma, metastatic, urinary bladder | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Bilateral, interstitial cell, adenoma | 20 (40%) | 24 (48%) | 17 (34%) | 14 (28%)
Interstitial cell, adenoma | 12 (24%) | 11 (22%) | 22 (44%) | 11 (22%)
Hematopoietic System
Bone marrow | (49) | (49) | (48) | (49)
Lymph node | (6) | (4) | (9) | (7)
Lymph node, bronchial | (8) | (9) | (9) | (9)
Carcinoma, metastatic, thyroid gland | – | 1 (11%) | – | –
Osteosarcoma, metastatic, bone | 1 (13%) | – | – | –
Lymph node, mandibular | (1) | (1) | (1) | (0)
Lymph node, mediastinal | (28) | (21) | (24) | (30)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Thymus | (42) | (43) | (41) | (44)
Carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (36) | (29) | (24) | (32)
Carcinoma | – | – | 1 (4%) | –
Fibroadenoma | 1 (3%) | 1 (3%) | 1 (4%) | 2 (6%)
Skin | (50) | (50) | (49) | (50)
Basal cell, adenoma | 1 (2%) | – | – | 1 (2%)
Basal cell, carcinoma | 1 (2%) | – | – | –
Keratoacanthoma | 3 (6%) | 3 (6%) | 3 (6%) | 2 (4%)
Squamous cell papilloma | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%)
Trichoepithelioma | 1 (2%) | – | 2 (4%) | –
Subcutaneous tissue, fibroma | 1 (2%) | 4 (8%) | 2 (4%) | 3 (6%)
Subcutaneous tissue, fibroma, multiple | – | – | 1 (2%) | –
Subcutaneous tissue, fibrosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | – | – | – | 1 (2%)
Subcutaneous tissue, lipoma | – | – | – | 1 (2%)
Subcutaneous tissue, sarcoma | – | 2 (4%) | – | –
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteoma | 1 (2%) | – | – | –
Osteosarcoma | 1 (2%) | – | – | 1 (2%)
Skeletal muscle | (3) | (4) | (7) | (11)
Carcinoma, metastatic, urinary bladder | – | 1 (25%) | – | –
Lipoma | 1 (33%) | – | – | –
Osteosarcoma, metastatic, bone | 1 (33%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | – | – | 1 (2%) | –
Peripheral nerve | (2) | (0) | (1) | (0)
Spinal cord | (2) | (0) | (1) | (0)
Respiratory System
Larynx | (50) | (49) | (49) | (49)
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | 1 (2%) | –
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 1 (2%) | 3 (6%) | 3 (6%)
Alveolar/bronchiolar carcinoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Carcinoma, metastatic, kidney | – | – | 1 (2%) | 1 (2%)
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | 1 (2%) | –
Carcinoma, metastatic, urinary bladder | – | 1 (2%) | – | –
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Osteosarcoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Squamous cell carcinoma | – | 1 (2%) | – | –
Nose | (49) | (50) | (50) | (50)
Sarcoma | – | – | 1 (2%) | –
Respiratory epithelium, adenoma | – | – | 1 (2%) | 4 (8%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (50) | (49) | (49) | (48)
Carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | –
Special Senses System
Eye | (48) | (48) | (47) | (49)
Harderian gland | (50) | (49) | (48) | (49)
Zymbal’s gland | (0) | (1) | (0) | (0)
Carcinoma | – | 1 (100%) | – | –
Urinary System
Kidney | (50) | (50) | (49) | (50)
Mesenchymal tumor malignant | 1 (2%) | – | – | 1 (2%)
Renal tubule, carcinoma | – | 2 (4%) | 1 (2%) | 1 (2%)
Urinary bladder | (49) | (50) | (49) | (50)
Transitional epithelium, carcinoma | – | 2 (4%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 2 (4%) | 1 (2%) | –
Leukemia mononuclear | 17 (34%) | 17 (34%) | 16 (32%) | 20 (40%)
Mesothelioma malignant | 1 (2%) | 12 (24%) | 28 (56%) | 23 (46%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 50 | 50 | 49 | 49
Total primary neoplasms | 129 | 145 | 163 | 147
Total animals with benign neoplasms | 47 | 48 | 47 | 48
Total benign neoplasms | 99 | 97 | 101 | 88
Total animals with malignant neoplasms | 27 | 35 | 39 | 42
Total malignant neoplasms | 30 | 48 | 62 | 59
Total animals with metastatic neoplasms | 1 | 2 | 2 | 3
Total metastatic neoplasms | 4 | 10 | 6 | 5
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Adrenal Cortex: Adenoma
Overall rate^a^ | 4/49 (8%) | 4/50 (8%) | 1/49 (2%) | 0/50 (0%)
Adjusted rate^b^ | 9.6% | 9.9% | 2.6% | 0.0%
Terminal rate^c^ | 3/25 (12%) | 3/27 (11%) | 0/22 (0%) | 0/19 (0%)
First incidence (days) | 661 | 535 | 555 | –^e^
Poly-3 test^d^ | P = 0.026N | P = 0.629 | P = 0.207N | P = 0.072N
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 5/49 (10%) | 11/50 (22%) | 8/48 (17%) | 8/50 (16%)
Adjusted rate | 12.0% | 26.6% | 21.5% | 20.7%
Terminal rate | 2/25 (8%) | 7/27 (26%) | 4/21 (19%) | 5/19 (26%)
First incidence (days) | 654 | 466 | 642 | 628
Poly-3 test | P = 0.301 | P = 0.076 | P = 0.201 | P = 0.223
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 6/49 (12%) | 12/50 (24%) | 8/48 (17%) | 9/50 (18%)
Adjusted rate | 14.3% | 28.8% | 21.5% | 23.2%
Terminal rate | 2/25 (8%) | 7/27 (26%) | 4/21 (19%) | 6/19 (32%)
First incidence (days) | 654 | 466 | 642 | 628
Poly-3 test | P = 0.311 | P = 0.087 | P = 0.296 | P = 0.228
Kidney (Renal Tubule): Adenoma (Step Sections)
Overall rate | 3/50 (6%) | 3/50 (6%) | 5/49 (10%) | 1/50 (2%)
Adjusted rate | 7.2% | 7.4% | 13.1% | 2.6%
Terminal rate | 3/25 (12%) | 1/27 (4%) | 3/22 (14%) | 0/19 (0%)
First incidence (days) | 729 (T) | 631 | 502 | 718
Poly-3 test | P = 0.328N | P = 0.647 | P = 0.304 | P = 0.341N
Kidney (Renal Tubule): Adenoma or Carcinoma (Single and Step Sections)
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/49 (12%) | 2/50 (4%)
Adjusted rate | 7.2% | 9.8% | 15.7% | 5.3%
Terminal rate | 3/25 (12%) | 1/27 (4%) | 4/22 (18%) | 1/19 (5%)
First incidence (days) | 729 (T) | 631 | 502 | 718
Poly-3 test | P = 0.485N | P = 0.484 | P = 0.194 | P = 0.546N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 7.0% | 2.5% | 7.9% | 7.8%
Terminal rate | 1/25 (4%) | 1/27 (4%) | 2/22 (9%) | 2/19 (11%)
First incidence (days) | 614 | 729 (T) | 683 | 593
Poly-3 test | P = 0.413 | P = 0.330N | P = 0.606 | P = 0.612
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 7.0% | 5.0% | 10.6% | 10.4%
Terminal rate | 1/25 (4%) | 2/27 (7%) | 3/22 (14%) | 3/19 (16%)
First incidence (days) | 614 | 729 (T) | 683 | 593
Poly-3 test | P = 0.281 | P = 0.532N | P = 0.435 | P = 0.441
Nose: Adenoma
Overall rate | 0/49 (0%) | 0/50 (0%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 2.7% | 10.5%
Terminal rate | 0/25 (0%) | 0/27 (0%) | 1/22 (5%) | 3/19 (16%)
First incidence (days) | – | – | 729 (T) | 635
Poly-3 test | P = 0.004 | –^f^ | P = 0.483 | P = 0.051
Pancreatic Islets: Adenoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 4.7% | 5.0% | 8.0% | 2.7%
Terminal rate | 0/25 (0%) | 2/27 (7%) | 3/22 (14%) | 1/19 (5%)
First incidence (days) | 676 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.455N | P = 0.674 | P = 0.449 | P = 0.541N
Pancreatic Islets: Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 4/49 (8%)
Adjusted rate | 4.8% | 5.0% | 10.6% | 10.6%
Terminal rate | 2/25 (8%) | 1/27 (4%) | 3/22 (14%) | 1/19 (5%)
First incidence (days) | 729 (T) | 723 | 683 | 676
Poly-3 test | P = 0.170 | P = 0.677 | P = 0.290 | P = 0.290
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate | 9.5% | 10.0% | 18.5% | 13.2%
Terminal rate | 2/25 (8%) | 3/27 (11%) | 6/22 (27%) | 2/19 (11%)
First incidence (days) | 676 | 723 | 683 | 676
Poly-3 test | P = 0.298 | P = 0.613 | P = 0.199 | P = 0.432
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 34/50 (68%) | 28/49 (57%) | 26/49 (53%) | 33/50 (66%)
Adjusted rate | 73.5% | 64.5% | 63.9% | 74.4%
Terminal rate | 17/25 (68%) | 16/27 (59%) | 16/21 (76%) | 15/19 (79%)
First incidence (days) | 562 | 548 | 418 | 437
Poly-3 test | P = 0.429 | P = 0.235N | P = 0.217N | P = 0.561
Preputial Gland: Carcinoma
Overall rate | 2/50 (4%) | 1/49 (2%) | 3/49 (6%) | 0/50 (0%)
Adjusted rate | 4.6% | 2.6% | 7.9% | 0.0%
Terminal rate | 0/25 (0%) | 0/26 (0%) | 1/22 (5%) | 0/19 (0%)
First incidence (days) | 492 | 694 | 555 | –
Poly-3 test | P = 0.281N | P = 0.536N | P = 0.443 | P = 0.268N
Preputial Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 1/49 (2%) | 5/49 (10%) | 0/50 (0%)
Adjusted rate | 9.3% | 2.6% | 13.1% | 0.0%
Terminal rate | 2/25 (8%) | 0/26 (0%) | 3/22 (14%) | 0/19 (0%)
First incidence (days) | 492 | 694 | 555 | –
Poly-3 test | P = 0.141N | P = 0.211N | P = 0.422 | P = 0.078N
Skin: Squamous Cell Papilloma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 7.2% | 2.5% | 2.7% | 2.6%
Terminal rate | 3/25 (12%) | 1/27 (4%) | 0/22 (0%) | 1/19 (5%)
First incidence (days) | 729 (T) | 729 (T) | 705 | 729 (T)
Poly-3 test | P = 0.258N | P = 0.323N | P = 0.343N | P = 0.342N
Skin: Keratoacanthoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 7.1% | 7.4% | 7.9% | 5.2%
Terminal rate | 1/25 (4%) | 2/27 (7%) | 2/22 (9%) | 0/19 (0%)
First incidence (days) | 675 | 492 | 574 | 535
Poly-3 test | P = 0.441N | P = 0.645 | P = 0.617 | P = 0.541N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 6/50 (12%) | 4/50 (8%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 14.2% | 9.9% | 10.4% | 7.8%
Terminal rate | 4/25 (16%) | 3/27 (11%) | 2/22 (9%) | 1/19 (5%)
First incidence (days) | 675 | 492 | 574 | 535
Poly-3 test | P = 0.244N | P = 0.394N | P = 0.431N | P = 0.286N
Skin: Trichoepithelioma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 7.1% | 0.0% | 5.3% | 2.6%
Terminal rate | 1/25 (4%) | 0/27 (0%) | 1/22 (5%) | 1/19 (5%)
First incidence (days) | 661 | – | 637 | 729 (T)
Poly-3 test | P = 0.356N | P = 0.129N | P = 0.548N | P = 0.345N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Trichoepithelioma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 9/50 (18%) | 4/50 (8%) | 6/50 (12%) | 4/50 (8%
Adjusted rate | 21.2% | 9.9% | 15.5% | 10.4%
Terminal rate | 5/25 (20%) | 3/27 (11%) | 3/22 (14%) | 2/19 (11%)
First incidence (days) | 661 | 492 | 574 | 535
Poly-3 test | P = 0.169N | P = 0.131N | P = 0.357N | P = 0.152N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 1/50 (2%) | 4/50 (8%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 2.4% | 10.0% | 7.9% | 7.9%
Terminal rate | 0/25 (0%) | 4/27 (15%) | 2/22 (9%) | 3/19 (16%)
First incidence (days) | 679 | 729 (T) | 705 | 729 (T)
Poly-3 test | P = 0.293 | P = 0.161 | P = 0.267 | P = 0.267
Skin (Subcutaneous Tissue): Fibroma, Fibrous Histiocytoma, Fibrosarcoma, or Sarcoma
Overall rate | 1/50 (2%) | 6/50 (12%) | 3/50 (6%) | 5/50 (10%)
Adjusted rate | 2.4% | 14.6% | 7.9% | 13.1%
Terminal rate | 0/25 (0%) | 4/27 (15%) | 2/22 (9%) | 4/19 (21%)
First incidence (days) | 679 | 294 | 705 | 617
Poly-3 test | P = 0.143 | P = 0.051 | P = 0.267 | P = 0.079
Testes: Adenoma
Overall rate | 32/50 (64%) | 35/50 (70%) | 39/50 (78%) | 25/50 (50%)
Adjusted rate | 70.8% | 80.5% | 87.9% | 58.8%
Terminal rate | 21/25 (84%) | 24/27 (89%) | 21/22 (96%) | 11/19 (58%)
First incidence (days) | 551 | 535 | 500 | 449
Poly-3 test | P = 0.072N | P = 0.186 | P = 0.026 | P = 0.155N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 4/50 (8%) | 5/49 (10%) | 4/49 (8%) | 1/48 (2%)
Adjusted rate | 9.4% | 12.5% | 10.9% | 2.7%
Terminal rate | 3/25 (12%) | 3/27 (11%) | 4/21 (19%) | 1/19 (5%)
First incidence (days) | 591 | 611 | 729 (T) | 729 (T)
Poly-3 test | P = 0.152N | P = 0.462 | P = 0.563 | P = 0.219N
Thyroid Gland (C-Cell): Carcinoma
Overall rate | 3/50 (6%) | 3/49 (6%) | 3/49 (6%) | 3/48 (6%)
Adjusted rate | 7.2% | 7.6% | 8.0% | 8.0%
Terminal rate | 2/25 (8%) | 2/27 (7%) | 1/21 (5%) | 1/19 (5%)
First incidence (days) | 717 | 563 | 586 | 635
Poly-3 test | P = 0.523 | P = 0.638 | P = 0.609 | P = 0.613
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 8/49 (16%) | 6/49 (12%) | 4/48 (8%)
Adjusted rate | 16.5% | 19.8% | 16.0% | 10.6%
Terminal rate | 5/25 (20%) | 5/27 (19%) | 4/21 (19%) | 2/19 (11%)
First incidence (days) | 591 | 563 | 586 | 635
Poly-3 test | P = 0.227N | P = 0.459 | P = 0.597N | P = 0.330N
All Organs: Mononuclear Cell Leukemia
Overall rate | 17/50 (34%) | 17/50 (34%) | 16/50 (32%) | 20/50 (40%)
Adjusted rate | 38.1% | 39.8% | 38.9% | 46.5%
Terminal rate | 8/25 (32%) | 9/27 (33%) | 6/22 (27%) | 7/19 (37%)
First incidence (days) | 551 | 560 | 563 | 437
Poly-3 test | P = 0.237 | P = 0.522 | P = 0.560 | P = 0.278
All Organs: Malignant Mesothelioma
Overall rate | 1/50 (2%) | 12/50 (24%) | 28/50 (56%) | 23/50 (46%)
Adjusted rate | 2.4% | 27.9% | 63.4% | 52.7%
Terminal rate | 0/25 (0%) | 5/27 (19%) | 10/22 (46%) | 7/19 (37%)
First incidence (days) | 562 | 535 | 500 | 449
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
All Organs: Benign Neoplasms
Overall rate | 47/50 (94%) | 48/50 (96%) | 47/50 (94%) | 48/50 (96%)
Adjusted rate | 98.4% | 99.6% | 98.2% | 99.2%
Terminal rate | 25/25 (100%) | 27/27 (100%) | 22/22 (100%) | 19/19 (100%)
First incidence (days) | 551 | 466 | 418 | 437
Poly-3 test | P = 0.685 | P = 0.780 | P = 0.890N | P = 0.831
All Organs: Malignant Neoplasms
Overall rate | 27/50 (54%) | 35/50 (70%) | 39/50 (78%) | 42/50 (84%)
Adjusted rate | 56.6% | 73.2% | 83.9% | 89.1%
Terminal rate | 11/25 (44%) | 16/27 (59%) | 16/22 (73%) | 17/19 (90%)
First incidence (days) | 367 | 294 | 500 | 437
Poly-3 test | P < 0.001 | P = 0.064 | P = 0.002 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 50/50 (100%) | 50/50 (100%) | 49/50 (98%) | 49/50 (98%)
Adjusted rate | 100.0% | 100.0% | 99.9% | 100.0%
Terminal rate | 25/25 (100%) | 27/27 (100%) | 22/22 (100%) | 19/19 (100%)
First incidence (days) | 367 | 294 | 418 | 437
Poly-3 test | P = 1.000 | – | P = 1.000 | P = 1.000

T = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, kidney, lung, nose, pancreatic islets, pituitary gland, preputial gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Malignant Mesothelioma in Control Male F344/N Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 0/50
Diethylamine (August 2003) | 0/50
Tetralin (June 2003) | 0/50
Vinylidene chloride (June 2005) | 1/50
Total (%) | 1/200 (0.5%)
Mean ± standard deviation | 0.5% ± 1.0%
Range | 0%–2%
Overall Historical Incidence: All Routes
Total (%) | 26/699 (3.7)
Mean ± standard deviation | 3.7% ± 3.1%
Range | 0%–8%

^a^ Data as of June 2013.

Table A-4 Historical Incidence of Renal Tubule Neoplasms in Control Male F344/N Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 1/50 | 0/50 | 1/50
Diethylamine (August 2003) | 0/50 | 0/50 | 0/50
Tetralin (June 2003) | 0/50 | 0/50 | 0/50
Vinylidene chloride (June 2005) | 0/50 | 0/50 | 0/50
Total (%) | 1/200 (0.5%) | 0/200 | 1/200 (0.5%)
Mean ± standard deviation | 0.5% ± 1.0% | – | 0.5% ± 1.0%
Range | 0%-2% | – | 0%-2%
Overall Historical Incidence: All Routes
Total (%) | 4/697 (0.6%) | 1/697 (0.1%) | 5/697 (0.7%)
Mean ± standard deviation | 0.6% ± 0.9% | 0.1% ± 0.5% | 0.7% ± 1.3%
Range | 0%-2% | 0%-2% | 0%-4%

^a^ Data as of June 2013.

Table A-5 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 21 | 15 | 23 | 27
Natural deaths | 4 | 8 | 5 | 4
Survivors
Terminal kill | 25 | 27 | 22 | 19
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Hyperplasia, squamous | – | – | – | 1 (2%)
Intestine large, cecum | (48) | (44) | (45) | (46)
Inflammation, acute | 1 (2%) | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | –
Arteriole, inflammation | – | – | 1 (2%) | –
Intestine large, colon | (47) | (46) | (47) | (48)
Arteriole, inflammation | – | – | 1 (2%) | –
Intestine large, rectum | (46) | (47) | (46) | (49)
Thrombosis | – | – | 1 (2%) | –
Intestine small, duodenum | (47) | (45) | (45) | (49)
Intestine small, ileum | (47) | (45) | (45) | (47)
Intestine small, jejunum | (47) | (43) | (45) | (47)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 2 (4%) | – | –
Basophilic focus | 15 (30%) | 7 (14%) | 5 (10%) | 5 (10%)
Clear cell focus | 22 (44%) | 23 (46%) | 19 (38%) | 15 (30%)
Cyst | – | – | 1 (2%) | –
Degeneration, cystic | 2 (4%) | 5 (10%) | 7 (14%) | 12 (24%)
Eosinophilic focus | 3 (6%) | 6 (12%) | 7 (14%) | 5 (10%)
Fatty change, diffuse | 4 (8%) | 19 (38%) | 18 (36%) | 26 (52%)
Hepatodiaphragmatic nodule | 1 (2%) | 1 (2%) | 1 (2%) | 5 (10%)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic | 28 (56%) | 46 (92%) | 46 (92%) | 44 (88%)
Inflammation, chronic active | 1 (2%) | – | – | –
Mixed cell focus | 1 (2%) | 1 (2%) | 8 (16%) | 6 (12%)
Necrosis | 2 (4%) | 6 (12%) | 8 (16%) | 6 (12%)
Bile duct, hyperplasia | 38 (76%) | 23 (46%) | 16 (32%) | 14 (28%)
Bile duct, inflammation, suppurative | – | – | 1 (2%) | –
Mesentery | (16) | (15) | (21) | (23)
Inflammation, chronic active | 2 (13%) | – | 1 (5%) | –
Fat, necrosis | 13 (81%) | 10 (67%) | 14 (67%) | 12 (52%)
Pancreas | (50) | (50) | (50) | (49)
Atrophy | 21 (42%) | 16 (32%) | 25 (50%) | 20 (41%)
Basophilic focus | 1 (2%) | – | – | –
Hyperplasia | 4 (8%) | 5 (10%) | 2 (4%) | 7 (14%)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | – | –
Mineralization | 1 (2%) | – | – | –
Ulcer | 4 (8%) | 3 (6%) | 1 (2%) | 6 (12%)
Stomach, glandular | (49) | (50) | (49) | (50)
Mineralization | 1 (2%) | – | 1 (2%) | –
Necrosis | – | – | 3 (6%) | 3 (6%)
Ulcer | – | – | 1 (2%) | 1 (2%)
Tongue | (0) | (1) | (0) | (2)
Hyperplasia, squamous | – | – | – | 2 (100%)
Tooth | (1) | (0) | (0) | (0)
Dysplasia | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (1) | (0) | (1) | (0)
Aorta, mineralization | 1 (100%) | – | 1 (100%) | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 42 (84%) | 41 (82%) | 39 (78%) | 35 (70%)
Inflammation, chronic active | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | –
Thrombosis | 3 (6%) | 3 (6%) | 6 (12%) | 8 (16%)
Endocrine System
Adrenal cortex | (49) | (50) | (49) | (50)
Hyperplasia | 26 (53%) | 27 (54%) | 27 (55%) | 27 (54%)
Hypertrophy | 1 (2%) | 2 (4%) | 2 (4%) | 4 (8%)
Necrosis | – | 2 (4%) | – | –
Adrenal medulla | (49) | (50) | (48) | (50)
Hyperplasia | 25 (51%) | 22 (44%) | 17 (35%) | 29 (58%)
Bilateral, hyperplasia | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (49)
Hyperplasia | 1 (2%) | 3 (6%) | 3 (6%) | 3 (6%)
Parathyroid gland | (50) | (49) | (47) | (45)
Hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Pituitary gland | (50) | (49) | (49) | (50)
Angiectasis | – | – | – | 1 (2%)
Pars distalis, angiectasis | 2 (4%) | – | – | 1 (2%)
Pars distalis, hemorrhage | – | 1 (2%) | – | –
Pars distalis, hyperplasia | 10 (20%) | 13 (27%) | 14 (29%) | 9 (18%)
Pars intermedia, angiectasis | 1 (2%) | – | – | –
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (49) | (48)
C-cell, hyperplasia | 15 (30%) | 16 (33%) | 19 (39%) | 19 (40%)
Follicular cell, hyperplasia | 2 (4%) | – | 2 (4%) | 1 (2%)
General Body System
Peritoneum | (0) | (2) | (4) | (3)
Mesothelium, hyperplasia | – | 1 (50%) | – | –
Tissue, NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (0) | (0) | (0) | (3)
Hyperplasia | – | – | – | 2 (67%)
Inflammation, suppurative | – | – | – | 1 (33%)
Epididymis | (50) | (50) | (50) | (50)
Degeneration | – | – | – | 1 (2%)
Granuloma sperm | – | 1 (2%) | – | –
Hyperplasia, mesothelium | – | 3 (6%) | 1 (2%) | –
Penis | (0) | (0) | (1) | (0)
Inflammation, suppurative | – | – | 1 (100%) | –
Preputial gland | (50) | (49) | (49) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | – | –
Prostate | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 4 (8%) | 7 (14%) | 5 (10%)
Inflammation, suppurative | 4 (8%) | 5 (10%) | 9 (18%) | 8 (16%)
Seminal vesicle | (48) | (50) | (48) | (48)
Hyperplasia | – | – | 1 (2%) | –
Testes | (50) | (50) | (50) | (50)
Atrophy | 9 (18%) | 10 (20%) | 13 (26%) | 4 (8%)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Hyperplasia, mesothelium | – | 2 (4%) | – | –
Arteriole, inflammation | – | 1 (2%) | 1 (2%) | –
Interstitial cell, hyperplasia | 4 (8%) | 4 (8%) | 6 (12%) | 3 (6%)
Tunic, hyperplasia | – | 2 (4%) | 2 (4%) | 2 (4%)
Hematopoietic System
Bone marrow | (49) | (49) | (48) | (49)
Hyperplasia, reticulum cell | 1 (2%) | – | – | –
Lymph node | (6) | (4) | (9) | (7)
Pancreatic, congestion | – | – | 1 (11%) | –
Pancreatic, hyperplasia, lymphoid | 1 (17%) | – | – | 1 (14%)
Pancreatic, infiltration cellular, histiocyte | – | – | – | –
Lymph node, bronchial | (8) | (9) | (9) | (9)
Congestion | – | – | 1 (11%) | –
Ectasia | – | 1 (11%) | 2 (22%) | –
Hyperplasia, lymphoid | 1 (13%) | – | – | –
Infiltration cellular, histocyte | – | – | – | 1 (11%)
Lymph node, mandibular | (1) | (1) | (1) | (0)
Lymph node, mediastinal | (28) | (21) | (24) | (30)
Congestion | – | – | 1 (4%) | –
Ectasia | 1 (4%) | – | – | –
Hyperplasia, lymphoid | 2 (7%) | – | 2 (8%) | 2 (7%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Congestion | – | – | 1 (2%) | –
Ectasia | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation, granulomatous | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Fibrosis | 3 (6%) | – | 2 (4%) | 4 (8%)
Hematopoietic cell proliferation | 3 (6%) | 1 (2%) | 1 (2%) | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Hyperplasia, stromal | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | 2 (4%) | 2 (4%)
Capsule, hyperplasia | – | – | 1 (2%) | –
Thymus | (42) | (43) | (41) | (44)
Infiltration cellular, polymorphonuclear | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (36) | (29) | (24) | (32)
Hyperplasia | – | 1 (3%) | – | –
Skin | (50) | (50) | (49) | (50)
Cyst epithelial inclusion | 4 (8%) | 2 (4%) | 2 (4%) | –
Hyperkeratosis | – | 1 (2%) | – | –
Hyperplasia, squamous | 1 (2%) | – | – | –
Inflammation, acute | – | – | 1 (2%) | –
Inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (3) | (4) | (7) | (11)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | – | – | –
Peripheral nerve | (2) | (0) | (1) | (0)
Spinal cord | (2) | (0) | (1) | (0)
Respiratory System
Larynx | (50) | (49) | (49) | (49)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Metaplasia, squamous | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | – | –
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Metaplasia, osseous | – | – | – | 1 (2%)
Mineralization | 1 (2%) | – | 1 (2%) | –
Thrombosis | 1 (2%) | 1 (2%) | 2 (4%) | –
Alveolar epithelium, hyperplasia | 7 (14%) | 18 (36%) | 14 (28%) | 14 (28%)
Alveolar epithelium, metaplasia, squamous | – | – | 1 (2%) | –
Alveolar epithelium, metaplasia, mucous | – | – | 1 (2%) | –
Mediastinum, inflammation, granulomatous | – | – | – | –
Nose | (49) | (50) | (50) | (50)
Foreign body | 2 (4%) | 2 (4%) | 2 (4%) | 5 (10%)
Hyperplasia | – | – | – | 1 (2%)
Inflammation, acute | 2 (4%) | – | – | –
Inflammation, chronic active | 9 (18%) | 36 (72%) | 45 (90%) | 48 (96%)
Thrombosis | 4 (8%) | 4 (8%) | 11 (22%) | 7 (14%)
Olfactory epithelium, metaplasia, respiratory | 3 (6%) | 49 (98%) | 49 (98%) | 48 (96%)
Olfactory epithelium, metaplasia, squamous | – | – | 1 (2%) | 5 (10%)
Respiratory epithelium, hyperplasia | 5 (10%) | 8 (16%) | 22 (44%) | 31 (62%)
Respiratory epithelium, metaplasia, squamous | – | – | 1 (2%) | 3 (6%)
Turbinate, atrophy | – | 50 (100%) | 50 (100%) | 50 (100%)
Turbinate, hyperostosis | – | 49 (98%) | 50 (100%) | 50 (100%)
Pleura | (0) | (1) | (0) | (1)
Hyperplasia | – | – | – | 1 (100%)
Infiltration cellular, mononuclear cell | – | – | – | 1 (100%)
Trachea | (50) | (49) | (49) | (48)
Special Senses System
Eye | (48) | (48) | (47) | (49)
Cataract | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%)
Degeneration | – | 1 (2%) | – | 1 (2%)
Cornea, inflammation, acute | 1 (2%) | 1 (2%) | – | –
Cornea, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Retina, atrophy | 2 (4%) | – | 1 (2%) | 1 (2%)
Harderian gland | (50) | (49) | (48) | (49)
Degeneration | – | – | – | 1 (2%)
Hyperplasia | – | 2 (4%) | 1 (2%) | –
Zymbal’s gland | (0) | (1) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (49) | (50)
Cyst | – | 1 (2%) | – | –
Hydronephrosis | – | 1 (2%) | – | –
Infarct | – | – | 1 (2%) | 2 (4%)
Inflammation, suppurative | – | 2 (4%) | 1 (2%) | 2 (4%)
Mineralization | 1 (2%) | – | – | –
Nephropathy | 50 (100%) | 47 (94%) | 47 (96%) | 47 (94%)
Thrombosis | – | 1 (2%) | – | –
Renal tubule, hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%)
Renal tubule, necrosis | – | – | 2 (4%) | –
Transitional epithelium, hyperplasia | – | – | 1 (2%) | 2 (4%)
Urinary bladder | (49) | (50) | (49) | (50)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Transitional epithelium, hyperplasia | – | – | 1 (2%) | 2 (4%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.