# Errata

Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Descriptions of cobalt exposure concentrations in the report were unclear regarding the form of cobalt used for the calculations.

In the Introduction on pages 4, 6, 7, and 8, and in the Discussion on page 113, the text was revised to clarify the form of cobalt used to calculate the exposure concentrations. The text on page 6 was also revised to clarify the effects on specific study animals. Text on pages 6 and 7 was revised to accurately reflect the study durations of chronic studies. This information was added to the HTML and PDF versions of this report. [July 3, 2023]

The cobalt sulfate heptahydrate nomenclature corrections are part of a broader issue affecting multiple peer-reviewed publications and NTP reports, as described below.

In the late 1980s and early 1990s, the National Toxicology Program (NTP) commissioned Battelle Pacific Northwest Laboratories to design and carry out prechronic (16- and 90-day) and chronic (2-year) inhalation toxicology and carcinogenicity studies with cobalt sulfate heptahydrate.^1-4^ The chemical, procured in one lot for all NTP studies, was crystalline cobalt sulfate heptahydrate, with a purity of approximately 99%.

The test material was aerosolized from an aqueous solution via compressed air nebulizer and dried prior to distribution to the exposure chambers. It was noted that generation of the aerosol from an aqueous solution, followed by drying, produced cobalt sulfate aerosol particles with fewer waters of hydration than the bulk chemical. The extent of hydration of the exposure atmosphere was evaluated in each study, with a more extensive analysis prior to the chronic study, when it was confirmed that the exposure chamber atmosphere consisted of the hexahydrate form.

Chamber aerosol concentrations were determined using real-time aerosol monitors and calibrated using filter grab samples collected from the chambers. The conversion of analyzed filter cobalt concentrations to chamber concentrations was based on the molecular weight ratio of cobalt sulfate:cobalt (155.00:58.993). Thus, in the prechronic and chronic studies, the units for the exposure concentrations were mg cobalt sulfate/m^3^ air. The basis for the exposure concentrations (i.e., as mg cobalt sulfate/m^3^) was presented in the laboratory report describing the inhalation exposure system and atmosphere as well as in the methods sections of the publications on the prechronic studies.^1,3^ However, when preparing Appendix F of NTP Technical Report 471 for the chronic studies, the detailed description of the expression of exposure concentrations was not included. Therefore, the identification of the test material as cobalt sulfate heptahydrate or the description of the primary species delivered to the chambers as cobalt sulfate hexahydrate may lead the reader to conclude that the exposure concentrations were based on the heptahydrate or hexahydrate form, respectively. This may further lead a reader to conclude that the chamber concentrations were based on a hydrated form of the chemical, which would underestimate the amount of cobalt in the atmosphere. The subsequent manuscript^4^ explicitly stated that the exposure concentrations were based on the hexahydrate form, and an erratum was issued to correct this error.

A study of cobalt metal was also conducted as part of the NTP cobalt research program.^5^ A comparison of the chronic toxicity and carcinogenicity findings in the two NTP cobalt studies (i.e., cobalt sulfate heptahydrate and cobalt metal) is presented in Behl et al. 2015.^6^ The exposure metric used for this comparison was mg cobalt/m^3^. The exposure concentrations in the cobalt sulfate heptahydrate study were calculated by multiplying the reported concentrations of cobalt sulfate by the molecular weight ratio of cobalt:cobalt sulfate (58.993:155.00). This calculation produced cobalt concentrations of 0.114, 0.38, and 1.14 mg cobalt/mg^3^ in the 0.3, 1.0, and 3.0 mg cobalt sulfate/m^3^ groups, respectively, as reported in Behl et al. 2015.^6^

References

1. National Toxicology Program (NTP). Toxicity studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1991. Toxicity Study Report Series No. 5. NIH Publication No. 91-3124. https://ntp.niehs.nih.gov/go/tox05abs

2. National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 471. NIH Publication No. 98-3961. https://ntp.niehs.nih.gov/go/tr471abs

3. Bucher JR, Elwell MR, Thompson MB, Chou BJ, Renne R, Ragan HA. Inhalation toxicity studies of cobalt sulfate in F344/N rats and B6C3F1 mice. Fundam Appl Toxicol. 1990; 15(2):357–372 http://dx.doi.org/10.1016/0272-0590(90)90061-N

4. Bucher JR, Hailey JR, Roycroft JR, Haseman JK, Sills RC, Grumbein SL, Mellick PW, Chou BJ. Inhalation toxicity and carcinogenicity studies of cobalt sulfate. Toxicol Sci. 1999; 49(1):56–67 http://dx.doi.org/10.1093/toxsci/49.1.56

5. National Toxicology Program (NTP). Toxicology studies of cobalt metal (CASRN 7440-48-4) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of cobalt metal in F344/NTac rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2014. Technical Report Series No. 581. https://doi.org/10.22427/NTP-TR-581

6. Behl M, Stout MD, Herbert RA, Dill JA, Baker GL, Hayden BK, Roycroft JH, Bucher JR, Hooth MJ. Comparative toxicity and carcinogenicity of soluble and insoluble cobalt compounds. Toxicology. 2015; 333:195–205. http://dx.doi.org/10.1016/j.tox.2015.04.008