# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology Studies of Cobalt Metal (CASRN 7440-48-4) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of Cobalt Metal in F344/NTAC Rats and B6C3F1/N Mice (Inhalation Studies) on October 29, 2013, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- John Cullen, V.M.D., Ph.D., Chairperson
  College of Veterinary Medicine
  North Carolina State University
  Raleigh, North Carolina
- Norman J. Barlow, M.B.A., M.L.D., D.V.M., Ph.D.
  Sanofi
  Boston, Massachusetts
- Russell C. Cattley, V.M.D., Ph.D.
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama
- Deborah Cory-Slechta, Ph.D., Primary Reviewer
  University of Rochester School of Medicine and Dentistry
  Rochester, New York
- Terry Gordon, Ph.D., Primary Reviewer
  New York University Langone Medical Center
  New York, New York
- Joel Parker, Ph.D.
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina
- Karen Regan, D.V.M., Primary Reviewer
  Regan Pathology/Toxicology Services, Inc.
  Ashland, Ohio
- Timothy Zacharewski, Ph.D., Primary Reviewer
  Michigan State University
  East Lansing, Michigan