# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M. Behl, Ph.D., Co-Study Scientist
  M.J. Hooth, Ph.D., Co-Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D., Experimental Pathology Laboratories, Inc.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  B.K. Hayden
  R.A. Renne, D.V.M.
  L.M. Staska, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  A.E. Brix, D.V.M., Ph.D.
  M.M. Gruebbel, D.V.M., Ph.D.
  R.A. Miller, D.V.M., Ph.D.
  R. Moore, D.V.M.
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  D.K. Giri, D.V.M., Ph.D, Coordinated 2-year rats (March 29, 2011)
  G.D. Hill, D.V.M., Ph.D, Coordinated 2-year mice (March 3, 2011)
- Gene Logic Laboratories, Inc.
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.