# References

1 International Agency for Research on Cancer (IARC). Chlorinated drinking-water; chlorination by-products; some other halogenated compounds; cobalt and cobalt compounds. IARC Monogr Eval Carcinog Risks Hum. Lyon, France: IARC; 1991. p. 363–472.
2 Donaldson JD, Beyersmann D. Cobalt and cobalt compounds. In: Ullmann's Encyclopedia of Industrial Chemistry. New York: Wiley-VCH; 2005. 10.1002/14356007.a07_281.pub2
3 The Merck Index. 14th ed. O’Neil MJ, editor. Whitehouse Station, NJ: Merck & Co. Inc; 2006. p. 408–409.
4 Om Group Inc (OMGI). Cobalt powder product descriptions. 2013. https://web.archive.org/web/20101220042624/http://www.omgi.com/product-am-powderspm.html [Accessed: March 2013]
5 Smith IC, Carson BL. Cobalt. In: Trace Metals in the Environment. Vol. 6. Ann Arbor, MI: Ann Arbor Science Publishers; 1981.
6 Donaldson JD. Cobalt and cobalt compounds. In: Gerhartz W, Yamamoto YS, Campbell FT, Pffeferkorn R, Rounsaville JF, editors. Ullman’s Encyclopedia of Industrial Chemistry. 5th ed. New York: VCH; 1986. p. 281–313.
7 Hodge FG. Cobalt and cobalt alloys. In: Kroschwitz JI, Howe-Grant M, editors. Kirk-Othmer Encyclopedia of Chemical Technology. New York: John Wiley & Sons; 1993. p. 760–777.
8 United States Geological Survey (USGS). 2002. https://minerals.usgs.gov/minerals/pubs/commodity/cobalt/cobalmyb02.pdf [Accessed: August 2013]
9 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for cobalt. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2004.
10 Cobalt Development Institute (CDI). 2013. https://web.archive.org/web/20200210043406/https://www.cobaltinstitute.org/ [Accessed August 2013]
11 Burstow C. Cobalt: The changing emphasis: Supply, demand and price outlook for the cobalt market. Proceedings of the Cobalt Conference; May 24-25 2000; Tokyo, Japan. Cobalt Development Institute, United Kingdom.
12 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR Records by chemical, including manufacturing, processing and use information. 2010. https://www.epa.gov/chemical-data-reporting/access-cdr-data#2006 [Accessed: August 2013]
13 United States Environmental Protection Agency (USEPA). Chemical Data Access Tool (CDAT): 2012 Chemical Data Reporting. 2013. https://web.archive.org/web/20110808061510/https://java.epa.gov/oppt_chemical_search/ [Accessed: April 2013]
14 Sibley SF. Cobalt. Mineral Facts and Problems. 1975 Edition. Washington, DC: Bureau of Mines; 1975. p. 269–280.
15 Shedd KB. Cobalt. In: Mineral Commodity Summaries. U.S. Geological Survey; 2013. [cited 2013 Aug]. p. 46–47. https://s3-us-west-2.amazonaws.com/prd-wret/assets/palladium/production/mineral-pubs/mcs/mcs2013.pdf.
16 Institute of Medicine (IOM). Dietary reference intakes for thiamine, riboflavin, niacin, vitamin B6, folate, vitamin B12, pantothenic acid, biotin and choline. National Academy Press, Washington, DC: Committee on the Scientific Evaluation of Dietary Reference Intakes, Food and Nutrition Board, Institute of Medicine; 1998. https://www.nap.edu/books/0309065542/html/index.html [Accessed: March 11, 2013]
17 Domingo JL. Cobalt in the environment and its toxicological implications. Rev Environ Contam Toxicol. 1989; 108:105–132. 10.1007/978-1-4613-8850-0_3 2646660
18 Reuber S, Kreuzer M, Kirchgessner M. Interactions of cobalt and iron in absorption and retention. J Trace Elem Electrolytes Health Dis. 1994; 8:151–158. 7599505
19 Schade SG, Felsher BF, Bernier GM, Conrad ME. Interrelationship of cobalt and iron absorption. J Lab Clin Med. 1970; 75(3):435–441. 4906743
20 Code of Federal Regulations (CFR). 40:§141.140.
21 Code of Federal Regulations (CFR). 40:Part 258.
22 Code of Federal Regulations (CFR). 40:Part 264.
23 Code of Federal Regulations (CFR). 40:§372.365.
24 American Conference of Governmental Industrial Hygienists (ACGIH). TLVs and BEIs based on the documentation of the threshold limit values for chemical substances and physical agents and biological exposure indices. Cincinnati, OH: ACGIH; 2013. p. 21.
25 Occupational Safety and Health Administration (OSHA). Shipyards, cobalt metal, dust, and fume. 2001. https://www.osha.gov/pls/oshaweb/owadisp.show_document?p_table=STANDARDS&p_id=10286 [Accessed: March 2013]
26 Registry of Toxic Effects of Chemical Substances (RTECS). Bethesda, MD: National Institute for Occupational Safety and Health, National Library of Medicine; 1991.
27 Nemery B, Casier P, Roosels D, Lahaye D, Demedts M. Survey of cobalt exposure and respiratory health in diamond polishers. Am Rev Respir Dis. 1992; 145(3):610–616. 10.1164/ajrccm/145.3.610 1312313
28 Barnes JE, Kanapilly GM, Newton GJ. Cobalt-60 oxide aerosols: Methods of production and short-term retention and distribution kinetics in the beagle dog. Health Phys. 1976; 30(5):391–398. 10.1097/00004032-197605000-00003 1270267
29 Brune D, Kjaerheim A, Paulsen G, Beltesbrekke H. Pulmonary deposition following inhalation of chromium-cobalt grinding dust in rats and distribution in other tissues. Scand J Dent Res. 1980; 88(6):543–551. 10.1111/j.1600-0722.1980.tb01265.x 6941368
30 Collier CG, Bailey MR, Hodgson A. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part V: Lung clearance of inhaled cobalt oxide particles in hamsters, rats and guinea-pigs. J Aerosol Sci. 1989; 20(2):233–247. 10.1016/0021-8502(89)90046-3
31 Kerfoot EJ, Fredrick WG, Domeier E. Cobalt metal inhalation studies on miniature swine. Am Ind Hyg Assoc J. 1975; 36(1):17–25. 10.1080/0002889758507202 1111264
32 Kreyling WG, Ferron GA, Haider B. Metabolic fate of inhaled Co aerosols in beagle dogs. Health Phys. 1986; 51:773–795. 10.1097/00004032-198612000-00007 3781852
33 Kyono H, Kusaka Y, Katsunori H, Kubota H, Yoko E. Ichikawa. Reversible lung lesions in rats due to short-term exposure to ultrafine cobalt particles. Ind Health. 1992; 30(3-4):103–118. 10.2486/indhealth.30.103 1301410
34 Patrick G, Batchelor AL, Stirling C. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part VI: Lung clearance of inhaled cobalt oxide particles in SPF Fischer rats. J Aerosol Sci. 1989; 20(2):249–255. 10.1016/0021-8502(89)90047-5
35 Popov LN, Kochetkova TA, Gusev MI, Markina NA, Elfimova EV. Accumulation, distribution and morphological changes in the body to the inhalatory exposure to a metallic cobalt aerosol [in Russian]. Gig Sanit. 1977; (6):12–15. 873221
36 Kerfoot EJ. Chronic animal inhalation toxicity to cobalt. Cincinnati, OH: U.S. Department of Health, Education, and Welfare, National Institute for Occupational Safety and Health; 1973.
37 Lasfargues G, Lison D, Maldague P, Lauwerys R. Comparative study of the acute lung toxicity of pure cobalt powder and cobalt-tungsten carbide mixture in rat. Toxicol Appl Pharmacol. 1992; 112(1):41–50. 10.1016/0041-008X(92)90277-Y 1733047
38 Lison D, Lauwerys R. Cobalt bioavailability from hard metal particles: Further evidence that cobalt alone is not responsible for the toxicity of hard metal particles. Arch Toxicol. 1994; 68(8):528–531. 10.1007/s002040050108 7802596
39 Ayala-Fierro F, Firriolo JM, Carter DE. Disposition, toxicity, and intestinal absorption of cobaltous chloride in male Fischer 344 rats. J Toxicol Environ Health A. 1999; 56(8):571–591. 10.1080/009841099157908 10321386
40 Bailey MR, Kreyling WG, Andre S, Batchelor A, Collier CG, Drosselmeyer E, Ferron GA, Foster P, Haider B, Hodgson A, et al. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part I: Objectives and summary of results. J Aerosol Sci. 1989; 20(2):169–188. 10.1016/0021-8502(89)90042-6
41 Barnaby CF, Smith T, Thompson BD. Dosimetry of the radioisotopes of cobalt. Phys Med Biol. 1968; 13(3):421–433. 10.1088/0031-9155/13/3/309 5700181
42 Hollins JG, McCullough RS. Radiation dosimetry of internal contamination by inorganic compounds of cobalt: An analysis of cobalt metabolism in rats. Health Phys. 1971; 21(2):233–246. 10.1097/00004032-197108000-00010 5094193
43 Naylor GP, Harrison JD. Gastrointestinal iron and cobalt absorption and iron status in young rats and guinea pigs. Hum Exp Toxicol. 1995; 14(12):949–954. 10.1177/096032719501401203 8962745
44 Bourg WJ, Nation JR, Clark DE. The effects of chronic cobalt exposure on passive-avoidance performance in the adult rat. Bull Psychon Soc. 1985; 23(6):527–530. 10.3758/BF03329874
45 Clyne N, Lins L-E, Pehrsson SK, Lundberg A, Werner J. Distribution of cobalt in myocardium, skeletal muscle and serum in exposed and unexposed rats. Trace Elem Med. 1988; 5:52–54.
46 Pehrsson SK, Hatori N, Clyne N, Koch J, Lins L-E, Ryden L. The effect of chronic cobalt exposure on cardiac function in rats. Trace Elem Med. 1991; 8:195–198.
47 Thomas RG, Furchner JE, London JE, Drake GA, Wilson JS, Richmond CR. Comparative metabolism of radionuclides in mammals-X. Retention of tracer-level cobalt in the mouse, rat, monkey and dog. Health Phys. 1976; 31(4):323–333. 10.1097/00004032-197610000-00003 825483
48 Andre S, Metivier H, Masse R. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part III: Lung clearance of inhaled cobalt oxide particles in baboons. J Aerosol Sci. 1989; 20(2):205–217. 10.1016/0021-8502(89)90044-X
49 Paley KR, Sobel ES, Yalow RS. Effect of oral and intravenous cobaltous chloride on thyroid function. J Clin Endocrinol Metab. 1958; 18(8):850–859. 10.1210/jcem-18-8-850 13563611
50 Smith T, Edmonds CJ, Barnaby CF. Absorption and retention of cobalt in man by whole-body counting. Health Phys. 1972; 22(4):359–367. 10.1097/00004032-197204000-00007 4625611
51 Sorbie J, Olatunbosun D, Corbett WE, Valberg LS. Cobalt excretion test for the assessment of body iron stores. Can Med Assoc J. 1971; 104(9):777–782. 5578125
52 Beaugelin-Seiller K, Baudin JP, Brottet D. Use of aquatic mosses for monitoring artificial radionuclides downstream of the nuclear power plant of Bugey (River Rhone, France). J Environ Radioact. 1994; 24(3):217–233. 10.1016/0265-931X(94)90041-8
53 Apostoli P, Porru S, Alessio L. Urinary cobalt excretion in short time occupational exposure to cobalt powders. Sci Total Environ. 1994; 150(1-3):129–132. 10.1016/0048-9697(94)90139-2 7939585
54 Mosconi G, Bacis M, Vitali MT, Leghissa P, Sabbioni E. Cobalt excretion in urine: Results of a study on workers producing diamond grinding tools and on a control group. Sci Total Environ. 1994; 150(1-3):133–139. 10.1016/0048-9697(94)90140-6 7939586
55 Beleznay E, Osvay M. Long-term clearance of accidentally inhaled 60Co aerosols in humans. Health Phys. 1994; 66(4):392–399. 10.1097/00004032-199404000-00003 8138404
56 Newton D, Rundo J. The long-term retention of inhaled cobalt-60. Health Phys. 1971; 21(3):377–384. 10.1097/00004032-197109000-00003 5095637
57 Foster P, Pearman I, Ramsden D. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part II: Lung clearance of inhaled cobalt oxide in man. J Aerosol Sci. 1989; 20(2):189–204. 10.1016/0021-8502(89)90043-8
58 Harp MJ, Scoular FI. Cobalt metabolism of young college women on self-selected diets. J Nutr. 1952; 47(1):67–72. 10.1093/jn/47.1.67 14939083
59 Valberg LS, Ludwig J, Olatunbosun D. Alteration in cobalt absorption in patients with disorders of iron metabolism. Gastroenterology. 1969; 56(2):241–251. 10.1016/S0016-5085(69)80123-X 5764593
60 Scansetti G, Botta GC, Spinelli P, Reviglione L, Ponzetti C. Absorption and excretion of cobalt in the hard metal industry. Sci Total Environ. 1994; 150(1-3):141–144. 10.1016/0048-9697(94)90141-4 7939587
61 Nielsen NH, Kristiansen J, Borg L, Christensen JM, Poulsen LK, Menné T. Repeated exposures to cobalt or chromate on the hands of patients with hand eczema and contact allergy to that metal. Contact Derm. 2000; 43(4):212–215. 10.1034/j.1600-0536.2000.043004212.x 11011920
62 Delahant AB. An experimental study of the effects of rare metals on animal lungs. AMA Arch Ind Health. 1955; 12:116–120. 14397854
63 Georgiadi GA. Change in the activity of the dehydrogenases and nonspecific enzymes in the respiratory tract mucosa of rats exposed to metallic cobalt dust in a chronic experiment [In Russian]. Zh Ushn Nos Gorl Bolezn. 1978; (1):63–67. 636624
64 Harding HE. Notes on the toxicology of cobalt metal. Br J Ind Med. 1950; 7(2):76–78. 10.1136/oem.7.2.76 15414282
65 Herndon BL, Jacob RA. McCann J. Physiological effects. In: Smith IC, Carson BL, editors. Trace Metals in the Environment. 1981. p. 925–1140.
66 National Toxicology Program (NTP). Toxicity studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1991. Toxicity Study Report Series No. 5. NIH Publication No. 91-3124.
67 Georgiadi GA, El’kind LA. Morphological changes in the respiratory tract mucosa under the influence of a metallic cobalt aerosol in a chronic experiment [in Russian]. Zh Ushn Nos Gorl Bolezn. 1978; (3):41–45. 664884
68 Bucher JR, Elwell MR, Thompson MB, Chou BJ, Renne R, Ragan HA. Inhalation toxicity studies of cobalt sulfate in F344/N rats and B6C3F1 mice. Fundam Appl Toxicol. 1990; 15(2):357–372. 10.1016/0272-0590(90)90061-N 2227161
69 Anttila S, Sutinen S, Paananen M, Kreus KE, Sivonen SJ, Grekula A, Alapieti T. Hard metal lung disease: A clinical, histological, ultrastructural and X-ray microanalytical study. Eur J Respir Dis. 1986; 69:83–94. 3758243
70 Davison AG, Haslam PL, Corrin B, Coutts II, Dewar A, Riding WD, Studdy PR, Newman-Taylor AJ. Interstitial lung disease and asthma in hard-metal workers: Bronchoalveolar lavage, ultrastructural, and analytical findings and results of bronchial provocation tests. Thorax. 1983; 38(2):119–128. 10.1136/thx.38.2.119 6857569
71 Demedts M, Gheysens B, Nagels J, Verbeken E, Lauweryns J, van den Eeckhout A, Lahaye D, Gyselen A. Hard-metal lung disease due to cobalt in diamond polishers. Am Rev Respir Dis. 1984; 129:A155.
72 Demedts M, Gheysens B, Nagels J, Verbeken E, Lauweryns J, van den Eeckhout A, Lahaye D, Gyselen A. Cobalt lung in diamond polishers. Am Rev Respir Dis. 1984; 130:130–135. 6742597
73 Deng JF, Sinks T, Elliot L, Smith D, Singal M, Fine L. Characterisation of respiratory health and exposures at a sintered permanent magnet manufacturer. Br J Ind Med. 1991; 48(9):609–615. 10.1136/oem.48.9.609 1911403
74 Gennart JP, Lauwerys R. Ventilatory function of workers exposed to cobalt and diamond containing dust. Int Arch Occup Environ Health. 1990; 62(4):333–336. 10.1007/BF00640843 2166005
75 Gheysens B, Auwerx J, Van den Eeckhout A, Demedts M. Cobalt-induced bronchial asthma in diamond polishers. Chest. 1985; 88(5):740–744. 10.1378/chest.88.5.740 2996839
76 Hartung M, Schaller KH, Brand E. On the question of the pathogenetic importance of cobalt for hard metal fibrosis of the lung. Int Arch Occup Environ Health. 1982; 50(1):53–57. 10.1007/BF00432493 7085087
77 Kusaka Y, Ichikawa Y, Shirakawa T, Goto S. Effect of hard metal dust on ventilatory function. Br J Ind Med. 1986; 43(7):486–489. 10.1136/oem.43.7.486 3718896
78 Kusaka Y, Iki M, Kumagai S, Goto S. Decreased ventilatory function in hard metal workers. Occup Environ Med. 1996; 53(3):194–199. 10.1136/oem.53.3.194 8704861
79 Kusaka Y, Iki M, Kumagai S, Goto S. Epidemiological study of hard metal asthma. Occup Environ Med. 1996; 53(3):188–193. 10.1136/oem.53.3.188 8704860
80 Kusaka Y, Yokoyama K, Sera Y, Yamamoto S, Sone S, Kyono H, Shirakawa T, Goto S. Respiratory diseases in hard metal workers: An occupational hygiene study in a factory. Br J Ind Med. 1986; 43(7):474–485. 10.1136/oem.43.7.474 3718895
81 Raffn E, Mikkelsen S, Altman DGM, Christensen J, Groth S. Health effects due to occupational exposure to cobalt blue dye among plate painters in a porcelain factory in Denmark. Scand J Work Environ Health. 1988; 14:378–384. 10.5271/sjweh.1903 3264937
82 Rastogi SK, Gupta BN, Husain T, Chandra H, Mathur N, Pangtey BS, Chandra SV, Garg N. A cross-sectional study of pulmonary function among workers exposed to multimetals in the glass bangle industry. Am J Ind Med. 1991; 20(3):391–399. 10.1002/ajim.4700200311 1928114
83 Ruokonen EL, Linnainmaa M, Seuri M, Juhakoski P, Söderström KO. A fatal case of hard-metal disease. Scand J Work Environ Health. 1996; 22(1):62–65. 10.5271/sjweh.111 8685677
84 Shirakawa T, Kusaka Y, Fujimura N, Goto S, Kato M, Heki S, Morimoto K. Occupational asthma from cobalt sensitivity in workers exposed to hard metal dust. Chest. 1989; 95(1):29–37. 10.1378/chest.95.1.29 2909353
85 Shirakawa T, Kusaka Y, Fujimura N, Goto S, Morimoto K. The existence of specific antibodies to cobalt in hard metal asthma. Clin Exp Allergy. 1988; 18(5):451–460. 10.1111/j.1365-2222.1988.tb02895.x 3233723
86 Sprince NL, Oliver LC, Eisen EA, Greene RE, Chamberlin RI. Cobalt exposure and lung disease in tungsten carbide production: A cross-sectional study of current workers. Am Rev Respir Dis. 1988; 138(5):1220–1226. 10.1164/ajrccm/138.5.1220 3264482
87 Sundaram P, Agrawal K, Mandke JV, Joshi JM. Giant cell pneumonitis induced by cobalt. Indian J Chest Dis Allied Sci. 2001; 43:47–49. 11370507
88 Swennen B, Buchet J-P, Stánescu D, Lison D, Lauwerys R. Epidemiological survey of workers exposed to cobalt oxides, cobalt salts, and cobalt metal. Br J Ind Med. 1993; 50(9):835–842. 10.1136/oem.50.9.835 8398878
89 Tabatowski K, Roggli VL, Fulkerson WJ, Langley RL, Benning T, Johnston WW. Giant cell interstitial pneumonia in a hard-metal worker: Cytologic, histologic and analytical electron microscopic investigation. Acta Cytol. 1988; 32:240–246. 3348063
90 Talbot RJ, Morgan A. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles. Part VIII: Lung clearance of inhaled cobalt oxide particles in mice. J Aerosol Sci. 1989; 20:261–265. 10.1016/0021-8502(89)90049-9
91 Van Cutsem EJ, Ceuppens JL, Lacquet LM, Demedts M. Combined asthma and alveolitis induced by cobalt in a diamond polisher. Eur J Respir Dis. 1987; 70:54–61. 3817065
92 Zanelli R, Barbic F, Migliori M, Michetti G. Uncommon evolution of fibrosing alveolitis in a hard metal grinder exposed to cobalt dusts. Sci Total Environ. 1994; 150(1-3):225–229. 10.1016/0048-9697(94)90157-0 7939601
93 Wiberg GS. The effect of cobalt ions on energy metabolism in the rat. Can J Biochem. 1968; 46(6):549–554. 10.1139/o68-085 5660412
94 Di Giulio C, Huang WX, Lahiri S, Mokashi A, Buerk DG. Cobalt stimulates carotid body chemoreceptors. J Appl Physiol. 1990; 68(5):1844–1849. 10.1152/jappl.1990.68.5.1844 2361886
95 Hatori N, Pehrsson K, Clyne N, Hansson G, Hofman-Bang C, Marklund SL, Rydén L, Sjöqvist P-O, Svensso L. Acute cobalt exposure and oxygen radical scavengers in the rat myocardium. Biochim Biophys Acta. 1993; 1181(3):257–260. 10.1016/0925-4439(93)90029-Z 8391326
96 Morelli L, Di Giulio C, Iezzi M, Data PG. Effect of acute and chronic cobalt administration on carotid body chemoreceptors responses. Sci Total Environ. 1994; 150(1-3):215–216. 10.1016/0048-9697(94)90153-8 7939599
97 Barborik M, Dusek J. Cardiomyopathy accompaning industrial cobalt exposure. Br Heart J. 1972; 34(1):113–116. 10.1136/hrt.34.1.113 4258223
98 Horowitz SF, Fischbein A, Matza D, Rizzo JN, Stern A, Machac J, Solomon SJ. Evaluation of right and left ventricular function in hard metal workers. Br J Ind Med. 1988; 45(11):742–746. 10.1136/oem.45.11.742 3203078
99 Jarvis JQ, Hammond E, Meier R, Robinson C. Cobalt cardiomyopathy: A report of two cases from mineral assay laboratories and a review of the literature. J Occup Med. 1992; 34(6):620–626. 1619493
100 Webb M. The biological action of cobalt and other metals III. Chelation of cations by dihydrolipoic acid. Biochim Biophys Acta. 1962; 65(1):47–65. 10.1016/0006-3002(62)90148-8 13999338
101 Lehninger AL. Principles of biochemistry. New York, NY: Worth Publishers, Inc; 1982. p. 361–466.
102 Alexander CS. Cobalt-beer cardiomyopathy: A clinical and pathologic study of twenty-eight cases. Am J Med. 1972; 53(4):395–417. 10.1016/0002-9343(72)90136-2 4263183
103 Alexander CS. Cobalt and the heart. Ann Intern Med. 1969; 70(2):411–413. 10.7326/0003-4819-70-2-411 5764511
104 Morin Y, Têtu A, Mercier G. Cobalt cardiomyopathy: Clinical aspects. Br Heart J. 1971; 33 Suppl:175–178. 10.1136/hrt.33.Suppl.175 5280148
105 Palmes ED, Nelson N, Laskin S, Kuschner M. Inhalation toxicity of cobalt hydrocarbonyl. Am Ind Hyg Assoc J. 1959; 20(6):453–468. 10.1080/00028895909343751 14430014
106 Stanley AJ, Hopps HC, Shideler AM. Cobalt polycythemia relative effects of oral and subcutaneous administration of cobaltous chloride. Proc Soc Exp Biol Med. 1947; 66(1):19–20. 10.3181/00379727-66-15968 20270659
107 Lammintausta K, Pitkänen O-P, Kalimo K, Jansen CT. Interrelationship of nickel and cobalt contact sensitization. Contact Derm. 1985; 13(3):148–152. 10.1111/j.1600-0536.1985.tb02527.x 4053597
108 Alomar A, Conde-Salazar L, Romaguera C. Occupational dermatoses from cutting oils. Contact Derm. 1985; 12(3):129–138. 10.1111/j.1600-0536.1985.tb01081.x 3158470
109 Dooms-Goossens A, Ceuterick A, Vanmaele N, Degreef H. Follow-up study of patients with contact dermatitis caused by chromates, nickel, and cobalt. Dermatologica. 1980; 160:249–260. 10.1159/000250501 7358190
110 Fischer T, Rystedt I. Cobalt allergy in hard metal workers. Contact Derm. 1983; 9(2):115–121. 10.1111/j.1600-0536.1983.tb04316.x 6221862
111 Goh CL, Gan SL, Ngui SJ. Occupational dermatitis in a prefabrication construction factory. Contact Derm. 1986; 15:235–240. 10.1111/j.1600-0536.1986.tb01343.x 2948758
112 Kanerva L, Estlander T, Jolanki R. Occupational skin disease in Finland: An analysis of 10 years of statistics from an occupational dermatology clinic. Int Arch Occup Environ Health. 1988; 60(2):89–94. 10.1007/BF00381486 2964415
113 Marcussen PV. Cobalt dermatitis. Clinical picture. Acta Derm Venereol. 1963; 43:231–234. 13932933
114 Valér M, Somogyi Z, Racz I. Studies concerning the sensitizing effect of cobalt. Dermatologica. 1967; 134:36–50. 10.1159/000254236 4226549
115 Bencko V, Wagner V, Wagnerová M, Reichrtová E. Immuno-biochemical findings in groups of individuals occupationally and non-occupationally exposed to emissions containing nickel and cobalt. J Hyg Epidemiol Microbiol Immunol. 1983; 27(4):387–394. 6663071
116 Katsarou A, Baxevanis C, Armenaka M, Volonakis M, Balamotis A, Papamihail M. Study of persistence and loss of patch test reactions to dichromate and cobalt. Contact Derm. 1997; 36(2):87–90. 10.1111/j.1600-0536.1997.tb00419.x 9062743
117 Löfström A, Wigzell H. Antigen specific human T cell lines for cobalt chloride. Acta Derm Venereol. 1986; 66:200–206. 2426895
118 Cirla AM. Cobalt-related asthma: Clinical and immunological aspects. Sci Total Environ. 1994; 150(1-3):85–94. 10.1016/0048-9697(94)90133-3 7939614
119 Shrivastava VK, David CV, Khare N, Khare N. Cobalt chloride induced histopathological changes in thyroid gland of female mice, Mus musculus. Pollut Res. 1996; 15:307–309.
120 Pedigo NG, George WJ, Anderson MB. Effects of acute and chronic exposure to cobalt on male reproduction in mice. Reprod Toxicol. 1988; 2(1):45–53. 10.1016/S0890-6238(88)80008-X 2980401
121 Bucher JR, Hailey JR, Roycroft JR, Haseman JK, Sills RC, Grumbein SL, Mellick PW, Chou BJ. Inhalation toxicity and carcinogenicity studies of cobalt sulfate. Toxicol Sci. 1999; 49(1):56–67. 10.1093/toxsci/49.1.56 10367342
122 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 471. NIH Publication No. 98-3961.
123 Szakmáry É, Ungváry G, Hudák A, Tátrai E, Náray M, Morvai V. Effects of cobalt sulfate on prenatal development of mice, rats, and rabbits, and on early postnatal development of rats. J Toxicol Environ Health A. 2001; 62(5):367–386. 10.1080/152873901300018110 11261899
124 Jordan C, Whitman RD, Harbut M, Tanner B. Memory deficits in workers suffering from hard metal disease. Toxicol Lett. 1990; 54(2-3):241–243. 10.1016/0378-4274(90)90190-W 2260122
125 Meecham HM, Humphrey P. Industrial exposure to cobalt causing optic atrophy and nerve deafness: A case report. J Neurol Neurosurg Psychiatry. 1991; 54(4):374–375. 10.1136/jnnp.54.4.374 2056332
126 Speijers GJA, Krajnc EI, Berkvens JM, Van Logten MJ. Acute oral toxicity of inorganic cobalt compounds in rats. Food Chem Toxicol. 1982; 20(3):311–314. 10.1016/S0278-6915(82)80298-6 7201957
127 Murdock HR Jr. Studies on the pharmacology of cobalt chloride. J Am Pharm Assoc. 1959; 48(3):140–142. 10.1002/jps.3030480303 13641038
128 Domingo JL, Llobet JM, Bernat R. A study of the effects of cobalt administered orally to rats. Arch Farmacol Toxicol. 1984; 10(1):13–20. 6508364
129 Holly RG. Studies on iron and cobalt metabolism. J Am Med Assoc. 1955; 158(15):1349–1352. 10.1001/jama.1955.02960150019005 13242351
130 Krasovskii GN, Fridlyand SA. Experimental data for the validation of the maximum permissible concentration of cobalt in water bodies. Hyg Sanit. 1971; 26:277–279.
131 Corrier DE, Mollenhauer HH, Clark DE, Hare MF, Elissalde MH. Testicular degeneration and necrosis induced by dietary cobalt. Vet Pathol. 1985; 22(6):610–616. 10.1177/030098588502200616 4082387
132 Mollenhauer HH, Corrier DE, Clark DE, Hare MF, Elissalde MH. Effects of dietary cobalt on testicular structure. Virchows Archiv B. 1985; 49(1):241–248. 10.1007/BF02912101 2865847
133 Nation JR, Bourgeois AE, Clark DE, Hare MF. The effects of chronic cobalt exposure on behavior and metallothionein levels in the adult rat. Neurobehav Toxicol Teratol. 1983; (1):9–15. 10.1016/0378-4274(83)90357-0 6856014
134 Anderson MB, Lepak K, Farinas V, George WJ. Protective action of zinc against cobalt-induced testicular damage in the mouse. Reprod Toxicol. 1993; 7(1):49–54. 10.1016/0890-6238(93)90009-V 8448416
135 Anderson MB, Pedigo NG, Katz RP, George WJ. Histopathology of testes from mice chronically treated with cobalt. Reprod Toxicol. 1992; 6(1):41–50. 10.1016/0890-6238(92)90019-P 1562797
136 Domingo JL, Paternain JL, Llobet JM, Corbella J. Effects of cobalt on postnatal development and late gestation in rats upon oral administration. Rev Esp Fisiol. 1985; 41:293–298. 4070758
137 Paternain JL, Domingo JL, Corbella J. Developmental toxicity of cobalt in the rat. J Toxicol Environ Health. 1988; 24(2):193–200. 10.1080/15287398809531153 3385796
138 Pedigo NG, Vernon MW. Embryonic losses after 10-week administration of cobalt to male mice. Reprod Toxicol. 1993; 7(2):111–116. 10.1016/0890-6238(93)90244-2 8499661
139 Seidenberg JM, Anderson DG, Becker RA. Validation of an in vivo developmental toxicity screen in the mouse. Teratog Carcinog Mutagen. 1986; 6(5):361–374. 10.1002/tcm.1770060503 2878502
140 Gilman JPW. Metal carcinogenesis: II. A study on the carcinogenic activity of cobalt, copper, iron, and nickel compounds. Cancer Res. 1962; 22(2):158–162. 13898693
141 Gilman JPW, Ruckerbauer GM. Metal carcinogenesis: I. Observations on the carcinogenicity of a refinery dust, cobalt oxide, and colloidal thorium dioxide. Cancer Res. 1962; 22(2):152–157. 13898692
142 Heath JC. The production of malignant tumours by cobalt in the rat. Br J Cancer. 1956; 10:668–673. 10.1038/bjc.1956.80 13426378
143 Heath JC. The histogenesis of malignant tumours induced by cobalt in the rat. Br J Cancer. 1960; 14:478–482. 10.1038/bjc.1960.52 13712614
144 Heath JC, Daniel MR. The production of malignant tumours by cobalt in the rat: Intrathoracic tumours. Br J Cancer. 1962; 16(3):473–478. 10.1038/bjc.1962.53 21772463
145 Shabaan AA, Marks V, Lancaster MC, Dufeu GN. Fibrosarcomas induced by cobalt chloride (CoCl2) in rats. Lab Anim. 1977; 11(1):43–46. 10.1258/002367777780959157 839722
146 Jensen AA, Tüchsen F. Cobalt exposure and cancer risk. Crit Rev Toxicol. 1990; 20(6):427–439. 10.3109/10408449009029330 2198048
147 Payne LR. The hazards of cobalt. J Soc Occup Med. 1977; 27(1):20–25. 10.1093/occmed/27.1.20 834025
148 Mur JM, Moulin JJ, Charruyer-Seinerra MP, Lafitte J. A cohort mortality study among cobalt and sodium workers in an electrochemical plant. Am J Ind Med. 1987; 11(1):75–81. 10.1002/ajim.4700110108 3812499
149 Moulin JJ, Wild P, Mur JM, Fournier-Betz M, Mercier-Gallay M. A mortality study of cobalt production workers: An extension of the follow-up. Am J Ind Med. 1993; 23(2):281–288. 10.1002/ajim.4700230205 8427256
150 National Toxicology Program (NTP). 12th Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011.
151 Lison D, Lauwerys R. Study of the mechanism responsible for the elective toxicity of tungsten carbide-cobalt powder toward macrophages. Toxicol Lett. 1992; 60(2):203–210. 10.1016/0378-4274(92)90275-O 1570634
152 De Boeck M, Kirsch-Volders M, Lison D. Cobalt and antimony: Genotoxicity and carcinogenicity. Mutat Res. 2003; 533(1-2):135–152. 10.1016/j.mrfmmm.2003.07.012 14643417
153 Lison D, De Boeck M, Verougstraete V, Kirsch-Volders M. Update on the genotoxicity and carcinogenicity of cobalt compounds. Occup Environ Med. 2001; 58(10):619–625. 10.1136/oem.58.10.619 11555681
154 Simonsen LO, Harbak H, Bennekou P. Cobalt metabolism and toxicology: A brief update. Sci Total Environ. 2012; 432:210–215. 10.1016/j.scitotenv.2012.06.009 22732165
155 Anard D, Kirsch-Volders M, Elhajouji A, Belpaeme K, Lison D. In vitro genotoxic effects of hard metal particles assessed by alkaline single cell gel and elution assays. Carcinogenesis. 1997; 18:177–184. 10.1093/carcin/18.1.177 9054604
156 Van Goethem F, Lison D, Kirsch-Volders M. Comparative evaluation of the in vitro micronucleus test and the alkaline single cell gel electrophoresis assay for the detection of DNA damaging agents: Genotoxic effects of cobalt powder, tungsten carbide and cobalt-tungsten carbide. Mutat Res Genet Toxicol Environ Mutagen. 1997; 392(1-2):31–43. 10.1016/S0165-1218(97)00043-8 9269329
157 De Boeck M, Lombaert N, De Backer S, Finsy R, Lison D, Kirsch-Volders M. In vitro genotoxic effects of different combinations of cobalt and metallic carbide particles. Mutagenesis. 2003; 18(2):177–186. 10.1093/mutage/18.2.177 12621074
158 Hartwig A, Asmuss M, Blessing H, Hoffmann S, Jahnke G, Khandelwal S, Pelzer A, Bürkle A. Interference by toxic metal ions with zinc-dependent proteins involved in maintaining genomic stability. Food Chem Toxicol. 2002; 40(8):1179–1184. 10.1016/S0278-6915(02)00043-1 12067581
159 Buchko GW, Hess NJ, Bandaru V, Wallace SS, Kennedy MA. Spectroscopic studies of zinc(II)- and cobalt(II)- associated escherichia coli formamidopyrimidine-DNA glycosylase: Extended x-ray absorption fine structure evidence for a metal-binding domain. Biochemistry. 2000; 39(40):12441–12449. 10.1021/bi001377k 11015225
160 Kopera E, Schwerdtle T, Hartwig A, Bal W. Co(II) and Cd(II) substitute for Zn(II) in the zinc finger derived from the DNA repair protein XPA, demonstrating a variety of potential mechanisms of toxicity. Chem Res Toxicol. 2004; 17(11):1452–1458. 10.1021/tx049842s 15540943
161 Asmuss M, Mullenders LHF, Eker A, Hartwig A. Differential effects of toxic metal compounds on the activities of Fpg and XPA, two zinc finger proteins involved in DNA repair. Carcinogenesis. 2000; 21:2097–2104. 10.1093/carcin/21.11.2097 11062174
162 De Boeck M, Lison D, Kirsch-Volders M. Evaluation of the in vitro direct and indirect genotoxic effects of cobalt compounds using the alkaline comet assay. Influence of interdonor and interexperimental variability. Carcinogenesis. 1998; 19(11):2021–2029. 10.1093/carcin/19.11.2021 9855019
163 De Boeck M, Lardau S, Buchet J-P, Kirsch-Volders M, Lison D. Absence of significant genotoxicity in lymphocytes and urine from workers exposed to moderate levels of cobalt-containing dust: A cross-sectional study. Environ Mol Mutagen. 2000; 36(2):151–160. 10.1002/1098-2280(2000)36:2<151::AID-EM10>3.0.CO;2-V 11013414
164 Griffis LC, Wolff RK, Beethe RL, Hobbs CH, McClellan RO. Evaluation of a multitiered inhalation exposure chamber. Toxicol Sci. 1981; 1(1):8–12. 10.1093/toxsci/1.1.8 7184776
165 Hill MA, Watson CR, Moss OR. An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405. UC-32. 10.2172/5306504
166 King-Herbert A, Thayer K. NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. 10.1080/01926230600935938 17162538
167 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):1079-1083. 10.1093/ajcp/20.11_ts.1079
168 Pearce RE, McIntyre CJ, Madan A, Sanzgiri U, Draper AJ, Bullock PL, Cook DC, Burton LA, Latham J, Nevins C, et al. Effects of freezing, thawing, and storing human liver microsomes on cytochrome P450 activity. Arch Biochem Biophys. 1996; 331(2):145–169. 10.1006/abbi.1996.0294 8660694
169 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
170 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
171 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
172 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
173 Cox DR. Regression models and life-tables. J R Stat Soc B. 1972; 34(2):187–220.
174 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62:679–682. 10.1093/biomet/62.3.679
175 Bailer AJ, Portier C. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44:417–431. 10.2307/2531856 3390507
176 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, UK: Chapman and Hall; 1997.
177 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
178 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor on-set for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
179 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49:793–801. 10.2307/2532200 8241374
180 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
181 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27:103–117. 10.2307/2528930 5547548
182 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28:519–531. 10.2307/2556164 5037867
183 Shirley E. A non-parametric equivalent of Williams’ Test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33:386–389. 10.2307/2529789 884197
184 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42:183–186. 10.2307/2531254 3719054
185 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6:241–252. 10.1080/00401706.1964.10490181
186 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
187 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company, Inc; 1957. 10.2307/2332898
188 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
189 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43:225–234. 10.2307/2531963 3567307
190 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
191 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59. 10.1006/rtph.1995.1009 7784636
192 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
193 Code of Federal Regulations (CFR). 21:Part 58.
194 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
195 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
196 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
197 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
198 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67:233–241. 7021938
199 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
200 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
201 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 S18:1–14. 10.1002/em.2850160502 2091921
202 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
203 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
204 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
205 Jain NC. Schalm’s veterinary hematology. 4th ed. Philadelphia: Lea & Febiger; 1986. p. 507–508.
206 Goldwasser E, Jacobson LO, Fried W, Plzak LF. Studies on erythropoiesis: V. The effect of cobalt on the production of erythropoietin. Blood. 1958; 13(1):55. 10.1182/blood.V13.1.55.55 13499580
207 Schofield CJ, Ratcliffe PJ. Oxygen sensing by HIF hydroxylases. Nat Rev Mol Cell Biol. 2004; 5:343–354. 10.1038/nrm1366 15122348
208 Epstein ACR, Gleadle JM, McNeill LA, Hewitson KS, O’Rourke J, Mole DR, Mukherji M, Metzen E, Wilson MI, Dhanda A, et al. C. elegans EGL-9 and mammalian homologs define a family of dioxygenases that regulate HIF by prolyl hydroxylation. Cell. 2001; 107(1):43–54. 10.1016/S0092-8674(01)00507-4 11595184
209 Yuan Y, Hilliard G, Ferguson T, Millhorn DE. Cobalt inhibits the interaction between hypoxia-inducible factor-alpha and von Hippel-Lindau protein by direct binding to hypoxia-inducible factor alpha. J Biol Chem. 2003; 278:15911–15916. 10.1074/jbc.M300463200 12606543
210 Taylor A, Marks V. Cobalt: A review. J Hum Nutr. 1978; 32:165–177. 670690
211 Nomura Y, Okamoto S-i, Sakamoto M, Feng Z, Nakamura T. Effect of cobalt on the liver glycogen content in the streptozotocin-induced diabetic rats. Mol Cell Biochem. 2005; 277:127–130. 10.1007/s11010-005-5777-y 16132723
212 Saker F, Ybarra J, Leahy P, Hanson RW, Kalhan SC, Ismail-Beigi F. Glycemia-lowering effect of cobalt chloride in the diabetic rat: Role of decreased gluconeogenesis. Am J Physiol. 1998; 274(6):E984–E991. 10.1152/ajpendo.1998.274.6.E984 9611146
213 Ybarra J, Behrooz A, Gabriel A, Koseoglu MH, Ismail-Beigi F. Glycemia-lowering effect of cobalt chloride in the diabetic rat: Increased GLUT1 mRNA expression. Mol Cell Endocrinol. 1997; 133(2):151–160. 10.1016/S0303-7207(97)00162-7 9406861
214 Kawakami T, Hanao N, Nishiyama K, Kadota Y, Inoue M, Sato M, Suzuki S. Differential effects of cobalt and mercury on lipid metabolism in the white adipose tissue of high-fat diet-induced obesity mice. Toxicol Appl Pharmacol. 2012; 258(1):32–42. 10.1016/j.taap.2011.10.004 22019852
215 Li M, Kim DH, Tsenovoy PL, Peterson SJ, Rezzani R, Rodella LF, Aronow WS, Ikehara S, Abraham NG. Treatment of obese diabetic mice with a heme oxygenase inducer reduces visceral and subcutaneous adiposity, increases adiponectin levels, and improves insulin sensitivity and glucose tolerance. Diabetes. 2008; 57(6):1526–1535. 10.2337/db07-1764 18375438
216 Nicolai A, Li M, Kim DH, Peterson SJ, Vanella L, Positano V, Gastaldelli A, Rezzani R, Rodella LF, Drummond G, et al. Heme oxygenase-1 induction remodels adipose tissue and improves insulin sensitivity in obesity-induced diabetic rats. Hypertension. 2009; 53(3):508–515. 10.1161/HYPERTENSIONAHA.108.124701 19171794
217 Kumar GP, Laloraya M, Laloraya MM. Powerful anti-sperm motility action of cobaltous ion and its recovery by a sulfhydryl compound. Contraception. 1990; 41(6):633–639. 10.1016/S0010-7824(09)91008-3 2163298
218 Gray J, Nicholson JK, Creasy DM, Timbrell JA. Studies on the relationship between acute testicular damage and urinary and plasma creatine concentration. Arch Toxicol. 1990; 64(6):443–450. 10.1007/BF01977625 2275602
219 Härkönen M, Kormano M. Acute cadmium-induced changes in the energy metabolism of the rat testis. J Reprod Fertil. 1970; 21(2):221–226. 10.1530/jrf.0.0210221 5445461
220 Caltana L, Merelli A, Lazarowski A, Brusco A. Neuronal and glial alterations due to focal cortical hypoxia induced by direct cobalt chloride (CoCl2) brain injection. Neurotox Res. 2009; 15(4):348–358. 10.1007/s12640-009-9038-9 19384568
221 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of gallium arsenide (CAS No. 1303-00-0) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 492. NIH Publication No. 00-3951.
222 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of indium phosphide (CAS No. 22398-80-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC.: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2001. Technical Report Series No. 499. NIH Publication No. 01-4433.
223 Boorman GA, Brockmann M, Carlton WW, Davis JMG, Dungworth DL, Hahn FF, Mohr U, Reichhelm H-BR, Turusov VS, Wagner BM. Classification of cystic keratinizing squamous lesions of the rat lung: Report of a workshop. Toxicol Pathol. 1996; 24(5):564–572. 10.1177/019262339602400505 8923677
224 Rittinghausen S, Dungworth DL, Ernst H, Mohr U. Primary pulmonary tumors. In: Mohr U, Dungworth DL, Capen CC, editors. Pathobiology of the Aging Rat. Washington, DC: ILSI Press; 1992. p. 161–172.
225 Rittinghausen S, Kaspareit J. Spontaneous cystic keratinizing epithelioma in the lung of a Sprague-Dawley rat. Toxicol Pathol. 1998; 26(2):298–300. 10.1177/019262339802600218 9547872
226 Hobbs CH, Abdo KM, Hahn FF, Gillett NA, Eustis SL, Jones RK, Benson JM, Barr EB, Dieter MP, Pickrell JA, et al. Summary of the chronic inhalation toxicity of talc in F344/N rats and B6C3F1 mice. In: Mohr U, Dungworth DL, Mauderly JL, Oberdorster G, editors. Toxic and Carcinogenic Effects of Solid Particles in the Respiratory Tract. Washington, D.C.: ILSI Press; 1993. p. 525–528.
227 Lee KP, Trochimowicz HJ, Reinhardt CF. Pulmonary response of rats exposed to titanium dioxide (TiO2) by inhalation for two years. Toxicol Appl Pharmacol. 1985; 79(2):179–192. 10.1016/0041-008X(85)90339-4 4002222
228 Martin JC, Daniel H, LeBouffant L. Short- and long- term experimental study of the toxicity of coal-mine dust and some of its constituents In: Walton WH, editor. Inhaled Particles IV (Part I) Proceedings of an International Symposium organized by the British Occupational Hygiene Society, Edinburg, September 22-26, 1975. Pergamon Press; 1977. p. 361-370.
229 Muhle H, Takenaka S, Mohr U, Dasenbrock C, Mermelstein R. Lung tumor induction upon long-term low-level inhalation of crystalline Silica. Am J Ind Med. 1989; 15(3):343–346. 10.1002/ajim.4700150309 2539015
230 Pott F, Dungworth DL, Heinrich U, Muhle H, Kamino K, Germann PG, Roller M, Rippe RM, Mohr U. Lung tumours in rats after intratracheal instillation of dusts. Ann Occup Hyg. 1994; 38:357–363.
231 Mauderly JL, Snipes MB, Barr EB, Belinsky SA, Bond JA, Brooks AL, Chang IY, Cheng YS, Gillett NA, Griffith WC, et al. Pulmonary toxicity of inhaled diesel exhaust and carbon black in chronically exposed rats. Part I: Neoplastic and nonneoplastic lung lesions. Res Rep Health Eff Inst. 1994; (68 Pt 1):1–75, 77–97. 7530965
232 Dixon D, Herbert RA, Kissling GE, Brix AE, Miller RA, Maronpot RR. Summary of chemically induced pulmonary lesions in the National Toxicology Program (NTP) toxicology and carcinogenesis studies. Toxicol Pathol. 2008; 36(3):428–439. 10.1177/0192623308315360 18441259
233 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,2',4,4',5,5'-hexachlorobiphenyl (PCB 153) (CAS No. 35065-27-1) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 529. NIH Publication No. 06-4465.
234 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 3,3',4,4',5-pentachlorobiphenyl (PCB 126) (CAS No. 57465-28-8) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 520. NIH Publication No. 06-4454.
235 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) (CAS No. 1746-01-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 521. NIH Publication No. 06-4468.
236 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of a binary mixture PCB 126, (CAS Nos. 57465-28-8 and 35065-27-1) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 530. NIH Publication No. 06-4466.
237 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of a binary mixture PCB 126 and PCB 118, (CAS Nos. 57465-28-8 and 31508-00-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 531. NIH Publication No. 07-4467.
238 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 3,3',4,4'-tetrachloroazobenzene (TCAB) (CAS No. 14047-09-7) in Harlan Sprague-Dawley rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 558. NIH Publication No. 11-5899.
239 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3',4,4',5-pentachlorobiphenyl (PCB 118) (CAS No. 31508-00-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 559. NIH Publication No. 11-5900.
240 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of talc (CAS No. 14807-96-6) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 421. NIH Publication No. 93-3152.
241 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nickel subsulfide (CAS No. 12035-72-2) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 453. NIH Publication No. 96-3369.
242 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nickel sulfate hexahydrate (CAS No. 10101-97-0) in F344/N rats and B6C3F1 mice (inhalation studies). National Institutes of Health, Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service; 1996. Technical Report Series No. 454. NIH Publication No. 96-3370.
243 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of molybdenum trioxide (CAS No. 1313-27-5) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1997. Technical Report Series No. 462. NIH Publication No. 97-3378.
244 Ozaki K, Haseman JK, Hailey JR, Maronpot RR, Nyska A. Association of adrenal pheochromocytoma and lung pathology in inhalation studies with particulate vompounds in the male F344 rat: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(2):263–270. 10.1080/019262302753559605 11950170
245 Collier CG, Hodgson A, Gray SA, Moody JC, Ball A. The lung clearance kinetics of ^57^Co_3_O_4_ in rats of various ages. J Aerosol Sci. 1991; 22(4):537–549. 10.1016/0021-8502(91)90009-7
246 Lehnert BE, Morrow PE. The initial lag in phagocytic rate by macrdphages in monolayer is related to particle encounters and binding. Immunol Invest. 1985; 14(6):515–521. 10.3109/08820138509022680 3830871
247 Lehnert BE, Morrow PE. Characteristics of alveolar macrophages following the deposition of a low burden of iron oxide in the lung. J Toxicol Environ Health. 1985; 16(6):855–868. 10.1080/15287398509530793 4093998
248 Morrow PE. Possible mechanisms to explain dust overloading of the lungs. Fundam Appl Toxicol. 1988; 10:369–384. 10.1016/0272-0590(88)90284-9 3286345
249 Morrow PE. Dust overloading of the lungs: Update and appraisal. Toxicol Appl Pharmacol. 1992; 113(1):1–12. 10.1016/0041-008X(92)90002-A 1553742
250 Takahashi H, Koshi K. Solubility and cell toxicity of cobalt, zinc and lead. Ind Health. 1981; 19:47–59. 10.2486/indhealth.19.47 7216841
251 Rae T. A study on the effects of particulate metals of orthopaedic interest on murine macrophages in vitro. J Bone Joint Surg Br. 1975; 57:444–450. 10.1302/0301-620X.57B4.444 1194310
252 Stopford W, Turner J, Cappellini D, Brock T. Bioaccessibility testing of cobalt compounds. J Environ Monit. 2003; 5(4):675–680. 10.1039/b302257a 12948248
253 Lee W, Ladanyi M. Genomics traces carcinogen fingerprints. Sci Transl Med. 2013; 5(197):197fs31. 10.1126/scitranslmed.3006810 23926198
254 Rodin SN, Rodin AS. Human lung cancer and p53: The interplay between mutagenesis and selection. Proc Natl Acad Sci USA. 2000; 97(22):12244–12249. 10.1073/pnas.180320897 11035769
255 Suda K, Tomizawa K, Mitsudomi T. Biological and clinical significance of KRAS mutations in lung cancer: An oncogenic driver that contrasts with EGFR mutation. Cancer Metastasis Rev. 2010; 29(1):49–60. 10.1007/s10555-010-9209-4 20108024
256 Horio Y, Chen A, Rice P, Roth JA, Malkinson AM, Schrump DS. Ki-ras and p53 mutations are early and late events, respectively, in urethane-induced pulmonary carcinogenesis in A/J mice. Mol Carcinog. 1996; 17(4):217–223. 10.1002/(SICI)1098-2744(199612)17:4<217::AID-MC5>3.0.CO;2-A 8989915
257 Westra WH. Early glandular neoplasia of the lung. Respir Res. 2000; 1(3):163–169. 10.1186/rr28 11667981
258 Wistuba II, Gazdar AF. Lung cancer preneoplasia. Annu Rev Pathol Mech Dis. 2006; 1(1):331–348. 10.1146/annurev.pathol.1.110304.100103 18039118
259 Hong H-HL, Ton T-VT, Kim Y, Wakamatsu N, Clayton NP, Chan P-C, Sills RC, Lahousse SA. Genetic alterations in K-ras and p53 cancer genes in lung neoplasms from B6C3F1 mice exposed to cumene. Toxicol Pathol. 2008; 36(5):720–726. 10.1177/0192623308320280 18648094
260 Rodenhuis S, van de Wetering ML, Mooi WJ, Evers SG, van Zandwijk N, Bos JL. Mutational activation of the K-ras oncogene. N Engl J Med. 1987; 317(15):929–935. 10.1056/NEJM198710083171504 3041218
261 Ogawa HI, Ohyama Y, Ohsumi Y, Kakimoto K, Kato Y, Shirai Y, Nunoshibaand T, Yamamoto K. Cobaltous chloride-induced mutagenesis in the supF tRNA gene of Escherichia coli. Mutagenesis. 1999; 14(2):249–253. 10.1093/mutage/14.2.249 10229930
262 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 S21:2–141. 10.1002/em.2850190603 1541260
263 MacGregor JT, Wehr CM, Henika PR, Shelby MD. The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
264 Tuveson DA, Jacks T. Modeling human lung cancer in mice: Similarities and shortcomings. Oncogene. 1999; 18(38):5318–5324. 10.1038/sj.onc.1203107 10498884
265 Malarkey DE, Hoenerhoff M, Maronpot RR. Carcinogenesis: Mechanisms and manifestations. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. Waltham, MA: Academic Press; 2013. p. 107. 10.1016/B978-0-12-415759-0.00005-4
266 Pao W, Girard N. New driver mutations in non-small-cell lung cancer. Lancet Oncol. 2011; 12(2):175–180. 10.1016/S1470-2045(10)70087-5 21277552
267 Boch C, Kollmeier J, Roth A, Stephan-Falkenau S, Misch D, Grüning W, Bauer TT, Mairinger T. The frequency of EGFR and KRAS mutations in non-small cell lung cancer (NSCLC): Routine screening data for central Europe from a cohort study. BMJ Open. 2013; 3(4):e002560. 10.1136/bmjopen-2013-002560 23558737
268 Ellis CA, Clark G. The importance of being K-Ras. Cell Signal. 2000; 12(7):425–434. 10.1016/S0898-6568(00)00084-X 10989276
269 Roberts PJ, Der CJ. Targeting the Raf-MEK-ERK mitogen-activated protein kinase cascade for the treatment of cancer. Oncogene. 2007; 26(22):3291–3310. 10.1038/sj.onc.1210422 17496923
270 Johnson BE, Jänne PA. Epidermal growth factor receptor mutations in patients with non-small cell lung cancer. Cancer Res. 2005; 65(17):7525–7529. 10.1158/0008-5472.CAN-05-1257 16140912
271 Husgafvel-Pursiainen K, Kannio A. Cigarette smoking and p53 mutations in lung cancer and bladder cancer. Environ Health Perspect. 1996; 104 Suppl 3:553–556. 8781382
272 Hernandez-Boussard TM, Hainaut P. A specific spectrum of p53 mutations in lung cancer from smokers: Review of mutations compiled in the IARC p53 database. Environ Health Perspect. 1998; 106(7):385–391. 10.1289/ehp.98106385 9637795
273 Toyooka S, Tsuda T, Gazdar AF. The TP53 gene, tobacco exposure, and lung cancer. Hum Mutat. 2003; 21(3):229–239. 10.1002/humu.10177 12619108
274 Herbst RS, Heymach JV, Lippman SM. Lung cancer. N Engl J Med. 2008; 359:1367–1380. 10.1056/NEJMra0802714 18815398
275 Hong HH, Ton TV, Kim Y, Wakamatsu N, Clayton NP, Chan PC, Sills RC, Lahousse SA. Genetic alterations in K-ras and p53 cancer genes in lung neoplasms from B6C3F1 mice exposed to cumene. Toxicol Pathol. 2008; 36(5):720–726. 10.1177/0192623308320280 18648094
276 Bialkowska A, Bialkowski K, Gerschenson M, Diwan BA, Jones AB, Olivero OA, Poirier MC, Anderson LM, Kasprzak KS, Sipowicz MA. Oxidative DNA damage in fetal tissues after transplacental exposure to 3′-azido-3′-deoxythymidine (AZT). Carcinogenesis. 2000; 21(5):1059–1062. 10.1093/carcin/21.5.1059 10783333
277 Donnelly PJ, Devereux TR, Foley JF, Maronpot RR, Anderson MW, Massey TE. Activation of K-ras in aflatoxin B 1-induced lung tumors from AC3F1 (A/J×C3H/HeJ) mice. Carcinogenesis. 1996; 17(8):1735–1740. 10.1093/carcin/17.8.1735 8761434
278 Ronai ZA, Gradia S, Peterson LA, Hecht SS. G to A transitions and G to T transversions in codon 12 of the Ki-ras oncogene isolated from mouse lung tumors induced by 4-(methylnitrosamino)-1-(3-pyridyl)-1-butanone (NNK) and related DNA methylating and pyridyloxobutylating agents. Carcinogenesis. 1993; 14(11):2419–2422. 10.1093/carcin/14.11.2419 7902220
279 Sills RC, Hong HL, Greenwell A, Herbert RA, Boornian GA, Devereux TR. Increased frequency of K-ras mutations in lung neoplasms from female B6C3F1 mice exposed to ozone for 24 or 30 months. Carcinogenesis. 1995; 16(7):1623–1628. 10.1093/carcin/16.7.1623 7614698