# Conclusions

Under the conditions of these 2-year inhalation studies, there was clear evidence of carcinogenic activity of cobalt metal in male F344/NTac rats based on increased incidences of alveolar/bronchiolar adenoma and carcinoma in the lung, including multiples, and on increased incidences of benign and malignant pheochromocytoma of the adrenal medulla, including bilateral neoplasms.^h^ The increased incidences of pancreatic islet adenoma or carcinoma (combined) were considered related to exposure. The occurrences of cystic keratinizing epithelioma of the lung and of renal tubule adenoma or carcinoma (combined) may have been related to exposure. There was clear evidence of carcinogenic activity of cobalt metal in female F344/NTac rats based on increased incidences of alveolar/bronchiolar adenoma and carcinoma in the lung, including multiples, and on increased incidences of benign and malignant pheochromocytoma of the adrenal medulla, including bilateral neoplasms. The occurrences of squamous cell neoplasms of the lung (predominantly cystic keratinizing epithelioma), and of mononuclear cell leukemia were considered related to exposure. The occurrences of pancreatic islet carcinoma may have been related to exposure. There was clear evidence of carcinogenic activity of cobalt metal in male and female B6C3F1/N mice based on increased incidences of alveolar/bronchiolar neoplasms of the lung (predominantly carcinoma), including multiple carcinoma.

h See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix O.

Exposure to cobalt metal resulted in increased incidences of nonneoplastic lesions of the lung and nose in male and female rats, the testes in male rats and mice, the adrenal medulla in female rats, and the lung, nose, larynx, and trachea in male and female mice.