# Discussion

Cobalt metal was nominated by the International Union of United Auto Workers and the Cobalt Development Institute for toxicology and carcinogenesis studies based on widespread occupational exposure, the occurrence of hard metal disease, and limited toxicity data. The NTP previously assessed the toxicity and carcinogenicity of a soluble cobalt compound, cobalt sulfate heptahydrate, in experimental animals exposed by inhalation.^66,68,122^ Findings from those studies showed lung cancer in rats and mice, thereby raising concerns regarding the carcinogenic potential of cobalt metal dust. Hence, NTP conducted studies on cobalt metal to obtain its toxicity and carcinogenicity profile and to compare and contrast the toxicity of insoluble cobalt metal with a soluble cobalt salt. This Technical Report presents the findings and conclusions of the 2-week, 3-month, and 2-year inhalation studies of rats and mice exposed to cobalt metal.

The exposure concentrations for the 2-week studies were estimated based on exposures of previously studied cobalt sulfate heptahydrate.^66^ In the current study, there was significant mortality in male and female rats exposed to 20 and 40 mg/m^3^ and body weight reductions in the 10 mg/m^3^ groups coupled with reduced urine volumes and concomitant increases in urine creatinine at the end of 2 weeks. Hence, 5 mg/m^3^ was selected as the highest exposure concentration for rats in the 3-month studies. In mice, there was significant mortality in males and females exposed to 40 mg/m^3^ and significant decreases in body weights in the 20 mg/m^3^ groups. Based on this, 10 mg/m^3^ was selected as the highest exposure concentration for mice in the 3-month study. Because the exposure concentrations in the mouse study were different from those in the rat study, only four concentrations were used in the rat study in order to optimize the number of inhalation chambers used in the studies.

In the 3-month studies, there was no exposure-related mortality in rats or mice. Consistent with the results of the 2-week studies, the respiratory tract was the primary site of toxicity in both rats and mice. In the lung, nonneoplastic lesions including chronic active lung inflammation, minimal to mild alveolar proteinosis, and minimal to moderate bronchiole epithelium hyperplasia generally occurred in both males and females. In the nose, there were indications of olfactory epithelium degeneration (rats and mice) and minimal to mild respiratory epithelium hyperplasia (rats) in males and females. There were also exposure-related lesions noted in the larynx and trachea of male and female mice. These findings are comparable with the previously conducted inhalation study on cobalt sulfate heptahydrate.^66,68^

Findings from the clinical pathology assessments conducted in the 3-month studies indicated erythrocytosis, as defined by an increase in the red blood cell mass and hemoglobin concentration. There were exposure concentration-related changes on days 3 and 23 and at 14 weeks in male rats and at 14 weeks in female rats with the red blood cell count reaching greater than or equal to 22% of the concurrent chamber control values in the high concentration groups (5 mg/m^3^). The differences in the time and magnitude of erythron changes due to cobalt metal exposure between the male and female rats is likely due, in part, to differences in sex hormones as testosterone is a known stimulator of erythropoiesis and estrogen a known suppressor.^205^ Minimal hematological effects were seen in the mice. The reason for the species differences in the erythrocytic response to cobalt is not known but has been previously reported for cobalt sulfate heptahydrate.^66^

Cobalt exposure has long been known to cause an erythrocytosis (independent of oxygen tension) through stimulation of erythropoietin,^206^ the mechanisms of which have been recently explained. It is now known that cobalt’s effects are due to its ability to stabilize hypoxia-inducible factor-1α (HIF-1α), a subunit of hypoxia-inducible factor-1 (HIF-1) a major regulator of oxygen homeostasis. There are a multitude of genes targeted by HIF-1 including erythropoietin, vascular endothelial growth factor, glucose transporter-1 (GLUT-1), and those related to various glycolytic enzymes.^207^ During normoxia, ubiquitin- and proteosome-dependent pathways utilize specific proline hydroxylases to continually degrade HIF-1α. By replacing the iron-binding site on these proline hydroxylases, cobalt renders them inactive, thereby indirectly stabilizing HIF-1α.^208,209^ There is also evidence that cobalt directly binds to HIF-1α thereby preventing its degradation.^209^

Other clinical chemistry indicators including glucose, cholesterol, and triglycerides were assessed in special study rats based on reports in the literature which suggest that cobalt administration affects triglyceride and cholesterol blood levels in rodents.^68,210^ Findings from the current studies indicated significant exposure-related decreases in cholesterol concentrations in both male and female rats, as well as significant decreases in glucose concentrations in male rats. Decreases in cholesterol and glucose concentrations are not uncommon findings in toxicology studies and usually represent a combination of decreased food intake and/or altered lipid and carbohydrate metabolism, the mechanisms of which are typically not known. Various studies have revealed several mechanisms by which cobalt may alter lipid and glucose metabolism. As previously mentioned, cobalt stabilizes HIF-1α which has the potential to activate genes involved in energy metabolism including those of glycolysis. In addition, short-term administration of cobalt to diabetic rats was shown to have a glycemia-lowering effect that may be mediated by reductions in systemic glucose production (modulation of glycogen metabolism and gluconeogenesis), increased tissue glucose uptake by induction of GLUT-1, or a combination of these two mechanisms.^211-213^ Administration of cobalt has also been shown to improve insulin sensitivity and glucose tolerance, as well as alter the ratio of HDL to LDL cholesterol in the blood of obese rats and mice by activation of heme-oxygenase-1 and increased secretion of adiponectin with AMK-activated protein kinase activation.^214-216^ In the current study, similar exposure-dependent effects were noted in the cobalt metal exposed rats and mice.

Cobalt metal exposure for 3 months had effects on the male reproductive system as indicated by a significant decrease in sperm motility in male rats and mice accompanied by marked germinal epithelium degeneration in the testes of mice. Cobalt has been shown to affect the motility of human sperm in vitro, suggesting a potential direct effect on the spermatozoa.^217^ The observed cobalt-related effects in the testes and epididymides of mice are consistent with those that have been previously reported, however the mode of action is unknown. Nevertheless, similar findings are also observed with cadmium chloride, and this finding is believed to be the result of cadmium chloride-induced testicular ischemia resulting in testicular degeneration and atrophy.^218,219^ Cobalt has been shown to induce hypoxia, resulting in ischemia in a variety of in vitro and in vivo models.^220^ Therefore, it is possible that cobalt-related effects on the testis and subsequently on the epididymis were the result of localized hypoxia. In female rats, although there appeared to be a higher probability of extended diestrus in the 5 mg/m^3^ group the toxicologic significance of this subtle alteration is unclear.

In the current 2-year studies, the survival of female rats was decreased in the top two exposure groups (2.5 and 5 mg/m^3^) with a statistically significant reduction in the 2.5 mg/m^3^ group. Mean body weights of both male and female rats were significantly decreased in the 2.5 and 5 mg/m^3^ groups. In mice, the survival of the males exposed to 2.5 or 5 mg/m^3^ was significantly less than that of the concurrent chamber controls. Mean body weights were reduced by greater than 10% in both males and females in the 5 mg/m^3^ group.

As with the 3-month studies, the respiratory tract was the major target for toxicity in the 2-year studies with the lung as the primary site for carcinogenicity in both rats and mice following cobalt metal exposure. In rats, there were exposure concentration-related significant increases in the incidences of alveolar/bronchiolar adenoma and carcinoma including multiple adenomas and carcinomas, thereby leading to clear evidence of carcinogenicity in male and female rats. In general, the alveolar/bronchiolar adenomas that occurred in rats and mice were morphologically similar to those that occur spontaneously. However, the alveolar/bronchiolar carcinomas tended to be larger, more invasive, pleomorphic masses that sometimes replaced entire lung lobes. In rats, several of the carcinomas had a prominent sarcomatous or desmoplastic component which is uncommon in spontaneous alveolar/bronchiolar carcinomas but not uncommon in inhalation studies with particulates.^122,221,222^ In male mice, there was clear evidence of carcinogenicity based on statistically significant increases in the incidences of alveolar/bronchiolar carcinoma including multiple carcinomas. In female mice, there was clear evidence of carcinogenicity based on significantly increased incidences of alveolar/bronchiolar adenoma or carcinoma (combined) including multiple carcinomas. In rats and mice, the incidences of hyperplasia in the alveolar and bronchiolar epithelia were significantly increased. In the lung, such hyperplasia is considered a preneoplastic lesion and can progress to neoplasia. In female mice, there was clear evidence of carcinogenicity based on significantly increased incidences of alveolar/bronchiolar neoplasms of the lung (predominantly carcinoma), including multiple carcinomas.

In mice, the lung neoplasms metastasized to other regions such as the cecum, liver, pancreas, heart, adrenal gland, testes, thymus, skin, skeletal muscle, nose, trachea, and kidney as indicated by the presence of neoplasms in these tissues that were morphologically similar to those in the lung.

In rats, exposure to cobalt metal induced cystic keratinizing epitheliomas (CKE) in the lungs with higher occurrences in females compared to males. CKEs are rarely observed spontaneous neoplasms in rats from NTP 2-year inhalation studies and are rarely found in other species.^223-225^ CKEs have been induced in the lungs of rats following intratracheal instillation or chronic inhalation exposure to various particulate compounds.^223,225-232^ Significantly increased incidences of CKEs were observed in female Sprague Dawley rats following exposure to polychlorinated biphenyls (PCB), dioxin, dioxin-like compounds, and mixtures of dioxin-like compounds by gavage for up to two years.^233-239^ CKEs are considered part of a spectrum of lesions that form a continuum considered to progress from squamous metaplasia to keratin cysts to CKE to squamous cell carcinoma. In the current study, few incidences of squamous metaplasia occurred in female rats, and squamous cysts were not observed, although minimal squamous differentiation was observed in some alveolar/bronchiolar carcinomas and a single incidence of a squamous cell carcinoma was observed in a female in the high concentration 5 mg/m^3^ group. The occurrence of CKEs was considered related to exposure in females based on the rarity of these neoplasms in NTP inhalation studies and the increase over the historical control range for all routes of administration.

Prolonged exposure to cobalt metal appeared to cause progressive injury to the lungs and nose in both male and female rats as indicated by the increasing incidences and severities of the nonneoplastic lesions relative to the 2-week and 3-month studies. In the 2-year studies, neoplasms that occurred in the lung were accompanied by a spectrum of generally similar inflammatory and nonneoplastic proliferative lesions of the respiratory tract. These lesions generally included epithelial hyperplasia, metaplasia, necrosis, and inflammation in the nose and bronchiolar and alveolar epithelial hyperplasia and inflammation and proteinosis of the lung in male and female rats and mice. A similar spectrum of inflammatory, fibrotic, and proliferative lesions were reported in the respiratory tract of female rats and mice in a previous NTP study on cobalt sulfate heptahydrate.^122^

In rats, another major target organ for carcinogenicity was the adrenal medulla as indicated by exposure concentration-related increased incidences of benign and malignant pheochromocytomas, including bilateral, in both males and females. The results of several NTP inhalation studies with particulate compounds suggest that there may be an association between the occurrence of benign and malignant alveolar/bronchiolar neoplasms and variably extensive chronic pulmonary nonneoplastic lesions of the lung and significantly increased incidences of hyperplasias and benign and malignant pheochromocytomas of the adrenal medulla in exposed male and female rats.^122,221,222,240-243^ With varying degrees of statistical significance, in some but not all studies, this relationship appeared to be associated with the severities of lung fibrosis and inflammation.^244^ In NTP studies, the mechanism(s) of this association between lung lesions and pheochromocytoma in rats is not understood. However, reduced gas exchange induced by extensive space-occupying neoplasms and nonneoplastic lung lesions such as fibrosis and chronic inflammation may lead to systemic hypoxemia that chronically stimulates catecholamine secretion from the adrenal medulla. This chronic hypersecretory activity may lead to medullary hyperplasia and subsequent neoplasia.^244^ In the present studies, abnormal breathing was observed in some animals, however clinical signs of cyanosis were not noted.

Cobalt metal also induced pancreatic islet neoplasms following inhalation exposure in male rats. There were significant increases in the incidences of pancreatic islet adenoma or carcinoma (combined) in the 2.5 and 5 mg/m^3^ groups and the instances exceeded the historical control range for all routes of administration. Based on the low spontaneous background rate, and significantly increased incidences, it was concluded that there was some evidence of carcinogenicity in the pancreatic islets of male rats. In female rats, there was an increase in the incidence of pancreatic islet carcinoma in the 5 mg/m^3^ group relative to concurrent chamber controls and historical controls (all routes). However, the absence of statistically significant trends or pairwise comparisons led to the conclusion of equivocal evidence of pancreatic islet carcinoma in female rats. This is the first time that the pancreas has been reported as a target organ of carcinogenicity in NTP inhalation studies.

In female rats, there were statistically significant increases in the incidences of mononuclear cell leukemia at all exposure concentrations compared to the chamber controls; however, no clear exposure-concentration relationship was seen. Although mononuclear cell leukemia is a common spontaneous neoplasm in F344 rats, the increased incidences in females in the current study were considered related to cobalt exposure.

Increased incidences of renal tubule adenoma or carcinoma (combined) occurred in male rats exposed to cobalt metal compared to the chamber control group, but the increases were not statistically significant. Since the standard evaluation of the kidney of males suggested the possibility of an exposure-related carcinogenic effect, an extended evaluation was performed by step-sectioning the kidney; however, the findings were not significantly different from the original evaluation. Although there was an overall positive trend in the incidences of renal tubule adenoma or carcinoma (combined) in male rats, no pairwise tests were significant, there was no exposure-concentration response, and three adenomas occurred in chamber control males. In addition, no supporting nonneoplastic findings occurred. However, because these lesions are relatively rare, NTP concluded that they may have been related to cobalt exposure.

Based on reports in the literature, the heart is one of the major target organs following occupational exposure to cobalt in both humans and animals.^9^ Occupational exposure of humans to cobalt-containing dust, either as cobalt metal or as hard metal, is believed to result in cardiomyopathy; however, in the majority of these and other reported occupational studies, coexposure to other substances was common.^9,97^ However, there was no indication of cardiomyopathy in the current studies.

Toxicokinetic studies were conducted as part of the 2-week, 3-month, and 2-year studies in rats and mice to inform study design, as well as to provide data on pulmonary retention and clearance and systemic distribution. In the 2-week studies, tissues from males and females were weighed and examined for cobalt concentrations and burdens at terminal kill. In females, cobalt was measured in the blood, serum, and lung of additional groups held for 3 weeks after exposure so that clearance from tissues could be evaluated. In the 3-month and 2-year studies, lung weights, lung cobalt concentrations, and lung cobalt burdens were determined in females. In the 3-month studies, the toxicokinetic study included time points during the exposure as well as during a postexposure period. In the 2-year studies, lung cobalt measurements were determined over the first 18 months of the studies. In the 3-month studies, blood cobalt concentrations and liver weights, cobalt concentrations, and cobalt burdens were also determined in females. In all three studies, exposure-related changes in tissue weights, especially exposure-related increases in lung weights which demonstrated greater increases, earlier onsets, and/or greater persistence during the postexposure period in rats and mice (2-week and 3-month studies), prompted the use of tissue cobalt burden (rather than concentration) for determination of cobalt deposition and clearance.

Cobalt concentrations and burdens were increased in all studies in all tissues examined, indicating systemic exposure of rats and mice to cobalt. In particular, liver cobalt concentrations in the 2-week and 3-month studies approached or even exceeded lung cobalt concentrations, particularly at higher exposure concentrations. Normalized lung burden data generally indicated that there were no biologically significant disproportionate changes in cobalt deposition or clearance with increasing exposure concentration; these data are consistent with the modeling data discussed below.

Lung deposition and clearance data from the 2-week studies were used to estimate lung clearance. As there were only two time points, the data were fit to a one-compartment model. Data from the 2-week studies were used to select time points for the 3-month studies (exposure and postexposure phases). Due to a lack of sufficiently early time points during the exposure phase, the data generated during the exposure phase were fit to a one-compartment model, while a two-compartment model was utilized for the postexposure phase. Time points for the 2-year lung deposition and clearance studies were selected using the 3-month data and included early time points (days 1, 2, 3, and 4). Following completion of these studies, the lung deposition and clearance data from the exposure phases of the 3-month and 2-year studies were fit to a two-compartment model. Modeling of the lung data generally indicated both rapid (approximately 1 to 5 days for all studies) and slow (longer with increasing exposure duration) clearance phases; the two-phase clearance from the lung probably contributed to the apparent two-phase elimination from the blood. Steady state was reached by the midpoint of the 3-month study in each species. In the 2-year studies, the times required to reach steady state were relatively long (12 to 18 months), due to the slow clearance half-lives. This phenomenon is consistent with previous studies^30,32,90^ and may be caused by binding of dissolved cobalt to tissues or movement of particles to the interstitium and the formation of foci of macrophages on the alveolar wall.^245^ In the 2-year studies, slow phase half-lives increased significantly with decreasing exposure concentration. When comparing the rapid and slow clearance phases, the majority (>95% in rats and >82% in mice) of the deposited cobalt was cleared with a very short half-life (approximately 1 to 5 days across studies), while the remainder was cleared more slowly. When comparing steady state lung cobalt burdens, it was apparent that burdens were similar in rats and mice, with maximum and steady state lung cobalt burdens (rapid + slow) of approximately 50 µg per lung at 5 mg/m^3^ in both species. These burdens were compared to those that would be required to cause lung overload, which occurs as a result of excessive volume of insoluble particles relative to that of the alveolar macrophage pool. Clearance by macrophages slows when particle volume is 6% of the macrophage pool volume and then ceases when particle volume is 60% of the macrophage pool volume, resulting in dramatically increased lung burdens and very long clearance half-lives.^246-249^ Overload was originally studied in F344 rats and assumes a density of one; however, for the current studies, the ratio of mouse to rat lung weight at 18 months of the chronic study and the use of the density of the cobalt test article (approximately 8.81 g/cm^3^) allowed for evaluation of overload specific to rats and mice exposed to cobalt metal. Based on these assumptions, 13.2 mg (rats) or 2.1 mg (mice) per lung would be required to cause overload. These values are 264 (rats) or 42 (mice) times the maximum cobalt lung burdens observed in the 2-year studies, indicating that overload was not approached in these studies.

Multiple lines of evidence, including the rapid clearance of cobalt from the lung and blood, the low lung cobalt burdens, the absence of particle overload, the systemic distribution and elimination of cobalt, and the observed toxicity/carcinogenicity to extrapulmonary sites are consistent with relatively soluble cobalt particles rather than insoluble particles.^30,32,33^ Cobalt has been reported to be insoluble in aqueous environments but able to be solubilized by strong mineral acids.^33,250^ In vivo studies by Rae^251^ show that macrophages were able to dissolve a significant amount of cobalt, despite toxicity to the cell. Based on this evidence, alveolar macrophages likely contributed to the solubilizaton and systemic absorption of cobalt via the lung in the current studies. Furthermore, studies by Stopford et al.^252^ using artificial fluids to mimic ingestion and inhalation indicate that lysosomes are likely responsible for dissolving cobalt taken up by macrophages and that any cobalt ingested via grooming or mucocilliary clearance would be solubilized by gastric juices. Because dissolution of cobalt results in toxicity to the macrophages, it is likely that the clearance of cobalt is due primarily to the dissolution and absorption of cobalt, rather than alveolar macrophage mediated clearance of intact particles via mucocilliary clearance. However, gastrointestinal absorption and systemic distribution following grooming or mucocilliary clearance may have also contributed to the tissue distribution of cobalt.

The mechanisms of cobalt-induced carcinogenesis are not well understood, although the genotoxicity of cobalt compounds has been established in a variety of test systems (reviewed in IARC^1^). In the current study, to identify a potential mode of action through which cobalt metal may be inducing its carcinogenic effects, mutation analysis was conducted on the most commonly altered cancer genes in human lung cancer: Kras, Egfr, and Tp53 in lung neoplasms from F344/NTac rats and B6C3F1/N mice exposed to cobalt metal. Chemical-specific genetic mutations have been previously demonstrated with tobacco smoke-induced lung cancer (C:G→A:T), ultraviolet light-induced melanoma (C:G→T:A), aflatoxin-induced hepatocellular carcinoma (C:G→A:T), and aristolochic acid-induced urothelial carcinoma (A:T→T:A).^253^ In addition, several cancers also harbor mutations in genes that may have several functions, such as tumor suppressor genes, oncogenes, DNA repair genes, apoptosis genes, and growth factor genes. Several of these mutations are “driver” mutations that are specific to each cancer type. In human lung cancer, the most common driver mutations occur in KRAS, EGFR, and TP53 genes.^254,255^ In the current study, hot spot regions in these genes from alveolar/bronchiolar carcinomas from rats and mice chronically exposed to cobalt metal were evaluated.

Findings showed that Kras mutations were more frequent than Tp53 and Egfr mutations within the alveolar/bronchiolar carcinomas from F344/NTac rats and B6C3F1/N mice chronically exposed to cobalt metal. Mutations in KRAS are considered to be an early event, whereas mutations within TP53 are thought to be a late event in the pathogenesis of lung cancer.^256,257^ KRAS and EGFR mutations are considered to be mutually exclusive in human lung cancer,^258^ but unexpectedly, in the current study 38% (3/8) of rats and 25% (3/12) of mice that harbored Egfr mutations also had Kras mutations. The significance of the presence of the independent occurrence of mutations in some alveolar/bronchiolar mutations is unclear but may be related to the repeated exposure to cobalt metal over the 2-year period or due to sampling of genetically heterogeneous tumors from the same lung sample. Alternatively, it may reflect the many pathways that still lead to cancer.

Mutations within codon 12 of Kras were observed in both spontaneous alveolar/bronchiolar carcinomas [27% (34/124)^259^] and alveolar/bronchiolar carcinomas from cobalt metal-exposed mice [67% (46/69)]. However, alveolar/bronchiolar carcinomas from cobalt metal-exposed mice had predominantly G→T transversions [80% (24/30)], whereas the spontaneous carcinomas had G→A transitions [70% (14/20)] in codon 12. The G→T transversions were also the most predominant mutations in alveolar/bronchiolar carcinomas from mice chronically exposed to cobalt sulfate heptahydrate aerosols,^122^ as well as other chemicals such as ozone, ethylene oxide, and cumene (Appendix K, Table K-17). This suggests that these chemicals target guanine or cytosine bases suggesting that these chemicals induce mutations at multiple sites and tissues by a common mechanism. G→T transversions are one of the more common Kras mutations in human lung cancer.^260^ G→T Kras mutations were reported to correlate with 8-hydroxydeoxyguanine adducts that result from oxidative stress. In the current study, these transversion mutations were seen almost exclusively in murine alveolar/bronchiolar carcinomas from cobalt exposure but not in spontaneous alveolar/bronchiolar carcinomas.

The results of the NTP bacterial mutagenicity assays lend support to the possibility that cobalt metal induces tumorigenesis by increasing oxidative stress. In bacterial mutagenicity assays conducted by NTP, positive results were seen in Salmonella typhimurium strain TA98 and equivocal results were seen in strain TA100 in the absence of S9 metabolizing enzymes; results for both strains were negative with the addition of S9 mix. The Escherichia coli WP2 uvrA/pKM101 strain gave negative results in the absence or presence of S9 mix. These observations are of interest considering that cobalt is known to produce reactive oxygen species that could lead to increases in 8-hydroxydeoxyguanine adducts, and the mutations identified in the cancer-related genes sequenced from cobalt metal-induced mouse lung tumors predominately occurred at G:C base pairs. Strain T98 detects a -1 frameshift that disrupts a dinucleotide run of (CG)_4_ residues; strain TA100 detects reverse mutations at a codon for proline (GGG) in hisG46, and the E. coli WP2 uvrA/pKM101 strain detects reverse mutations at the trpE ochre (TAA) codon. Taken together, the degree to which cobalt metal was mutagenic in the three strains correlated with the ability of each strain to detect mutational events at G:C base pairs. In support of this observation, sequencing of the supF tRNA mutational reporter gene in bacteria exposed to cobalt chloride showed that almost all mutational events (base substitutions and frameshifts) occurred at G:C base pairs.^261^ Cobalt metal-induced mutagenicity was not apparent with addition of S9 mix in any bacterial strain that was tested by NTP. Although the composition of S9 mix has not been fully characterized, it contains microsomal and cytosolic enzymes, and could, therefore, contain radical scavenging enzymes such as glutathione peroxidase, glutathione reductase, glutathione-S-transferase, catalase, and superoxide dismutase. The presence of these enzymes in S9 mix may have ameliorated the mutagenic effects of cobalt. Alternatively (or additionally), the absence of cobalt-induced mutagenic activity in the presence of S9 mix might have been due to binding of cobalt to S9 proteins.

The NTP has conducted two 2-year inhalation studies, one on cobalt sulfate heptahydrate^122^ and the current study on cobalt metal. Both compounds induced alveolar/bronchiolar adenomas and carcinomas and nonneoplastic respiratory tract lesions in rats and mice and pheochromocytomas in rats. As there are no tissue burden data available for the cobalt sulfate heptahydrate study, exposure concentrations of cobalt have been used for comparison. When the exposure concentrations in the [struck: of] cobalt sulfate heptahydrate study, which were based on cobalt sulfate, are normalized to cobalt metal using the molecular weight ratio of cobalt:cobalt sulfate [struck: heptahydrate], the highest concentration of cobalt sulfate [struck: heptahydrate] (3.0 mg/m^3^) results in an exposure concentration of cobalt (1.14 mg/m^3^) that is similar to the lowest exposure concentration (1.25 mg/m^3^) of cobalt metal in the current study.^g^ At the similar cobalt exposure concentration, there were more neoplasms in each sex-species group with cobalt metal, with the exception of female rats; however, significantly increased incidences of lung neoplasms were observed in all four sex-species groups with both cobalt sulfate heptahydrate and cobalt metal. For pheochromocytomas, the responses at the similar cobalt concentration were also similar. Increased incidences of pancreatic islet neoplasms in male and female rats and mononuclear cell leukemia in female rats exposed to cobalt metal indicated systemic carcinogenicity; however, incidences of these neoplasms were increased at concentrations greater than those used in the cobalt sulfate heptahydrate studies. There were also some differences in the affected tissues, types, incidences, and severities of nonneoplastic respiratory tract lesions between the two studies at the similar exposure concentration. Overall, there was significant toxicity to the respiratory tract in both studies at the similar cobalt exposure concentration, and comparisons of data between the two studies suggest that cobalt is toxic and carcinogenic, at least in the respiratory tract, at a similar exposure concentration.

g ERRATUM: Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]