# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-581.

## Rats

### Two-week Study

The exposure concentrations for the 2-week study were estimated based on exposures of previously studied cobalt sulfate heptahydrate.^66^ All rats exposed to 40 mg/m^3^ and all male and three female rats exposed to 20 mg/m^3^ died before the end of the study; the majority of deaths occurred by study day 7 (Table 2). Final mean body weights were significantly decreased in male and female rats exposed to 10 mg/m^3^ and were 20% and 12% less than those of the chamber control groups, respectively. In addition, the final mean body weight was significantly decreased in female rats exposed to 20 mg/m^3^ and was 45% less than that of the chamber controls. Mean body weight gains of 10 mg/m^3^ males and females and 20 mg/m^3^ females were significantly less than those of the chamber controls. Females exposed to 20 mg/m^3^ lost weight during the study. Exposure-related clinical findings included abnormal breathing, lethargy, and thinness in male rats exposed to 20 or 40 mg/m^3^, and in females exposed to 40 mg/m^3^. Dark lungs were observed at necropsy in all early-death rats of both sexes exposed to 40 mg/m^3^ and most rats exposed to 20 mg/m^3^. Pale lungs were noted in two females exposed to 20 mg/m^3^, four males exposed to 10 mg/m^3^, and one male exposed to 5 mg/m^3^.

Table 2 Survival and Body Weights of Rats in the Two-week Inhalation Study of Cobalt Metal^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 102 ± 2 | 144 ± 3 | 41 ± 2
2.5 | 5/5 | 102 ± 2 | 144 ± 2 | 42 ± 2 | 100
5 | 5/5 | 102 ± 3 | 140 ± 4 | 38 ± 2 | 97
10 | 5/5 | 100 ± 3 | 155 ± 6** | 14 ± 4** | 80
20 | 0/5^c^ | 103 ± 3 | – | – | –
40 | 0/5^d^ | 101 ± 3 | – | – | –
Female
0 | 5/5 | 88 ± 4 | 112 ± 4 | 24 ± 2
2.5 | 5/5 | 88 ± 2 | 112 ± 2 | 24 ± 1 | 100
5 | 5/5 | 86 ± 3 | 107 ± 3 | 21 ± 1 | 96
10 | 5/5 | 87 ± 4 | 98 ± 4** | 11 ± 1** | 88
20 | 2/5^e^ | 86 ± 3 | 61 ± 5** | −23 ± 0** | 55
40 | 0/5^f^ | 86 ± 3 | – | – | –

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 2 weeks/number initially in group.

^c^ Days of deaths: 5, 5, 5, 9, 13.

^d^ Days of deaths: 5, 6, 6, 7, 7.

^e^ Days of deaths: 5, 7, 13.

^f^ Days of deaths: 5, 6, 6, 6, 7.

Absolute lung weights of females exposed to 10 or 20 mg/m^3^ and the relative lung weights of both sexes exposed to 10 mg/m^3^ and females exposed to 20 mg/m^3^ were significantly greater than those of the chamber controls (Table 3 and Table G-1). Absolute and relative liver weights of males exposed to 2.5 mg/m^3^ or greater and absolute liver weights of females exposed to 5 mg/m^3^ or greater were significantly less than those of the chamber controls. The relative liver weight of 20 mg/m^3^ females was significantly greater than that of the chamber controls. Absolute kidney and thymus weights of males exposed to 10 mg/m^3^ and females exposed to 20 mg/m^3^.

Table 3 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
Male
n | 5 | 5 | 5 | 5 | 0 | 0
Necropsy body wt | 144 ± 3 | 144 ± 2 | 140 ± 4 | 115 ± 6** | – | –
L. Kidney
Absolute | 0.61 ± 0.02 | 0.61 ± 0.01 | 0.58 ± 0.01 | 0.52 ± 0.02** | – | –
Relative | 4.25 ± 0.06 | 4.26 ± 0.08 | 4.12 ± 0.09 | 4.57 ± 0.10* | – | –
Liver
Absolute | 5.84 ± 0.16 | 5.10 ± 0.09** | 5.08 ± 0.15** | 4.29 ± 0.24** | – | –
Relative | 40.61 ± 0.46 | 35.40 ± 0.28** | 36.35 ± 0.63** | 37.43 ± 0.86** | – | –
Lung
Absolute | 1.14 ± 0.10 | 1.16 ± 0.08 | 1.19 ± 0.04 | 1.28 ± 0.12 | – | –
Relative | 7.91 ± 0.61 | 8.07 ± 0.55 | 8.49 ± 0.30 | 11.13 f± 0.50** | – | –
L. Testis
Absolute | 0.886 ± 0.040 | 0.928 ± 0.017 | 0.852 ± 0.035 | 0.590 ± 0.088** | – | –
Relative | 6.165 ± 0.246 | 6.446 ± 0.155 | 6.103 ± 0.248 | 5.053 ± 0.502 | – | –
Thymus
Absolute | 0.374 ± 0.013 | 0.358 ± 0.025 | 0.358 ± 0.007 | 0.284 ± 0.008** | – | –
Relative | 2.605 ± 0.054 | 2.485 ± 0.161 | 2.560 ± 0.023 | 2.498 ± 0.112 | – | –
Female
n | 5 | 5 | 5 | 5 | 2 | 0
Necropsy body wt | 112 ± 4 | 112 ± 2 | 107 ± 3 | 98 ± 4** | 61 ± 5** | –
L. Kidney
Absolute | 0.52 ± 0.02 | 0.50 ± 0.01 | 0.50 ± 0.02 | 0.46 ± 0.01* | 0.35 ± 0.00** | –
Relative | 4.66 ± 0.11 | 4.46 ± 0.05 | 4.63 ± 0.08 | 4.74 ± 0.12 | 5.75 ± 0.42** | –
Liver
Absolute | 4.07 ± 0.16 | 3.77 ± 0.05 | 3.61 ± 0.13** | 3.44 ± 0.05** | 2.57 ± 0.06** | –
Relative | 36.37 ± 0.49 | 33.59 ± 0.16 | 33.78 ± 1.08 | 35.17 ± 1.00 | 42.15 ± 2.12** | –
Lung
Absolute | 0.86 ± 0.04 | 0.83 ± 0.01 | 0.91 ± 0.04 | 1.03 ± 0.06* | 1.01 ± 0.04* | –
Relative | 7.71 ± 0.36 | 7.44 ± 0.07 | 8.49 ± 0.34 | 10.54 ± 0.69** | 16.54 ± 0.56** | –
Thymus
Absolute | 0.317 ± 0.016 | 0.324 ± 0.011 | 0.352 ± 0.022 | 0.289 ± 0.011 | 0.064 ± 0.016** | –
Relative | 2.842 ± 0.167 | 2.895 ± 0.126 | 3.289 ± 0.201 | 2.948 ± 0.092 | 1.024 ± 0.178** | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data are available for 20 mg/m^3^ males or 40 mg/m^3^ males or females due to 100% mortality and the relative thymus weights of females exposed to 20 mg/m^3^ were significantly less than those of the chamber controls. Absolute testis weight of the 10 mg/m^3^group was significantly less than that of the chamber controls; no histopathologic assessment was performed.

Increased incidences of nonneoplastic lesions of the lung occurred in exposed male and female rats, and the lesions were generally of minimal to mild severity (Table 4). The incidences of minimal to moderate hemorrhage were significantly increased in male rats exposed to 20 or 40 mg/m^3^ and females exposed to 40 mg/m^3^. Hemorrhage was observed in rats that died or were killed moribund and consisted of erythrocytes within the alveoli. Incidences of minimal to mild acute inflammation were significantly increased in males exposed to 20 or 40 mg/m^3^ and females exposed to 40 mg/m^3^. Inflammation consisted of proteinaceous fluid (edema) and infiltrates of neutrophils within the alveolar septa and spaces. Incidences of minimal to mild alveolar epithelium hyperplasia were increased in male and female rats exposed to 20 or 40 mg/m^3^; the incidence in 40 mg/m^3^ males was significantly increased. Hyperplasia consisted of focal, variably sized proliferation of the cuboidal to polygonal epithelial (Type II) cells along the alveolar septa; cell nuclei varied from round to pleomorphic. Incidences of alveolus histiocytic cellular infiltration were generally significantly increased in males exposed to 5 mg/m^3^ or greater and in females exposed to 20 or 40 mg/m^3^. Histiocyte infiltration consisted of increased numbers of foamy histiocytes (macrophages) within alveolar spaces. Incidences of cytoplasmic vacuolization of bronchiolar epithelium were significantly increased in 2.5, 5, or 10 mg/m^3^ males and females. Affected bronchiolar epithelial cells were enlarged and had a foamy appearance due to the accumulation of poorly demarcated cytoplasmic vacuoles. Incidences of necrosis of the bronchiolar epithelium were increased in males exposed to 20 or 40 mg/m^3^ and in females exposed to 10 mg/m^3^ or greater. Necrosis consisted of segmental to complete loss of the epithelium in terminal bronchioles; in some cases the remaining epithelial cells appeared hypereosinophilic. Minimal to moderate randomly scattered areas of interstitial fibrosis of the alveolar septa were associated with areas of inflammation and alveolar epithelium hyperplasia in males and females exposed to 10 or 20 mg/m^3^. Fibrosis consisted of irregular expansion of the interstitium of the alveolar septa by variable amounts of collagen fibers.

Table 4 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Rats in the Two-week Inhalation Study of Cobalt Metal

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
Male
Lung^a^ | 5 | 5 | 5 | 5 | 5 | 5
Hemorrhage^b^ | 0 | 0 | 0 | 1 (1.0)^c^ | 5** (1.2) | 5** (3.0)
Inflammation, Acute | 0 | 0 | 0 | 0 | 4* (1.3) | 5** (2.0)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 3 (1.7) | 5** (1.4)
Alveolus, Infiltration Cellular, Histiocyte | 0 | 0 | 4* (1.0) | 3 (1.3) | 5** (2.0) | 5** (1.2)
Bronchiole, Epithelium, Vacuolization Cytoplasmic | 0 | 5** (1.2) | 5** (1.6) | 5**(2.0) | 1 (2.0) | 0
Bronchiole, Epithelium, Necrosis | 0 | 0 | 0 | 0 | 2 (1.0) | 3 (1.0)
Interstitium, Fibrosis | 0 | 0 | 0 | 5** (1.2) | 2 (3.0) | 0
Nose | 5 | 5 | 5 | 5 | 5 | 5
Olfactory Epithelium, Necrosis | 0 | 3 (1.0) | 4* (1.3) | 4* (1.0) | 4* (2.8) | 5** (3.0)
Olfactory Epithelium, Atrophy | 0 | 5** (1.6) | 5** (1.8) | 5** (2.4) | 3 (1.7) | 3 (1.7)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 1 (1.0) | 3 (1.3) | 5** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 2 (1.0) | 1 (1.0)
Female
Lung | 5 | 5 | 5 | 5 | 5 | 5
Hemorrhage | 0 | 0 | 0 | 0 | 3 (2.0) | 5** (2.8)
Inflammation, Acute | 0 | 0 | 0 | 0 | 2 (1.0) | 5** (1.4)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 2 (1.0)
Alveolus, Infiltration Cellular, Histiocyte | 0 | 0 | 0 | 0 | 5** (2.0) | 5** (1.8)
Bronchiole, Epithelium, Vacuolization Cytoplasmic | 0 | 4* (1.0) | 5** (1.0) | 5** (1.8) | 3 (1.7) | 0
Bronchiole, Epithelium, Necrosis | 0 | 1 (1.0) | 1 (1.0) | 4* (1.0) | 3 (1.0) | 3 (1.0)
Interstitium, Fibrosis | 0 | 0 | 0 | 4* (1.0) | 3 (3.0) | 0
Nose | 5 | 5 | 5 | 5 | 5 | 5
Olfactory Epithelium, Necrosis | 0 | 5** (1.0) | 3 (1.0) | 5** (1.0) | 5** (2.0) | 5** (3.0)
Olfactory Epithelium, Atrophy | 0 | 5** (1.8) | 5** (2.0) | 5** (2.0) | 4* (2.8) | 1 (2.0)
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 5** (1.4) | 5** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 1 (1.0) | 0

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Increased incidences of nonneoplastic lesions of the nose occurred in exposed male and female rats (Table 4). Incidences of minimal to moderate olfactory epithelium necrosis were significantly increased in most exposed groups of rats. Necrosis consisted of vacuolization and disorganization of the olfactory epithelium lining the dorsal meatus in Levels II and III nasal sections and the medial surface of ethmoturbinates in Level III; in some cases there was partial or complete loss of the epithelium. The incidences of olfactory epithelium atrophy were significantly increased in all groups of rats exposed to 2.5, 5, or 10 mg/m^3^ and in females exposed to 20 mg/m^3^. Atrophy accompanied necrosis and appeared as decreased numbers of layers and density of olfactory epithelial cells in the areas adjacent to necrosis. The remaining olfactory cells were often disorganized with clear spaces between rows of neuronal and sustentacular epithelial cells. The incidences of respiratory epithelium necrosis were significantly increased in 40 mg/m^3^ males and females exposed to 20 or 40 mg/m^3^. Necrosis was a subtle lesion characterized by focal degeneration and loss of the mucosal epithelium; in some cases, a decrease in the height (atrophy) of the epithelium resulted. In some areas, a single layer of flat epithelial cells covered areas of degenerated epithelium and was considered an attempt at epithelial regeneration. In a few other areas, a thin layer of squamous epithelium replaced the olfactory and respiratory epithelia and was diagnosed as respiratory epithelium squamous metaplasia.

#### Tissue Burden Studies

Tissue weights and concentrations were determined in male and female rats at terminal kill and in additional female rats held for 3 weeks postexposure (Appendix I). Data were generated on male rats exposed to 10 mg/m^3^ or less due to mortality at 20 mg/m^3^. In females, data were generated on all exposure groups; however, a relatively small number of samples (n = 1 to 3) was available in 20 mg/m^3^ females due to decreased survival.

Male and female rat lung weights increased with increasing exposure concentration at terminal kill and in females held for the 3-week recovery period (Table I-1); these increases were significant at higher exposure concentrations in females. In general, kidney, liver, heart, and femur weights decreased with increasing exposure concentration in males and females; some of these decreases were significant at higher exposure concentrations. In males exposed to 10 mg/m^3^, testis weights were decreased in comparison to chamber controls. Because of the significant changes in female lung weights, lung burdens rather than concentrations were evaluated for toxicokinetic parameters.

At terminal kill, cobalt concentrations and burdens increased with increasing exposure concentration in all tissues examined (Table I-1). In general, normalized burdens did not increase with increasing exposure concentration, with the exception of the liver in males and females. Cobalt concentrations in tissues decreased in the order of lung > liver > kidney > femur > heart > serum > blood ~ testes (males). Cobalt burdens in the tissues of male and female rats decreased in the order of liver > lung > kidney > heart > femur ~ testes (males). These data indicate that the tissues examined tended to accumulate cobalt at concentrations greater than could be found in blood and serum, that cobalt was distributed to extra-pulmonary tissues, and that more cobalt accumulated in the liver than in the lung, particularly at the higher concentrations. At 3 weeks postexposure in female rats, cobalt concentrations were markedly reduced in blood, serum, and lung.

Kinetic analysis of data from female rats exposed to 20 mg/m^3^ or less indicated elimination half-lives of 9.2 to 11.1 days (blood), 2.8 to 3.4 days (serum; 10 and 20 mg/m^3^ only, due to undetectable serum concentrations of cobalt at lower exposure concentrations at 3 weeks postexposure) and 4.2 to 5.6 days (lung) (Table I-2). Lung cobalt deposition rates and predicted steady-state lung cobalt burdens generally increased less than proportionally across exposure concentrations except when comparing 10 and 20 mg/m^3^.

In general, the volume of urine collected from male and female rats during the 16-hour collection period after exposure on day 12 decreased with increasing exposure concentration (Table I-3). Increased creatinine concentrations were observed in both sexes in the higher exposure concentration groups. Urinary cobalt concentration increased with increasing exposure concentration in both sexes. When normalized to creatinine, cobalt concentrations increased approximately in proportion to exposure concentration. Total cobalt excreted increased with exposure at lower concentrations before decreasing at higher concentrations.

Exposure Concentration Selection Rationale: Based on significant mortality in male and female rats exposed to 20 and 40 mg/m^3^ and body weight reductions in the 10 mg/m^3^ groups coupled with reduced urine volumes with concomitant increases in urine creatinine at the end of the 2-week study, 5 mg/m^3^ was selected as the highest exposure concentration for the 3-month inhalation study in rats. The lesions in the nose were minimal in the 5 mg/m^3^ group and were not considered sufficiently severe to preclude the use of this concentration. When exposure concentrations for the 3-month studies are different for two species, NTP has elected to have one less exposure concentration for one species as opposed to adding an extra chamber to accommodate the differences in species. Hence, only four concentrations were used in the 3-month rat studies.

### Three-month Study

All male and female rats survived to the end of the study (Table 5). The final mean body weights of males and females exposed to 5 mg/m^3^ were significantly less than those of the chamber controls, and the mean body weight gain of 5 mg/m^3^ males was significantly less than that of the chamber controls (Table 5 and Figure 1). There were no clinical signs related to cobalt metal exposure. At necropsy, pale foci were noted in the lungs of most exposed male and female rats. Based on reports in the literature describing the ability of cobalt to decrease hepatic cytochrome P450 levels and activity,^9^ these enzymes were assayed in the current study. On days 26 and 40, microsomal suspensions of liver samples from special study female rats not used for tissue burden studies were prepared and acetanilide-4-hydroxylase (A4H), 7-ethoxyresorufin-O-deethylase (EROD), and 7-pentoxyresorufin-O-deethylase (PROD) activities were determined (Table J-1). There were no consistent trends in A4H, EROD, or PROD activities relative to exposure concentrations at either time point.

Table 5 Survival and Body Weights of Rats in the Three-month Inhalation Study of Cobalt Metal^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 107 ± 2 | 319 ± 5 | 212 ± 4
0.625 | 10/10 | 107 ± 3 | 336 ± 6 | 229 ± 4 | 105
1.25 | 10/10 | 107 ± 2 | 327 ± 7 | 220 ± 6 | 102
2.5 | 10/10 | 107 ± 3 | 326 ± 6 | 220 ± 5 | 102
5 | 10/10 | 107 ± 3 | 297 ± 5* | 190 ± 4** | 93
Female
0 | 10/10 | 88 ± 3 | 201 ± 3 | 113 ± 4
0.625 | 10/10 | 88 ± 3 | 205 ± 4 | 117 ± 5 | 102
1.25 | 10/10 | 89 ± 3 | 198 ± 4 | 109 ± 2 | 98
2.5 | 10/10 | 88 ± 2 | 199 ± 4 | 111 ± 3 | 99
5 | 10/10 | 87 ± 2 | 187 ± 3* | 100 ± 4 | 93

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 3 months/number initially in group.

Figure 1

Growth Curves for Rats Exposed to Cobalt Metal by Inhalation for Three Months

The hematology and clinical chemistry data for rats are presented in Table 6 and Table F-1. Erythrocytosis characterized by exposure concentration-related increases in the hemoglobin concentration, erythrocyte count, hematocrit value, and manual packed cell volume occurred in males exposed to 2.5 and 5 mg/m^3^ on days 3 and 23 and all exposed groups by week 14; at week 14, female rats also had increases in these parameters. Animals in the lower exposure groups demonstrated these increases but less consistently. In addition, reticulocyte counts were increased in 5 mg/m^3^ males at all three time points, while in the female rats, reticulocyte counts were increased in all exposed groups on day 23 and in the 2.5 and 5 mg/m^3^ groups at week 14. At week 14, platelet counts were mildly (<18%) decreased in all of the exposed groups of females and in males exposed to 1.25 mg/m^3^ or greater. These platelet count changes may represent an altered peripheral distribution or decreased production. All other hematology changes observed were considered within biological variability and not toxicologically relevant.

Table 6 Selected Clinical Pathology Data for Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 9 | 10
Week 14 | 10 | 10 | 10 | 10 | 10
Hematocrit (spun) (%)
Day 3 | 46.5 ± 0.2 | 46.4 ± 0.2 | 47.4 ± 0.2* | 47.7 ± 0.3** | 51.2 ± 0.4**
Day 23 | 47.9 ± 0.4 | 48.5 ± 0.4 | 49.9 ± 0.5** | 51.1 ± 0.2** | 53.3 ± 0.4**
Week 14 | 49.6 ± 0.4 | 51.6 ± 0.4** | 59.2 ± 0.4** | 61.8 ± 0.2** | 63.9 ± 0.3**
Packed cell volume (mL/dL)
Day 3 | 45.1 ± 0.2 | 44.5 ± 0.3 | 45.7 ± 0.3 | 46.1 ± 0.4* | 49.7 ± 0.4**
Day 23 | 46.8 ± 0.4 | 47.3 ± 0.4 | 49.0 ± 0.6** | 49.7 ± 0.2** | 51.5 ± 0.5**
Week 14 | 49.6 ± 0.5 | 51.7 ± 0.4** | 58.3 ± 0.4** | 60.7 ± 0.1** | 62.9 ± 0.3**
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.1 | 13.8 ± 0.1 | 14.1 ± 0.1** | 14.2 ± 0.1** | 15.5 ± 0.1**
Day 23 | 15.0 ± 0.1 | 14.9 ± 0.1 | 15.4 ± 0.2 | 15.8 ± 0.1** | 16.1 ± 0.2**
Week 14 | 15.6 ± 0.1 | 16.3 ± 0.1** | 18.7 ± 0.1** | 19.7 ± 0.1** | 20.3 ± 0.1**
Erythrocytes (10^6^/µL)
Day 3 | 7.30 ± 0.06 | 7.27 ± 0.09 | 7.46 ± 0.05 | 7.57 ± 0.08* | 8.22 ± 0.08**
Day 23 | 7.97 ± 0.09 | 8.05 ± 0.09 | 8.36 ± 0.11* | 8.44 ± 0.06** | 9.27 ± 0.14**
Week 14 | 9.19 ± 0.10 | 9.67 ± 0.09** | 11.20 ± 0.06** | 11.80 ± 0.06** | 11.90 ± 0.08**
Reticulocytes (10^3^/µL)
Day 3 | 612.0 ± 42.3 | 562.3 ± 24.5^b^ | 613.0 ± 30.8 | 622.1 ± 25.6 | 873.8 ± 53.4**
Day 23 | 262.9 ± 13.9 | 261.3 ± 17.8 | 280.9 ± 14.3 | 291.6 ± 18.6 | 339.6 ± 25.1*
Week 14 | 219.8 ± 16.0 | 191.7 ± 19.9 | 189.3 ± 13.1 | 272.7 ± 18.7 | 360.0 ± 35.9*
Platelets (10^3^/µL)
Day 3 | 899.7 ± 14.0 | 883.5 ± 23.9 | 939.4 ± 14.4 | 903.8 ± 22.8 | 1,123.7 ± 34.2**
Day 23 | 740.8 ± 16.2 | 712.0 ± 16.3 | 732.1 ± 22.7 | 682.0 ± 44.5 | 796.7 ± 12.8
Week 14 | 682.5 ± 27.7 | 646.8 ± 8.7 | 611.2 ± 13.8* | 548.2 ± 22.3** | 573.2 ± 15.3**
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10
Total protein (g/dL)
Day 3 | 6.1 ± 0.1 | 5.9 ± 0.0 | 6.0 ± 0.0 | 6.1 ± 0.1 | 6.3 ± 0.1*
Day 23 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1
Week 14 | 7.4 ± 0.1 | 7.3 ± 0.0 | 7.4 ± 0.1 | 7.3 ± 0.1 | 7.1 ± 0.1**
Albumin (g/dL)
Day 3 | 4.3 ± 0.0 | 4.1 ± 0.0** | 4.2 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0
Day 23 | 4.6 ± 0.1 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0
Week 14 | 4.9 ± 0.1 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0
Globulin (g/dL)
Day 3 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 2.0 ± 0.0**
Day 23 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.1 ± 0.1 | 2.0 ± 0.0 | 2.0 ± 0.0
Week 14 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.3 ± 0.0**
Cholesterol (mg/dL)
Day 3 | 95 ± 2 | 87 ± 1* | 84 ± 1** | 79 ± 2** | 81 ± 2**
Day 23 | 79 ± 1 | 76 ± 2 | 70 ± 1** | 73 ± 2** | 63 ± 1**
Week 14 | 91 ± 1 | 91 ± 1 | 88 ± 2 | 79 ± 2** | 67 ± 1**
Glucose (mg/dL)
Day 3 | 135 ± 2 | 138 ± 1 | 134 ± 2 | 136 ± 1 | 129 ± 4
Day 23 | 132 ± 3 | 132 ± 4 | 143 ± 9 | 139 ± 8 | 120 ± 2
Week 14 | 126 ± 3 | 128 ± 3 | 118 ± 5* | 111 ± 3** | 104 ± 4**
Female
n | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (spun) (%)
Day 3 | 49.0 ± 0.6 | 47.8 ± 0.7 | 47.6 ± 0.5 | 48.9 ± 0.3 | 49.9 ± 0.5
Day 23 | 51.6 ± 0.5 | 50.9 ± 0.3 | 51.0 ± 0.3 | 52.0 ± 0.2 | 53.3 ± 1.9**
Week 14 | 48.3 ± 0.5 | 48.7 ± 0.4 | 52.6 ± 0.6** | 57.3 ± 0.5** | 59.5 ± 0.3**
Packed cell volume (mL/dL)
Day 3 | 47.6 ± 0.6 | 46.7 ± 0.6 | 46.5 ± 0.5 | 47.6 ± 0.3 | 48.3 ± 0.5
Day 23 | 51.3 ± 0.5 | 50.2 ± 0.3 | 50.5 ± 0.3 | 51.0 ± 0.3 | 51.7 ± 1.7
Week 14 | 49.1 ± 0.5 | 49.5 ± 0.4 | 53.1 ± 0.5** | 57.1 ± 0.5** | 60.0 ± 0.4**
Hemoglobin (g/dL)
Day 3 | 14.8 ± 0.2 | 14.4 ± 0.2 | 14.5 ± 0.2 | 14.7 ± 0.1 | 15.2 ± 0.2
Day 23 | 16.1 ± 0.1 | 15.8 ± 0.1 | 16.0 ± 0.1 | 16.2 ± 0.1 | 16.4 ± 0.6*
Week 14 | 15.5 ± 0.2 | 15.8 ± 0.1* | 16.9 ± 0.2** | 18.3 ± 0.1** | 19.1 ± 0.1**
Erythrocytes (10^6^/µL)
Day 3 | 7.79 ± 0.12 | 7.62 ± 0.13 | 7.65 ± 0.09 | 7.77 ± 0.08 | 8.07 ± 0.12
Day 23 | 8.49 ± 0.09 | 8.24 ± 0.07 | 8.43 ± 0.10 | 8.56 ± 0.05 | 8.75 ± 0.31*
Week 14 | 8.55 ± 0.09 | 8.69 ± 0.06 | 9.30 ± 0.10** | 10.05± 0.07** | 10.47 ± 0.09 **
Reticulocytes (10^3^/µL)
Day 3 | 489.3 ± 22.4 | 497.7 ± 30.8 | 544.1 ± 28.1 | 511.9 ± 25.5 | 520.0 ± 23.6
Day 23 | 184.1 ± 11.1 | 244.2 ± 9.9** | 212.9 ± 12.4* | 276.7 ± 18.9** | 386.6 ± 20.4**
Week 14 | 202.5 ± 13.0 | 224.5 ± 13.0 | 222.2 ± 8.8 | 246.5 ± 10.8* | 316.7 ± 25.0**
Platelets (10^3^/µL)
Day 3 | 905.6 ± 27.8 | 841.4 ± 22.5 | 914.7 ± 18.8 | 912.4 ± 20.1 | 875.0 ± 27.4
Day 23 | 783.1 ± 20.5 | 799.2 ± 13.2 | 763.0 ± 25.7 | 800.7 ± 21.5 | 807.9 ± 22.2
Week 14 | 702.1 ± 8.0 | 660.2 ± 14.7* | 646.6 ± 17.3** | 575.3 ± 16.7**^b^ | 608.0 ± 16.8**
Clinical Chemistry
Total protein (g/dL)
Day 3 | 6.2 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.0
Day 23 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1
Week 14 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.4 ± 0.1 | 7.4 ± 0.1* | 7.0 ± 0.1**
Albumin (g/dL)
Day 3 | 4.6 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0
Day 23 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.1
Week 14 | 5.3 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.0 | 5.0 ± 0.1**
Globulin (g/dL)
Day 3 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.7 ± 0.1 | 1.6 ± 0.0 | 1.8 ± 0.0**
Day 23 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 1.9 ± 0.0 | 1.9 ± 0.1
Week 14 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.1 | 2.3 ± 0.0 | 2.1 ± 0.1**
Cholesterol (mg/dL)
Day 3 | 98 ± 2 | 95 ± 2 | 91 ± 2* | 91 ± 2* | 93 ± 2
Day 23 | 102 ± 3 | 97 ± 2 | 97 ± 2 | 93 ± 3* | 89 ± 3**
Week 14 | 102 ± 3 | 100 ± 2 | 92 ± 3* | 91 ± 3** | 76 ± 2**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

At week 14, total protein concentrations were mildly decreased (<10%) in 2.5 and 5 mg/m^3^ females, as well as 5 mg/m^3^ males. This change was paired with mild decreases in albumin and globulin concentrations in 5 mg/m^3^ females and a mild decrease in globulin concentration in 5 mg/m^3^ males. These changes are most likely related to altered food intake compared to concurrent chamber controls and are supported by the mild decreases (7%) in body weights of 5 mg/m^3^ males and females. Exposure concentration-dependent decreases in cholesterol concentrations were observed at all three time points in both males and females. While this change was not always observed with the lower exposure concentrations, these decreases were consistently observed in the 2.5 and 5 mg/m^3^ groups of both sexes on day 23 and at week 14. In addition, glucose concentration was decreased in 1.25 mg/m^3^ or greater males at week 14. All other biochemical changes were transient or inconsistent and not considered toxicologically relevant.

Absolute and relative lung weights of all exposed groups of males and females were significantly greater than those of the chamber controls (Table G-2). The increased lung weights are related to the histopathologic changes observed in the lungs.

Sperm motility was significantly decreased in males exposed to 1.25, 2.5, or 5 mg/m^3^, and the decrease in the 5 mg/m^3^ group was approximately 8% (Table 7 and Table H-1). The Markov transition matrix analyses of estrous cyclicity indicated that females in the 5 mg/m^3^ group had a significantly higher probability of extended diestrus than the chamber control females (Table H-2 and Table H-3; Figure H-1). The toxicologic significance of this subtle alteration in the estrous cycle is unclear and there were no cobalt-related histopathologic findings observed in the female reproductive organs.

Table 7 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 319 ± 5 | 327 ± 7 | 326 ± 6 | 297 ± 5*
L. Cauda epididymis | 0.1741 ± 0.0054 | 0.1775 ± 0.0043 | 0.1853 ± 0.0075 | 0.1688 ± 0.0038
L. Epididymis | 0.4850 ± 0.0095 | 0.4999 ± 0.0117 | 0.4926 ± 0.0146 | 0.4846 ± 0.0116
L. Testis | 1.3700 ± 0.0179 | 1.3680 ± 0.0147 | 1.3778 ± 0.0205 | 1.3947 ± 0.0124
Spermatid measurements
Spermatid heads (10^6^/testis) | 174.00 ± 10.16 | 180.00 ± 10.06 | 176.50 ± 5.81 | 172.50 ± 5.94
Spermatid heads (10^6^/g testis) | 141.3 ± 8.7 | 146.5 ± 8.2 | 142.5 ± 3.7 | 139.9 ± 4.8
Epididymal spermatozoal measurements
Sperm motility (%) | 88.8 ± 0.8 | 86.0 ± 1.1* | 83.8 ± 1.3** | 81.9 ± 1.3**
Sperm (10^6^/cauda epididymis) | 104.52 ± 3.78 | 98.40 ± 3.13 | 102.27 ± 3.04 | 94.15 ± 3.18
Sperm (10^6^/g cauda epididymis) | 602.3 ± 21.6 | 556.4 ± 19.3 | 564.1 ± 37.0 | 559.4 ± 19.6

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test (body weight) or Shirley’s test (sperm motility).

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid, sperm/cauda epididymis, and sperm/g cauda epididymis).

In the lung, a spectrum of nonneoplastic lesions was observed that included chronic active inflammation, alveolus proteinosis, bronchiole epithelium hyperplasia, and alveolar epithelium hyperplasia (Table 8). Minimal to mild chronic active inflammation and generally minimal to mild alveolus proteinosis occurred in all exposed males and females, and minimal to mild bronchiole epithelium hyperplasia occurred in all males and females exposed to 1.25 mg/m^3^ or greater. The severities of these lesions generally increased with increasing exposure concentration. Chronic active inflammation consisted of a mixture of macrophages, neutrophils, and lymphocytes in the alveolar spaces and was sometimes associated with minimal hyperplasia of the alveolar epithelium and minimal fibrosis of the alveolar interstitium. At higher exposure concentrations, the inflammatory cells were more diffusely distributed throughout the lung. However, at the lower exposure concentrations, the inflammatory cells tended to occur in focal, subpleural aggregates. The pale foci noted grossly at necropsy correlated with subpleural inflammation. There were also perivascular and peribronchiolar infiltrates of macrophages, neutrophils, and lymphocytes with extension into the adjacent alveoli. Some males and females exposed to 5 mg/m^3^ had minimal infiltrates of inflammatory cells in the walls of bronchioles with minimal proliferation of fibrovascular tissue into the lumen. Alveolar proteinosis consisted of clumps of dense amorphous eosinophilic material or less dense, more dispersed accumulations of proteinaceous debris within the alveolar spaces. Alveoli also contained increased numbers of macrophages that contained eosinophilic material similar to that in the alveolar spaces. Hyperplasia of bronchiolar epithelium was characterized by proliferation of the epithelial cells lining terminal bronchioles and alveolar ducts. The hyperplastic cells were cuboidal with increased cytoplasm that sometimes contained poorly defined cytoplasmic vacuoles.

Table 8 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Rats in the Three-month Inhalation Study of Cobalt Metal

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Lung^a^ | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active^b^ | 0 | 10** (1.9)^c^ | 10** (1.9) | 10** (1.5) | 10** (2.4)
Alveolus, Proteinosis | 0 | 10** (1.8) | 10** (2.2) | 10** (2.2) | 10** (2.7)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 10** (1.0) | 10** (1.4) | 10** (2.2)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.5)
Nose | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Degeneration | 0 | 0 | 2 (1.0) | 9** (1.0) | 10** (2.5)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 2 (1.0) | 6** (1.2) | 10** (1.7)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 3 (1.0) | 9** (1.0) | 10** (1.8)
Turbinate, Atrophy | 0 | 0 | 0 | 3 (1.0) | 9** (1.0)
Female
Lung | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active | 2 (1.0) | 10** (1.9) | 10** (1.5) | 10** (1.6) | 10** (2.4)
Alveolus, Proteinosis | 0 | 10** (1.8) | 10** (1.9) | 10** (1.9) | 10** (2.1)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 10** (1.0) | 10** (1.3) | 10** (2.0)
Alveolar Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 1 (1.0)
Nose | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Degeneration | 0 | 0 | 5* (1.0) | 10** (1.0) | 10** (2.5)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 10** (2.2)
Respiratory Epithelium, Hyperplasia | 0 | 1 (1.0) | 0 | 9** (1.0) | 10** (1.8)
Turbinate, Atrophy | 0 | 0 | 0 | 4* (1.0) | 6** (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Minimal alveolar epithelium hyperplasia occurred in low numbers of males and females exposed to 5 mg/m^3^, but the increased incidences of this lesion were not statistically significant (Table 8). Alveolar epithelium hyperplasia was characterized by randomly scattered, focal, irregular proliferations of cuboidal or sometimes ciliated alveolar epithelial cells. Alveolar epithelial hyperplasia is frequently observed in inhalation studies with particulates and may be considered a reparative response and sometimes occurs as a component of inflammatory changes in the lung.

In the nose, a spectrum of nonneoplastic lesions were observed that included olfactory epithelium degeneration and hyperplasia, respiratory epithelium hyperplasia, and turbinate atrophy. The incidences of olfactory epithelium degeneration and minimal to mild respiratory epithelium hyperplasia were significantly increased in males and females exposed to 2.5 or 5 mg/m^3^; the incidence of olfactory epithelium degeneration was also significantly increased in 1.25 mg/m^3^ females (Table 8). In addition, the incidences of olfactory epithelium hyperplasia were significantly increased in 2.5 mg/m^3^ males and 5 mg/m^3^ males and females. Degeneration of the olfactory epithelium was a focal or multifocal lesion that variably involved the epithelium lining the dorsal meatus, ethmoid turbinates, and nasal septa. In affected sites, there was vacuolization and disorganization of the epithelium with variable individual cell necrosis and/or loss of epithelial cells. Olfactory epithelium hyperplasia was characterized by clusters or nests of cells proliferating within or just adjacent to the olfactory epithelium, sometimes with extension into the lamina propria around glandular ducts. The proliferating cells sometimes formed rosettes and had scant cytoplasm and large, round to oval nuclei. Increased incidences of minimal turbinate atrophy occurred in males and females exposed to 2.5 or 5 mg/m^3^; the increases were statistically significant in 2.5 mg/m^3^ females and 5 mg/m^3^ males and females. Respiratory epithelium hyperplasia involved the turbinates and/or lateral walls of the Level I and II nasal sections. Hyperplasia appeared as increased numbers of cells in the respiratory or transitional epithelium resulting in crowding of the cells or an increase in the number of cell layers. The epithelial cells were squamous to cuboidal, usually not ciliated, and some cells were hypertrophied. Turbinate atrophy occurred in all three sections of the nose and was characterized by short and blunt turbinates that had attenuation and/or loss of turbinate bone and interstitial tissue in the lamina propria including the glands, vessels, nerve bundles, and connective tissue, and as a result, the nasal passages appeared wider than normal.

#### Tissue Burden Studies

Lung and liver weights and lung, blood, and liver cobalt concentrations were determined in female rats (Table I-4). Lung weights were increased in all exposed groups starting on day 40 (5 mg/m^3^) or day 61 (2.5 mg/m^3^ or less) and remained greater than those in the chamber controls throughout the exposure and postexposure periods. Because of the significant changes in lung weights with exposure concentration, lung cobalt burdens rather than lung cobalt concentrations were evaluated for toxicokinetic parameters.

Liver weights of exposed groups of females were either decreased or similar to chamber controls at each time point (Table I-4).

Lung cobalt concentrations and burdens increased with increasing exposure concentration and were significantly increased over chamber controls with all exposure concentrations at all time points. By day 26, the concentrations and burdens of cobalt in the lung of all exposed groups appeared to reach steady state and did not change significantly through the end of exposure (day 89) before decreasing rapidly during the first week of the postexposure period and then more slowly until the end of the postexposure period (Table I-4). Lung cobalt concentrations in chamber control animals were at or below the limit of detection (LOD) at all time points. Lung cobalt burden data normalized to exposure concentration indicated increases in burden that were proportional to exposure concentration.

During the 3-month exposure, blood cobalt concentrations in chamber control animals were at or below the LOD at all time points and concentrations in the exposed groups generally increased in proportion to exposure concentration at all time points (Table I-4). Within each exposure concentration, blood cobalt concentrations appeared to be at or near steady state starting from the earliest time point and continuing throughout the exposure period. However, during the recovery period, blood cobalt concentrations fell very rapidly; the largest declines occurred during the first week postexposure. Accordingly, because of the extensive elimination of cobalt from the blood, it was not possible to demonstrate dose proportionality from blood concentration data collected during the recovery period. In addition, it was not possible to fit the blood data to a two-compartment model due to the lack of early sampling times; however, it appears that there were both rapid and slow clearance phases from the blood.

Liver cobalt concentrations in the chamber control group were at or below the LOD, and concentrations and burdens in the exposed groups increased with increasing exposure concentration at both time points (days 26 and 40) (Table I-4). Cobalt concentrations and burdens in the liver of exposed animals were generally lower on day 40 compared to day 26. The normalized liver cobalt burdens were similar across the exposed groups at both time points. At both time points liver cobalt burdens were similar to and in some cases greater than the corresponding lung cobalt burdens.

Pulmonary clearance of cobalt during the recovery period showed a well-defined two-phase elimination profile (Table I-5). The rapid phase exhibited half-lives ranging from 1.8 to 2.6 days and was followed by a slower lung clearance phase with half-lives of 19 to 23 days. A two-compartment clearance model could not be fit to the lung cobalt burden data collected during the 3-month study due to the lack of data collected prior to 5 days of exposure, but a one-compartment model provided an adequate fit to these data (Table I-6). The results indicated that half-lives ranged from 4.7 to 9.0 days.

Exposure Concentration Selection Rationale: There were no significant effects on survival or body weight in the 5 mg/m^3^ groups in the 3-month study. In addition, increases in lung weights, and incidences of nonneoplastic lesions in the nose and lung, and alterations of erythroid parameters were not considered sufficiently severe to preclude exposure at this concentration. Hence, 5 mg/m^3^ was selected as the highest exposure concentration for the 2-year inhalation study in rats.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 9 and in the Kaplan-Meier survival curves (Figure 2). Survival of female rats exposed to 2.5 mg/m^3^ was significantly less than that of the chamber control group.

Table 9 Survival of Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental deaths^a^ | 0 | 0 | 1 | 0
Moribund | 28 | 28 | 27 | 32
Natural deaths | 5 | 2 | 6 | 2
Animals surviving to study termination | 17 | 20 | 16 | 16
Percent probability of survival at end of study^b^ | 34 | 40 | 33 | 32
Mean survival (days)^c^ | 663 | 670 | 677 | 669
Survival analysis^d^ | P = 0.808 | P = 0.796N | P = 0.988N | P = 1.000
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 11 | 20 | 19 | 24
Natural deaths | 4 | 4 | 7 | 1
Animals surviving to study termination | 35 | 26 | 24 | 25^e^
Percent probability of survival at end of study | 70 | 52 | 48 | 50
Mean survival (days) | 688 | 685 | 663 | 672
Survival analysis | P = 0.135 | P = 0.112 | P = 0.038 | P = 0.060

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^174^ is in the chamber control column, and the results of the life table pairwise comparisons^173^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 2

Kaplan-Meier Survival Curves for Rats Exposed to Cobalt Metal by Inhalation for Two Years

#### Body Weights and Clinical Findings

Mean body weights of 2.5 and 5 mg/m^3^ males were at least 10% less than those of the chamber control group after weeks 99 and 12, respectively, and those of 2.5 and 5 mg/m^3^ females were at least 10% less after weeks 57 and 21, respectively (Figure 3; Table 10 and Table 11). Exposure-related clinical findings included abnormal breathing and thinness in male and female rats.

Figure 3

Growth Curves for Rats Exposed to Cobalt Metal by Inhalation for Two Years

Table 10 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of Cobalt Metal

Day | Chamber Control | | 1.25 mg/m^3^ | | | 2.5 mg/m^3^ | | | 5 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 86 | 50 | 86 | 100 | 50 | 85 | 99 | 50 | 86 | 99 | 50
9 | 120 | 50 | 120 | 100 | 50 | 117 | 97 | 50 | 104 | 87 | 50
16 | 150 | 50 | 153 | 102 | 50 | 150 | 100 | 50 | 138 | 92 | 50
23 | 179 | 50 | 184 | 103 | 50 | 182 | 102 | 50 | 169 | 95 | 50
30 | 207 | 50 | 212 | 103 | 50 | 209 | 101 | 50 | 193 | 93 | 50
37 | 231 | 50 | 237 | 103 | 50 | 234 | 101 | 50 | 216 | 94 | 50
44 | 253 | 50 | 258 | 102 | 50 | 254 | 101 | 50 | 235 | 93 | 50
51 | 271 | 50 | 275 | 101 | 50 | 271 | 100 | 50 | 249 | 92 | 50
58 | 286 | 50 | 292 | 102 | 50 | 286 | 100 | 50 | 263 | 92 | 50
65 | 301 | 50 | 307 | 102 | 50 | 302 | 100 | 50 | 277 | 92 | 50
72 | 313 | 50 | 320 | 102 | 50 | 315 | 101 | 50 | 288 | 92 | 50
79 | 326 | 50 | 331 | 102 | 50 | 324 | 99 | 50 | 296 | 91 | 50
86 | 337 | 50 | 342 | 102 | 50 | 334 | 99 | 50 | 305 | 90 | 50
114 | 371 | 50 | 377 | 102 | 50 | 367 | 99 | 50 | 328 | 88 | 50
142 | 398 | 50 | 405 | 102 | 50 | 391 | 98 | 50 | 350 | 88 | 50
170 | 420 | 50 | 425 | 101 | 50 | 410 | 98 | 50 | 359 | 86 | 50
198 | 436 | 50 | 438 | 100 | 50 | 423 | 97 | 50 | 374 | 86 | 50
226 | 454 | 50 | 456 | 101 | 50 | 439 | 97 | 50 | 387 | 85 | 50
254 | 467 | 50 | 469 | 100 | 50 | 454 | 97 | 50 | 397 | 85 | 50
282 | 480 | 50 | 480 | 100 | 50 | 464 | 97 | 50 | 403 | 84 | 50
310 | 490 | 50 | 489 | 100 | 50 | 471 | 96 | 50 | 408 | 83 | 50
338 | 495 | 50 | 495 | 100 | 50 | 475 | 96 | 50 | 409 | 83 | 50
366 | 498 | 50 | 499 | 100 | 50 | 479 | 96 | 50 | 412 | 83 | 50
394 | 512 | 48 | 507 | 99 | 50 | 487 | 95 | 50 | 417 | 82 | 50
422 | 520 | 48 | 515 | 99 | 49 | 493 | 95 | 50 | 417 | 80 | 50
450 | 522 | 47 | 517 | 99 | 48 | 497 | 95 | 50 | 417 | 80 | 50
478 | 527 | 47 | 522 | 99 | 48 | 501 | 95 | 49 | 417 | 79 | 48
506 | 524 | 47 | 523 | 100 | 48 | 500 | 96 | 49 | 415 | 79 | 47
534 | 531 | 45 | 525 | 99 | 48 | 499 | 94 | 49 | 412 | 78 | 46
562 | 533 | 43 | 524 | 98 | 46 | 499 | 94 | 47 | 410 | 77 | 44
590 | 530 | 42 | 513 | 97 | 43 | 494 | 93 | 45 | 409 | 77 | 41
618 | 528 | 38 | 501 | 95 | 38 | 482 | 91 | 40 | 398 | 75 | 39
646 | 510 | 37 | 495 | 97 | 35 | 474 | 93 | 37 | 392 | 77 | 35
660 | 498 | 37 | 479 | 96 | 35 | 463 | 93 | 33 | 381 | 76 | 32
674 | 488 | 33 | 474 | 97 | 30 | 452 | 93 | 32 | 369 | 76 | 32
688 | 490 | 25 | 482 | 99 | 25 | 453 | 92 | 27 | 352 | 72 | 30
702 | 485 | 21 | 472 | 97 | 24 | 429 | 89 | 25 | 355 | 73 | 22
716 | 467 | 20 | 459 | 98 | 21 | 414 | 89 | 19 | 333 | 71 | 20
Mean for Weeks
1–13 | 235 | – | 240 | 102 | – | 236 | 100 | – | 217 | 92 | –
14–52 | 446 | – | 448 | 101 | – | 433 | 97 | – | 379 | 85 | –
53–103 | 510 | – | 500 | 98 | – | 476 | 93 | – | 394 | 77 | –

Table 11 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of Cobalt Metal

Day | Chamber Control | | 1.25 mg/m^3^ | | | 2.5 mg/m^3^ | | | 5 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt (g) | Wt. (% of Controls) | No. of Survivors
1 | 77 | 50 | 78 | 102 | 50 | 77 | 100 | 50 | 78 | 101 | 50
9 | 98 | 50 | 100 | 101 | 50 | 97 | 99 | 50 | 92 | 93 | 50
16 | 115 | 50 | 117 | 102 | 50 | 115 | 100 | 50 | 110 | 95 | 50
23 | 128 | 50 | 132 | 103 | 50 | 130 | 101 | 50 | 126 | 98 | 50
30 | 139 | 50 | 143 | 103 | 50 | 141 | 102 | 50 | 138 | 99 | 50
37 | 148 | 50 | 154 | 104 | 50 | 152 | 103 | 50 | 148 | 100 | 50
44 | 157 | 50 | 163 | 103 | 50 | 161 | 103 | 50 | 156 | 99 | 50
51 | 164 | 50 | 170 | 103 | 50 | 169 | 103 | 50 | 161 | 98 | 50
58 | 170 | 50 | 176 | 104 | 50 | 173 | 102 | 50 | 167 | 98 | 50
65 | 175 | 50 | 182 | 104 | 50 | 181 | 103 | 50 | 172 | 98 | 50
72 | 180 | 50 | 188 | 105 | 50 | 186 | 103 | 50 | 177 | 99 | 50
79 | 185 | 50 | 192 | 104 | 50 | 189 | 102 | 50 | 179 | 97 | 50
86 | 190 | 50 | 197 | 104 | 50 | 195 | 103 | 50 | 182 | 96 | 50
114 | 203 | 50 | 211 | 104 | 50 | 203 | 100 | 50 | 190 | 93 | 50
142 | 215 | 50 | 224 | 104 | 50 | 211 | 98 | 49 | 197 | 91 | 50
170 | 226 | 50 | 233 | 103 | 50 | 218 | 96 | 49 | 204 | 90 | 50
198 | 235 | 50 | 242 | 103 | 50 | 223 | 95 | 49 | 208 | 88 | 50
226 | 243 | 50 | 251 | 103 | 50 | 231 | 95 | 49 | 215 | 88 | 50
254 | 252 | 49 | 260 | 103 | 50 | 240 | 95 | 49 | 220 | 87 | 50
282 | 264 | 49 | 273 | 103 | 50 | 246 | 93 | 49 | 224 | 85 | 50
310 | 272 | 49 | 282 | 104 | 50 | 256 | 93 | 48 | 229 | 84 | 50
338 | 283 | 48 | 295 | 104 | 50 | 261 | 92 | 48 | 233 | 83 | 50
366 | 293 | 48 | 305 | 104 | 50 | 271 | 92 | 48 | 242 | 83 | 50
394 | 305 | 48 | 315 | 103 | 50 | 279 | 91 | 48 | 249 | 82 | 50
422 | 318 | 48 | 325 | 102 | 49 | 287 | 90 | 48 | 257 | 81 | 50
450 | 322 | 48 | 332 | 103 | 49 | 291 | 90 | 48 | 263 | 81 | 50
478 | 328 | 48 | 340 | 104 | 49 | 296 | 90 | 48 | 268 | 82 | 47
506 | 331 | 48 | 344 | 104 | 49 | 299 | 90 | 48 | 272 | 82 | 45
534 | 338 | 46 | 349 | 103 | 48 | 302 | 89 | 47 | 273 | 81 | 44
562 | 344 | 45 | 349 | 101 | 48 | 304 | 88 | 46 | 275 | 80 | 44
590 | 350 | 45 | 354 | 101 | 46 | 303 | 87 | 42 | 274 | 79 | 41
618 | 346 | 44 | 349 | 101 | 41 | 303 | 87 | 37 | 273 | 79 | 38
646 | 344 | 43 | 348 | 101 | 36 | 305 | 89 | 34 | 271 | 79 | 34
660 | 344 | 42 | 347 | 101 | 36 | 303 | 88 | 33 | 269 | 78 | 34
674 | 348 | 39 | 342 | 98 | 35 | 303 | 87 | 32 | 267 | 77 | 31
688 | 350 | 38 | 339 | 97 | 32 | 299 | 85 | 29 | 261 | 75 | 31
702 | 351 | 36 | 338 | 96 | 29 | 294 | 84 | 26 | 255 | 73 | 30
716 | 349 | 36 | 338 | 97 | 26 | 292 | 84 | 24 | 244 | 70 | 29
Mean for Weeks
1–13 | 148 | – | 153 | 103 | – | 151 | 102 | – | 145 | 98 | –
14–52 | 244 | – | 252 | 103 | – | 232 | 95 | – | 213 | 88 | –
53–103 | 335 | – | 338 | 101 | – | 296 | 88 | – | 263 | 79 | –

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of mononuclear cell leukemia and neoplasms and/or nonneoplastic lesions of the lung, nose, adrenal medulla, pancreatic islets, kidney, liver, and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Lung: The incidences of alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and alveolar/ bronchiolar adenoma or carcinoma (combined) occurred with positive trends in male and female rats and with the exception of the incidence of alveolar/bronchiolar adenoma in 1.25 mg/m^3^ females, the incidences were significantly greater than those in the chamber controls (Table 12, Table A-3, and Table B-3). In addition, the incidences of these neoplasms in all exposed groups exceeded the historical control ranges for all routes of administration. Incidences of multiple alveolar/bronchiolar adenoma generally increased with increasing exposure concentrations in males and females. Significantly increased incidences of multiple alveolar/bronchiolar carcinoma occurred in all exposed groups of males and in females exposed to 5 mg/m^3^ (Table 12, Table A-1, and Table B-1). Increased incidences of cystic keratinizing epithelioma occurred in exposed groups of female rats; however, the increases were not statistically significant. In male rats, single incidences of cystic keratinizing epithelioma occurred in the 1.25 and 5 mg/m^3^ exposure groups. One female rat exposed to 5 mg/m^3^ had a squamous cell carcinoma (Table 12 and Table B-1). Cystic keratinizing epithelioma and squamous cell carcinoma have not been observed in the lung of 100 historical controls for all routes of administration (Table 12).

Table 12 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Number Examined Microscopically | 50 | 50 | | 50 | 50
Alveolar Epithelium, Hyperplasia^a^ | 3 (1.0)^b^ | 47** (2.8) | | 49** (3.3) | 49** (3.6)
Alveolus, Proteinosis | 0 | 48** (2.6) | | 49** (2.9) | 49** (3.1)
Inflammation, Chronic Active | 22 (1.1) | 50** (3.0) | | 50** (2.9) | 50** (2.9)
Bronchiole, Epithelium, Hyperplasia | 0 | 44** (1.5) | | 47** (2.7) | 50** (3.7)
Alveolar/bronchiolar Adenoma, Multiple | 1 | 3 | | 2 | 6
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^d^ | 2/50 (4%) | 10/50 (20%) | | 10/50 (20%) | 14/50 (28%)
Adjusted rate^e^ | 5.0% | 24.1% | | 23.3% | 32.5%
Terminal rate^f^ | 1/17 (6%) | 6/20 (30%) | | 2/16 (13%) | 4/16 (25%)
First incidence (days) | 611 | 577 | | 535 | 478
Poly-3 test^g^ | P = 0.011 | P = 0.015 | | P = 0.018 | P < 0.001
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 6* | | 14** | 30**
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 0/50 (0%) | 16/50 (32%) | | 34/50 (68%) | 36/50 (72%)
Adjusted rate | 0.0% | 38.2% | | 76.8% | 80.6%
Terminal rate | 0/17 (0%) | 7/20 (35%) | | 16/16 (100%) | 14/16 (88%)
First incidence (days) | –^i^ | 580 | | 472 | 552
Poly-3 test | P < 0.001 | P < 0.001 | | P < 0.001 | P < 0.001
Alveolar/bronchiolar Adenoma or Carcinoma^j^
Overall rate | 2/50 (4%) | 25/50 (50%) | | 39/50 (78%) | 44/50 (88%)
Adjusted rate | 5.0% | 58.0% | | 84.6% | 93.6%
Terminal rate | 1/17 (6%) | 13/20 (65%) | | 16/16 (100%) | 16/16 (100%)
First incidence (days) | 611 | 577 | | 472 | 478
Poly-3 test | P < 0.001 | P < 0.001 | | P < 0.001 | P < 0.001
Cystic Keratinizing Epithelioma^h^ | 0 | 1 | | 0 | 1
Female
Number Examined Microscopically | 50 | 50 | | 50 | 50
Alveolar Epithelium, Hyperplasia | 9 (1.1) | 49** (2.8) | | 50** (2.7) | 49** (3.4)
Alveolus, Proteinosis | 0 | 50** (2.7) | | 50** (2.7) | 50** (2.9)
Inflammation, Chronic Active | 20 (1.0) | 50** (3.0) | | 50** (2.9) | 50** (2.9)
Bronchiole, Epithelium, Hyperplasia | 0 | 47** (1.5) | | 46** (2.1) | 48** (3.8)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | | 3 | 4
Alveolar/bronchiolar Adenoma (includes multiple)^j^
Overall rate | 2/50 (4%) | 7/50 (14%) | | 9/50 (18%) | 13/50 (26%)
Adjusted rate | 4.5% | 16.2% | | 22.1% | 30.9%
Terminal rate | 1/35 (3%) | 5/26 (19%) | | 6/24 (25%) | 8/25 (32%)
First incidence (days) | 698 | 590 | | 587 | 579
Poly-3 test | P = 0.002 | P = 0.072 | | P = 0.016 | P < 0.001
Alveolar/bronchiolar Carcinoma, Multiple | | | 0 | 4 | 3
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 0/50 (0%) | 9/50 (18%) | | 17/50 (34%) | 30/50 (60%)
Adjusted rate | 0.0% | 21.3% | | 42.0% | 69.2%
Terminal rate | 0/35 (0%) | 9/26 (35%) | | 14/24 (58%) | 20/25 (80%)
First incidence (days) | – | 730 (T) | | 690 | 471
Poly-3 test | P < 0.001 | P < 0.001 | | P < 0.001 | P < 0.001
Alveolar/bronchiolar Adenoma or Carcinoma (combined)^j^
Overall rate | 2/50 (4%) | 15/50 (30%) | | 20/50 (40%) | 38/50 (76%)
Adjusted rate | 4.5% | 34.7% | | 48.5% | 86.2%
Terminal rate | 1/35 (3%) | 13/26 (50%) | | 14/24 (58%) | 25/25 (100%)
First incidence (days) | 698 | 590 | | 587 | 471
Poly-3 test | P < 0.001 | P < 0.001 | | P < 0.001 | P < 0.001
Cystic Keratinizing Epithelioma^h^ | 0 | 4 | | 1 | 2
Squamous Cell Carcinoma^h^ | 0 | 0 | | 0 | 1

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for 2-year studies (all routes): 5/100.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Historical control incidence: 0/100.

^i^ Not applicable; no neoplasms in animal group.

^j^ Historical control incidence: 2/100.

Alveolar/bronchiolar adenomas were discrete, expansile, densely cellular masses that compressed the surrounding lung parenchyma (Figure 7). They were composed of relatively well differentiated, uniform, cuboidal to columnar cells supported by a fine fibrovascular stroma and arranged in solid nests or papillary fronds that projected into alveolar spaces. Alveolar/bronchiolar carcinomas were larger, irregular, poorly circumscribed, unencapsulated, expansile, locally invasive masses that effaced the lung parenchyma (Figure 8). They were composed of poorly differentiated, moderately to markedly pleomorphic (anaplastic) cuboidal, columnar, or polygonal cells with pleomorphic nuclei; occasionally, cells had mitotic figures. The cells were arranged in single to multiple layers, formed irregular papillary or acinar structures and/or solid sheets and were supported by fibrovascular stroma. Some carcinomas had areas of squamous differentiation, and many contained extensive areas of necrosis, desmoplastic tissue, and inflammation (Figure 9). Other carcinomas had a core of dense fibrous tissue with embedded islands of malignant cells arranged in irregular cords, clusters, and acini. In several animals, metastases were observed in other tissues. Cystic keratinizing epitheliomas were well circumscribed, unencapsulated, irregularly expansive masses that effaced the lung parenchyma. The epitheliomas consisted of an irregular wall of well differentiated squamous epithelium surrounding a core of concentrically arranged keratin (Figure 10). Invariably the walls of these neoplasms had areas that lacked orderly maturation with foci of basal cell disorganization. The outer portion of the lesion grew by expansion into the adjacent lung, but evidence of invasion was not observed. The squamous cell carcinoma was an infiltrative mass that obliterated the normal lung architecture. The neoplastic cells formed swirling clusters, often around laminated keratin, separated by small to moderate amounts of fibrous stroma. The cells were polygonal, variable in size and shape, and contained small to moderate amounts of eosinophilic cytoplasm.

Figure 7

Alveolar/Bronchiolar Adenoma in the Lung of a F344/NTac Female Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The adenoma is distinctly demarcated from the surrounding alveolar parenchyma (arrows).

Figure 8

Alveolar/Bronchiolar Carcinoma in the Lung of a F344/NTac Female Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The carcinoma is highly invasive and has effaced the lung parenchyma. Note several areas of necrosis (arrows) within the carcinoma.

Figure 9

Sarcomatous Type Alveolar/Bronchiolar Carcinoma in the Lung of a F344/NTac Female Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The carcinoma is composed mostly of anaplastic spindyloid cells that surround islands of neoplastic epithelial cells (arrows). Note an area of necrosis in the upper right corner of the plate (asterisk).

Figure 10

Cystic Keratinizing Epithelioma in the Lung of a Male F344/NTac Rat Exposed to 1.25 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

This neoplasm is characterized by a central mass of concentrically arranged keratin surrounded by wall of squamous epithelium (arrows).

Point mutations in Kras (31%), Egfr (17%), and Tp53 (23%) were noted in the alveolar/bronchiolar carcinomas in rats chronically exposed to cobalt metal dust. Because there were no spontaneous alveolar/bronchiolar carcinomas in the F344/NTac rats in the concurrent cobalt metal study, spontaneous alveolar/bronchiolar carcinomas were evaluated from F344 rat vehicle control groups in previous NTP chronic bioassays. None of these mutations were noted in the controls.

The incidences of alveolar epithelium hyperplasia, alveolar proteinosis, chronic active inflammation, and bronchiole epithelium hyperplasia in all exposed groups of male and female rats were significantly greater than those in the chamber control groups (Table 12, Table A-7, and Table B-7). The severities of these lesions generally increased with increasing exposure concentration. This spectrum of nonneoplastic lesions invariably occurred together and presented as a complex mix of changes, and at times it was difficult to separate the individual components. Alveolar epithelium hyperplasia was a multifocal and sometimes focally extensive, discrete, randomly distributed but frequently subpleural lesion characterized by proliferation of flat to cuboidal to low columnar epithelial cells (presumed to be Type II pneumocytes).

lining the alveolar septa; however, the underlying alveolar architecture was generally maintained (Figure 11 and Figure 12). The interstitium of the alveolar septa was also variably expanded by increased amounts of collagen. Alveolar proteinosis was characterized by accumulations of brightly eosinophilic, wispy to globular, homogeneous, proteinaceous material filling the alveolar spaces (Figure 13); this proteinaceous material frequently contained acicular cholesterol crystals or cleft-like spaces. These lesions were invariably accompanied by chronic active inflammation which consisted of complex mixtures of predominantly macrophages and lymphocytes mixed with lesser numbers of neutrophils within the alveolar spaces and septa and low numbers of multinucleated giant cells (Figure 14); clear cleft-like spaces (cholesterol clefts) were frequently present among the inflammatory cells. Also associated with areas of chronic active inflammation, there were frequently variable proliferation of the alveolar epithelial (Type II) cells and variable alveolar septal interstitial fibrosis. Frequently, there were large numbers of inflammatory cell infiltrates, mostly macrophages, accumulated around the alveolar/bronchiolar neoplasms. The alveolar macrophages were frequently engorged with an intensely eosinophilic material similar to that in the alveolar spaces, and many macrophages also contained acicular cholesterol crystals. Multifocal accumulations of plump foamy macrophages within the alveolar spaces were considered a component of the inflammation changes. Bronchiole epithelium hyperplasia was characterized by proliferation and disorganized crowding of ciliated, cuboidal columnar to pleomorphic epithelial cells lining terminal bronchioles with extension onto adjacent alveolar septa (Figure 15). There was often minimal to mildly increased amounts of collagen in the interstitium of the bronchiolar wall.

Figure 11

Discrete, Focal Alveolar Epithelial Hyperplasia (Arrows) in the Lung of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Alveolar epithelial hyperplasia is characterized by proliferation of uniformly cuboidal alveolar epithelial (Type II) cells along the alveolar septa. The architecture of the alveolar parenchyma is generally maintained; however, the proliferation cells are forming papillary structures that project into the alveolar spaces. Note macrophages within the alveolar spaces.

Figure 12

Focally Extensive Area of Alveolar Epithelial Hyperplasia (Arrows) in the Lung of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Figure 13

Alveolar Proteinosis in the Lung of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Note the homogenously eosinophilic protein material (arrows) within the alveolar spaces some of which stains brightly eosinophilic.

Figure 14

An Area of Chronic Active Inflammation (Arrows) in the Lung of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The alveoli are filled with mostly macrophages, mixed with lesser numbers of neutrophils and degenerate cellular debris (arrows). Note clear angular cleft-like spaces (cholesterol clefts) among the inflammatory cells and debris. Proliferating alveolar epithelial cells line the alveoli.

Figure 15

Bronchiolar Epithelial Hyperplasia in the Lung of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Increased numbers of disorganized cuboidal to columnar epithelial cells (arrows), some of which are ciliated, line the terminal bronchiole. The proliferating cells have extended to line alveoli immediately adjacent to the bronchiole. Note macrophages within the alveoli.

Nose: A spectrum of nonneoplastic lesions occurred with positive trends in male and female rats, and the incidences were often significantly greater than those in the chamber controls (Table 13, Table A-7, and Table B-7). For some lesions, the severities increased with increasing exposure concentration. Chronic active inflammation was most prominent in Levels I and II and less often in Level III nasal section. Chronic active inflammation consisted of infiltrates of mostly lymphocytes, plasma cells, neutrophils, and fewer macrophages within the lamina propria and overlying epithelium accompanied by cellular debris in the nasal passages. Suppurative inflammation occurred primarily in Level II and consisted of accumulations of nondegenerate and degenerate neutrophils mixed with eosinophilic proteinaceous material, occasional macrophages, cellular debris, and sometimes colonies of coccobacilli and foreign material within the nasal passages and adjacent epithelium and lamina propria of the nasal turbinates (Figure 16). More pronounced suppurative inflammation was often accompanied by florid hyperplasia of the adjacent epithelium.

Table 13 Incidences of Nonneoplastic Lesions of the Nose in Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Number Examined Microscopically | 48 | 47 | 45 | 50
Inflammation, Chronic Active^a^ | 28 (1.2)^b^ | 35* (1.3) | 40** (1.7) | 49** (2.6)
Inflammation, Suppurative | 9 (1.0) | 12 (1.7) | 24** (2.2) | 46** (2.6)
Olfactory Epithelium, Metaplasia, Respiratory | 12 (1.1) | 26** (1.7) | 37** (1.5) | 50** (2.2)
Olfactory Epithelium, Atrophy | 2 (1.0) | 21** (1.0) | 34** (1.0) | 29** (1.2)
Olfactory Epithelium, Hyperplasia | 0 | 1 (1.0) | 2 (1.5) | 7** (1.1)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 1 (1.0) | 0 | 13** (1.0)
Olfactory Epithelium, Necrosis | 0 | 1 (1.0) | 5* (1.6) | 5* (1.8)
Respiratory Epithelium, Hyperplasia | 20 (1.3) | 35** (1.2) | 45** (1.7) | 50** (2.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 1 (1.0) | 11** (1.2) | 35** (1.3)
Respiratory Epithelium, Necrosis | 1 (1.0) | 4 (1.8) | 5 (1.4) | 13** (1.6)
Turbinate, Atrophy | 1 (1.0) | 35** (1.0) | 35** (1.0) | 41** (1.0)
Female
Number Examined Microscopically | 50 | 50 | 49 | 50
Inflammation, Chronic Active | 22 (1.3) | 42** (1.1) | 39** (1.1) | 50** (2.4)
Inflammation, Suppurative | 6 (1.2) | 4 (1.3) | 4 (1.0) | 42** (2.2)
Olfactory Epithelium, Metaplasia, Respiratory | 6 (1.0) | 18** (1.3) | 24** (1.2) | 47** (2.1)
Olfactory Epithelium, Atrophy | 0 | 22** (1.1) | 35** (1.0) | 35** (1.2)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 3 (1.0) | 5* (1.0)
Olfactory Epithelium, Hyperplasia, Basal Cell | 0 | 0 | 1 (1.0) | 19** (1.0)
Olfactory Epithelium, Necrosis | 0 | 2 (1.5) | 0 | 1 (3.0)
Respiratory Epithelium, Hyperplasia | 15 (1.2) | 43** (1.0) | 48** (1.0) | 49** (2.1)
Respiratory Epithelium, Metaplasia, Squamous | 2 (1.0) | 0 | 3 (1.0) | 45** (2.0)
Respiratory Epithelium, Necrosis | 1 (3.0) | 1 (2.0) | 1 (1.0) | 15** (1.6)
Turbinate, Atrophy | 1 (1.0) | 38** (1.0) | 27** (1.0) | 45** (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 16

Suppurative Inflammation in a Nasal Maxilloturbinate in the Level II Section in the Nose of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

There are numerous neutrophils throughout the submucosal tissue of the turbinate (long arrows) and a purely neutrophilic exudate in the nasal passages (arrowheads).

Respiratory metaplasia and/or atrophy of the olfactory epithelium occurred in the dorsal meatuses of Level II and sometimes Level III. When the predominant change in the affected segment was replacement of the olfactory epithelium by respiratory type columnar epithelial cells, olfactory epithelium respiratory metaplasia was diagnosed (Figure 17). When the olfactory epithelium was attenuated due to loss of olfactory epithelial cells, olfactory epithelium atrophy was diagnosed (Figure 18). Olfactory epithelium hyperplasia mostly occurred in rats exposed to 5 mg/m^3^ and consisted of small, focal, intraepithelial proliferations of epithelial cells that formed clusters or rosettes that sometimes extended into the lamina propria (Figure 18). Olfactory epithelium basal cell hyperplasia was invariably associated with olfactory epithelium hyperplasia and consisted of disorganized proliferation and crowding of the basal olfactory epithelial cells. Necrosis of the olfactory epithelium was a minimal to mild lesion mostly affecting male rats and a few females and was associated with inflammatory lesions. In sites of necrosis, the epithelium was effaced and replaced by cellular and karyorrhectic debris.

Figure 17

Respiratory Epithelial Metaplasia of the Olfactory Epithelium of an Ethmoid Turbinate in the Nose of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The normal olfactory epithelium (arrowheads) is replaced by tall ciliated columnar epithelial cells (arrows) similar to respiratory epithelium that lines the naso- and maxilloturbinates.

Figure 18

Olfactory Epithelial Atrophy and Olfactory Epithelial Hyperplasia in the Ethmoid Turbinate in the Nose of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

In contrast to the normal olfactory epithelium (arrowheads), the atrophic epithelium is attenuated (long arrows). Note hyperplastic olfactory epithelium forming rosette-like structures along the lower margins of the atrophic epithelium (short arrows).

Respiratory epithelium hyperplasia occurred in the epithelium lining the tips of the nasoturbinates, maxilloturbinates, and the septa in Levels I and II. In affected sites, the epithelium was thickened by increased numbers of cuboidal to ciliated columnar epithelial cells crowded in multiple layers sometimes forming undulations with invaginations into the underlying lamina propria (Figure 19). This lesion was most prominent in areas of suppurative inflammation. Respiratory epithelium squamous metaplasia was most common at the tips of the nasoturbinates and along the lateral walls of Level I and less often Level II. In affected sites, flattened squamous epithelium of variable thickness replaced the ciliated columnar epithelium normally present in this location (Figure 19). Necrosis of the respiratory epithelium was associated with the inflammatory lesions and primarily affected rats in the 5 mg/m^3^ groups. In areas of necrosis, the epithelium was effaced and replaced by cellular and karyorrhectic debris (Figure 20); necrosis would sometimes extend into the submucosa and sinuses.

Figure 19

Respiratory Epithelial Hyperplasia and Squamous Metaplasia in a Maxilloturbinate in the Nose of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The normal single layer of tall ciliated columnar epithelial cells is replaced by multiple disorganized layers of proliferating epithelial cells (arrows). Squamous metaplasia is characterized by replacement of the normal respiratory epithelium by flattened squamous epithelial cells (arrowheads). There is chronic active inflammation throughout the submucosal tissue.

Figure 20

Necrosis of the Respiratory Epithelium in a Maxilloturbinate in the Nose of a Female F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The epithelium is replaced by a coagulum of necrotic epithelial cells and cellular debris (arrows).

Turbinate atrophy was a minimal to mild change that primarily affected the naso- and maxilloturbinates in Levels I and II and occasionally Level III. Affected turbinates were short, thin, and blunted due to attenuation of the turbinate bone and loss of structures in the lamina propria, including the glands, vessels, nerve bundles, and connective tissue. As a result, the nasal passages appeared wider than normal (Figure 21). The nasal septum was sometimes similarly affected and had a noticeable decrease in width.

Figure 21

Atrophy of the Ethmoid Turbinates in the Nose of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The turbinate scrolls are short, thin, and somewhat blunted, and there is increased space within the nasal passages.

Adrenal Medulla: The incidences of benign pheochromocytoma, malignant pheochromocytoma, and benign or malignant pheochromocytoma (combined) occurred with positive trends in male and female rats and with the exception of the incidence of malignant pheochromocytoma in 2.5 mg/m^3^ females, the incidences in rats exposed to 2.5 or 5 mg/m^3^ were significantly greater than those in the chamber controls and exceeded the historical control incidences for all routes of administration (Table 14, Table A-4, and Table B-4). The incidences of bilateral benign pheochromocytoma were significantly increased in all exposed groups of males and in 2.5 and 5 mg/m^3^ females, and the incidences of bilateral malignant pheochromocytoma were significantly increased in male and female rats exposed to 5 mg/m^3^.

Table 14 Incidences of Neoplasms and Nonneoplastic Lesions of the Adrenal Medulla in Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Hyperplasia^a^ | 19 (2.3)^b^ | 21 (2.5) | 9* (3.0) | 9** (2.4)
Benign Pheochromocytoma, Bilateral | 4 | 13* | 22** | 21**
Benign Pheochromocytoma (includes bilateral)^c^
Overall rate^d^ | 15/50 (30%) | 23/50 (46%) | 37/50 (74%) | 34/50 (68%)
Adjusted rate^e^ | 35.8% | 54.3% | 81.2% | 76.4%
Terminal rate^f^ | 3/17 (18%) | 12/20 60%) | 15/16 (94%) | 14/16 (88%)
First incidence (days) | 519 | 583 | 582 | 572
Poly-3 test^g^ | P < 0.001 | P = 0.059 | P < 0.001 | P < 0.001
Malignant Pheochromocytoma, Bilateral | 0 | 0 | 0 | 7**
Malignant Pheochromocytoma (includes bilateral)^h^
Overall rate | 2/50 (4%) | 2/50 (4%) | 9/50 (18%) | 16/50 (32%)
Adjusted rate | 5.0% | 5.0% | 21.4% | 39.1%
Terminal rate | 0/17 (0%) | 2/20 (10%) | 3/16 (19%) | 9/16 (56%)
First incidence (days) | 668 | 729 (T) | 628 | 646
Poly-3 test | P < 0.001 | P = 0.693N | P = 0.030 | P < 0.001
Benign or Malignant Pheochromocytoma^i^
Overall rate | 17/50 (34%) | 23/50 (46%) | 38/50 (76%) | 41/50 (82%)
Adjusted rate | 40.2% | 54.3% | 82.7% | 90.7%
Terminal rate | 3/17 (18%) | 12/20 (60%) | 15/16 (94%) | 16/16 (100%)
First incidence (days) | 519 | 583 | 582 | 572
Poly-3 test | P < 0.001 | P = 0.130 | P < 0.001 | P < 0.001
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Hyperplasia | 12 (1.8) | 27** (2.0) | 27** (2.3) | 10 (2.8)
Benign Pheochromocytoma, Bilateral | 2 | 4 | 8* | 19**
Benign Pheochromocytoma (includes bilateral)^j^
Overall rate | 6/50 (12%) | 12/50 (24%) | 22/50 (44%) | 36/50 (72%)
Adjusted rate | 13.6% | 27.2% | 52.1% | 80.6%
Terminal rate | 6/35 (17%) | 5/26 (19%) | 13/24 (54%) | 21/25 (84%)
First incidence (days) | 730 (T) | 598 | 590 | 579
Poly-3 test | P < 0.001 | P = 0.091 | P < 0.001 | P < 0.001
Malignant Pheochromocytoma, Bilateral | 0 | 1 | 1 | 4*
Malignant Pheochromocytoma (includes bilateral)^k^
Overall rate | 0/50 (0%) | 2/50 (4%) | 3/50 (6%) | 11/50 (22%)
Adjusted rate | 0.0% | 4.7% | 7.5% | 27.0%
Terminal rate | 0/35 (0%) | 2/26 (8%) | 2/24 (8%) | 9/25 (36%)
First incidence (days) | –^l^ | 730 (T) | 715 | 712
Poly-3 test | P < 0.001 | P = 0.228 | P = 0.102 | P < 0.001
Benign or Malignant Pheochromocytoma^m^
Overall rate | 6/50 (12%) | 13/50 (26%) | 23/50 (46%) | 40/50 (80%)
Adjusted rate | 13.6% | 29.4% | 54.5% | 89.4%
Terminal rate | 6/35 (17%) | 6/26 (23%) | 14/24 (58%) | 24/25 (96%)
First incidence (days) | 730 (T) | 598 | 590 | 579
Poly-3 test | P < 0.001 | P = 0.058 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for 2-year studies (all routes): 25/100.

^d^ Number of animals with neoplasm per number of animals with adrenal medulla examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 2/100.

^i^ Historical control incidence: 27/100.

^j^ Historical control incidence: 7/100.

^k^ Historical control incidence: 1/100.

^l^ Not applicable; no neoplasms in animal group.

^m^ Historical control incidence: 8/100.

Benign pheochromocytoma occurred as variably sized, well-demarcated, expansile proliferations of medullary cells that formed large trabeculae or solid clusters separated by delicate fibrous stroma and/or sinusoids (Figure 22). The cells were polygonal to spindyloid and moderately uniform in size and shape.

Figure 22

Benign Pheochromocytoma in the Adrenal Medulla of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The neoplasm is well-circumscribed and expansive but still within the confines of the adrenal medulla (arrows).

Malignant pheochromocytomas were generally larger, irregular, poorly demarcated invasive masses that effaced the adrenal gland extending through the capsule into the periadrenal tissue; the neoplastic cells were poorly differentiated and pleomorphic (Figure 23). In some animals, malignant pheochromocytomas metastasized to other organs. The incidences of medullary hyperplasia in the adrenal gland were significantly increased in female rats exposed to 1.25 or 2.5 mg/m^3^ (Table 14 and Table B-7); incidences of this lesion were significantly decreased in male rats exposed to 2.5 or 5 mg/m^3^ (Table 14 and Table A-7). Hyperplasia occurred as focally discrete proliferations of medullary epithelial cells that blended with, but did not compress, the surrounding medullary parenchyma. The cells were generally smaller and more basophilic than the surrounding normal medullary epithelial cells.

Figure 23

Malignant Pheochromocytoma in the Adrenal Medulla of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The neoplasm (arrows) is expansive, has replaced the adrenal medulla, and has invaded into and through the adrenal cortex.

Pancreatic Islets: The incidences of carcinoma and adenoma or carcinoma (combined) occurred with positive trends in male rats, and the incidences of adenoma, carcinoma, and adenoma or carcinoma (combined) generally exceeded the historical control incidences for all routes of administration (Table 15, Table A-1, Table A-2, and Table A-5). The incidences of adenoma in 2.5 mg/m^3^ males and of adenoma or carcinoma (combined) in males exposed to 2.5 or 5 mg/m^3^ were significantly greater than those in the chamber controls. Incidences of adenoma, carcinoma, and adenoma or carcinoma (combined) in 5 mg/m^3^ females were slightly increased; the increases were not statistically significant but did exceed the historical control incidences for all routes of administration (Table 15, Table B-1, Table B-2, and Table B-6). Adenomas were well circumscribed, expansile masses that compressed the acini. The neoplastic cells were well differentiated with minimal to mild cellular atypia and slightly altered growth patterns (Figure 24). Carcinomas were poorly circumscribed, unencapsulated, irregular, expansile, and invasive masses that effaced the parenchyma (Figure 25). Carcinomas had a heterogeneous growth pattern with cells that were moderately to markedly pleomorphic.

Table 15 Incidences of Neoplasms of the Pancreatic Islets in Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Adenoma^a^
Overall rate^b^ | 0/50 (0%) | 1/50 (2%) | 6/48 (13%) | 3/49 (6%)
Adjusted rate^c^ | 0.0% | 2.5% | 15.1% | 7.7%
Terminal rate^d^ | 0/17 (0%) | 0/20 (0%) | 1/16 (6%) | 3/16 (19%)
First incidence (days) | –^f^ | 684 | 618 | 729 (T)
Poly-3 test^e^ | P = 0.052 | P = 0.504 | P = 0.015 | P = 0.116
Carcinoma^g^
Overall rate | 2/50 (4%) | 1/50 (2%) | 5/48 (10%) | 6/49 (12%)
Adjusted rate | 5.0% | 2.5% | 12.6% | 15.1%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 3/16 (19%) | 2/16 (13%)
First incidence (days) | 675 | 675 | 618 | 679
Poly-3 test | P=0.021 | P=0.496N | P=0.213 | P=0.129
Adenoma or Carcinoma (combined)^g^
Overall rate | 2/50 (4%) | 2/50 (4%) | 10/48 (21%) | 9/49 (18%)
Adjusted rate | 5.0% | 4.9% | 24.7% | 22.6%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 3/16 (19%) | 5/16 (31%)
First incidence (days) | 675 | 675 | 618 | 679
Poly-3 test | P = 0.002 | P = 0.689N | P = 0.013 | P = 0.022
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Adenoma^h^ | 0 | 0 | 0 | 1 (2%)
Carcinoma^h^ | 1 (2%) | 0 | 0 | 3 (6%)
Adenoma or Carcinoma^g^
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 7.2%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/24 (0%) | 1/25 (4%)
First incidence (days) | 234 | – | – | 506
Poly-3 test | P = 0.060 | P = 0.512N | P = 0.523N | P = 0.279

(T) Terminal kill.

^a^ Historical control incidence for 2-year studies (all routes): 0/100.

^b^ Number of animals with neoplasm per number of animals with pancreatic islets examined microscopically.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^f^ Not applicable; no neoplasms in animal group.

^g^ Historical control incidence for all routes: 2/100.

^h^ Historical control incidence for all routes: 1/100.

Figure 24

Islet Cell Adenoma in the Pancreas of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The adenoma (arrows) is well-circumscribed and expansive and composed of uniformly normal islet cells partially separated into variably sized packets by a delicate fibrovascular stroma.

Figure 25

Islet Cell Carcinoma in the Pancreas of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The carcinoma (arrows) has almost completely replaced the pancreas and invaded adjacent tissue.

Kidney: In the standard evaluation of the kidney, the incidences of renal tubule adenoma, carcinoma, and adenoma or carcinoma (combined) were slightly increased in male rats exposed to 5 mg/m^3^ (Table 16, Table A-1, and Table A-2). Although not statistically significant, the incidences in this group exceeded the historical control incidences for all routes of administration (Table 16 and Table A-6). In the standard evaluation, a single section of each kidney is routinely examined microscopically. Because the incidences of renal tubule neoplasms in the standard evaluation suggested the possibility of a treatment-related carcinogenic effect, an extended evaluation of the kidney was performed in male rats to explore this possibility. For the extended evaluation, kidneys of male rats were step-sectioned at 1 mm intervals to obtain three to four additional sections from each kidney, and these sections were examined microscopically. In the extended evaluation, additional renal tubule adenomas and renal tubule hyperplasias were identified but no additional renal tubule carcinomas (Table 16); a renal tubule oncocytoma was identified in one male exposed to 2.5 mg/m^3^. In the combined standard and extended evaluations, the incidences of renal tubule hyperplasia in the exposed groups were similar to that in the chamber controls. The incidence of renal tubule adenoma in the 5 mg/m^3^ group was greater than that in the chamber control group, but the increase was not statistically significant. The incidences of renal tubule carcinomas were unchanged.

Table 16 Incidences of Neoplasms and Nonneoplastic Lesions of the Kidney in Male Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Single Sections (Standard Evaluation)
Number Examined Microscopically | 50 | 50 | 50 | 50
Renal Tubule, Hyperplasia^a^ | 0 | 0 | 0 | 0
Renal Tubule, Adenoma, Multiple | 0 | 0 | 0 | 1
Renal Tubule, Adenoma (includes multiple)^b^ | 0 | 1 | 0 | 3
Renal Tubule, Carcinoma^c^ | 0 | 0 | 0 | 2
Renal Tubule, Adenoma or Carcinoma^b^ | 0 | 1 | 0 | 4
Step Sections (Extended Evaluation)
Number Examined Microscopically | 50 | 50 | 50 | 50
Renal Tubule, Hyperplasia | 5 | 3 | 5 | 4
Renal Tubule, Adenoma | 3 | 1 | 1 | 3
Renal Tubule, Carcinoma | 0 | 0 | 0 | 2
Renal Tubule, Adenoma or Carcinoma | 3 | 1 | 1 | 5
Renal Tubule, Oncocytoma | 0 | 0 | 1 | 0
Single Sections and Step Sections (Combined)
Number Examined Microscopically | 50 | 50 | 50 | 50
Renal Tubule, Hyperplasia | 5 | 3 | 5 | 4
Renal Tubule, Adenoma (includes multiple) | 3 | 1 | 1 | 6
Renal Tubule, Carcinoma | 0 | 0 | 0 | 2
Renal Tubule, Adenoma or Carcinoma
Overall rate^d^ | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 7/50 (14%)
Adjusted rate^e^ | 7.5% | 2.5% | 2.4% | 17.4%
Terminal rate^f^ | 0/17 (0%) | 1/20 (5%) | 1/16 (6%) | 4/16 (25%)
First incidence (days) | 678 | 729 (T) | 729 (T) | 691
Poly-3 test^g^ | P = 0.023 | P = 0.302N | P = 0.294N | P = 0.158

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Historical control incidence for 2-year studies (all routes): 1/100.

^c^ Historical control incidence: 0/100.

^d^ Number of animals with neoplasm per number of animals with kidney examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

Renal tubule adenomas were small, well circumscribed proliferations of renal tubule epithelial cells with a cross-sectional area greater than five times that of a single, normal renal tubule. The cells were well differentiated and uniform in size and shape and formed poorly defined papillary structures or solid clusters of cells (Figure 26). Renal tubule carcinomas were larger, expansive, and invasive masses that effaced and replaced much of the renal parenchyma (Figure 27).

Figure 26

Renal Tubule Adenoma in the Kidney of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The adenoma (arrows) is well-circumscribed and consists of relatively uniform large cells with a granular to glassy cytoplasm.

Figure 27

Renal Tubule Carcinoma in the Kidney of a Male F344/NTac Rat Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The carcinoma (arrows) is invasive and has replaced much of the renal parenchyma.

Mononuclear Cell Leukemia: The incidences of mononuclear cell leukemia were significantly increased in all exposed groups of female rats and exceeded the historical control incidence for all routes of administration (Table 17, Table B-1, Table B-2, and Table B-6).

Table 17 Incidences of Mononuclear Cell Leukemia in Female Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
All Organs: Mononuclear Cell Leukemia^a^
Overall rate^b^ | 16/50 (32%) | 29/50 (58%) | 28/50 (56%) | 27/50 (54%)
Adjusted rate^c^ | 35.7% | 62.4% | 60.5% | 58.9%
Terminal rate^d^ | 12/35 (34%) | 15/26 (58%) | 12/24 (50%) | 13/25 (52%)
First incidence (days) | 663 | 590 | 117 | 473
Poly-3 test^e^ | P = 0.118 | P = 0.007 | P = 0.013 | P = 0.019

^a^ Historical control incidence for 2-year studies (all routes): 35/100.

^b^ Number of animals with mononuclear cell leukemia per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

Liver: The incidences of basophilic focus occurred with positive trends in male and female rats and in all exposed groups of males (chamber control, 5/50; 1.25 mg/m^3^, 17/50; 2.5 mg/m^3^, 17/50; 5 mg/m^3^, 19/50) and in females exposed to 5 mg/m^3^ (16/50, 20/50, 22/50, 33/50), and the incidences were significantly greater than those in the chamber control groups (Table A-7 and Table B-7). Basophilic foci occur spontaneously in rats, and the incidences are sometimes increased with exposure to chemicals. They are considered putative preneoplastic lesions; however, the incidences of hepatocellular neoplasms were not increased in male or female rats exposed to cobalt metal (Table A-1 and Table B-1).

Testes: The incidence of infarct was significantly increased in male rats exposed to 5 mg/m^3^ (1/50, 0/50, 2/50, 12/50) (Table A-4). Infarcts were mostly unilateral, and in affected testes, there was complete effacement of the parenchyma due to necrosis with loss of differential staining (tissue was diffusely hypereosinophilic) and cellular detail. Multifocal intratubular mineralization was current in a few of the affected testes.

#### Tissue Burden Studies

Lung weights and lung cobalt burdens were determined in female rats (Table I-7). Lung weights increased in all exposed groups; however, increases in lung weights occurred earlier in the study (day 184) in the 2.5 and 5 mg/m^3^ groups than in the 1.25 mg/m^3^ group (day 366). Because of the significant changes in lung weights with increasing exposure concentration, lung cobalt burdens rather than lung cobalt concentrations were evaluated for toxicokinetic parameters.

Cobalt concentrations and burdens in the lung increased with increasing exposure concentration and were significantly increased in all exposed groups of female rats at all time points compared to those in the chamber control group (Table I-7). Cobalt concentrations in the chamber control group were at or below the limit of detection (LOD) at all time points except day 548 [one animal had a lung cobalt concentration exceeding the LOD but less than the experimental limit of quantitation (ELOQ)]. By day 184, lung cobalt concentrations for all exposed groups appeared to reach steady state and did not change significantly through day 548; lung cobalt burdens increased rapidly by day 4, but by day 184 the rate of increase slowed as lung burdens asymptotically approached steady state. Analysis of normalized lung cobalt burdens revealed no tendency toward disproportionate changes and no biologically significant differences in normalized burdens with increasing exposure concentration.

The lung cobalt burden data from the exposure phases of the 3-month and 2-year studies were modeled using a two-compartment model; these data show that steady state was clearly reached at 2.5 and 5 mg/m^3^ but not at 1.25 mg/m^3^ (Table I-1). Rapid clearance phase half-lives were between 1.53 days and 2.94 days (Table I-8), while slow clearance phase half-lives were 789 days, 167 days, and 83 days for 1.25 mg/m^3^, 2.5 mg/m^3^, and 5 mg/m^3^, respectively. The apparent lack of achievement of steady state and long half-life at 1.25 mg/m^3^ are likely spurious findings due to uncertainty in the model. Cobalt deposition rates were 1.4, 2.1, and 5.6 μg cobalt/day during the rapid clearance phase and 0.018, 0.078, and 0.29 μg cobalt/day during the slow clearance phase at 1.25, 2.5, and 5 mg/m^3^, respectively. Steady-state lung cobalt burdens including both the rapid and slow clearance phases (L_SSa_ + L_SSb_) were approximately 25.4, 27.8, and 46.8 µg cobalt/lung in animals exposed to 1.25, 2.5, and 5 mg/m^3^, respectively. The fractions of deposition in the slow clearance phase (F_B_) for the exposed groups were quite low, increasing from 0.012 to 0.049 as exposure concentrations increased, corresponding to total slow phase lung cobalt clearances of 1.2% to 4.9%; clearances of total deposited cobalt during the rapid clearance phase ranged from 98.8% to 95.1% [(1−F_B_) × 100] with increasing exposure concentration.

## Mice

### Two-week Study

The exposure concentrations for the 2-week study were estimated based on exposures of previously studied cobalt sulfate heptahydrate.^66^ Three male and three female mice exposed to 40 mg/m^3^ died before the end of the study (Table 18). Final mean body weights were significantly decreased in male and female mice exposed to 20 or 40 mg/m^3^ by 9% and 27% (males) or 16% and 38% (females), respectively, compared to the chamber control groups. Mean body weight gains of 20 and 40 mg/m^3^ males and all exposed groups of females were significantly less than those of the chamber controls. Females exposed to 20 mg/m^3^ and males and females exposed to 40 mg/m^3^ lost weight during the study. Exposure-related clinical findings included abnormal breathing, lethargy, and thinness in males exposed to 20 or 40 mg/m^3^ and females exposed to 10 mg/m^3^ or greater. At necropsy, tan lungs were observed in most males and females exposed to 20 or 40 mg/m^3^. Dark lung lobes were observed in one early-death male.

Table 18 Survival and Body Weights of Mice in the Two-week Inhalation Study of Cobalt Metal^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 23.4 ± 0.3 | 25.7 ± 0.5 | 2.3 ± 0.3
2.5 | 5/5 | 23.5 ± 0.3 | 25.0 ± 0.5 | 1.5 ± 0.2 | 97
5 | 5/5 | 23.6 ± 0.3 | 25.9 ± 0.3 | 2.2 ± 0.4 | 101
10 | 5/5 | 23.8 ± 0.3 | 25.3 ± 0.5 | 1.5 ± 0.2 | 98
20 | 5/5 | 23.1 ± 0.4 | 23.4 ± 0.4** | 0.2 ± 0.4** | 91
40 | 2/5^c^ | 23.0 ± 0.4 | 18.9 ± 1.1** | −4.7 ± 1.7** | 73
Female
0 | 5/5 | 19.1 ± 0.3 | 20.8 ± 0.1 | 1.7 ± 0.3
2.5 | 5/5 | 19.8 ± 0.5 | 20.3 ± 0.5 | 0.5 ± 0.2* | 98
5 | 5/5 | 19.8 ± 0.5 | 20.1 ± 0.5 | 0.3 ± 0.4* | 97
10 | 5/5 | 19.4 ± 0.4 | 20.0 ± 0.6 | 0.6 ± 0.4* | 96
20 | 5/5 | 19.0 ± 0.3 | 17.4 ± 0.4** | −1.6 ± 0.2** | 84
40 | 2/5^d^ | 18.9 ± 0.2 | 13.0 ± 1.6** | −6.1 ± 1.1** | 62

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 17 days/number initially in group.

^c^ Days of deaths: 5, 5, 8.

^d^ Days of deaths: 6, 7, 9.

Absolute lung weights of both sexes exposed to 5 mg/m^3^ or greater and relative lung weights of males exposed to 10 mg/m^3^ or greater and of females exposed to 5 mg/m^3^ or greater were significantly increased compared to the chamber controls (Table 19 and Table G-3). Absolute liver weights of all exposed groups of males and females and the relative liver weights of both sexes exposed to 2.5, 5, 10, or 20 mg/m^3^ were significantly less than those of the chamber controls. Absolute testis weight of the 40 mg/m^3^ group was significantly less than that of the chamber controls.

Table 19 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 m/m^3^
n | 5 | 5 | 5 | 5 | 5 | 2
Male
Necropsy body wt | 25.7 ± 0.5 | 25.0 ± 0.5 | 25.9 ± 0.3 | 25.3 ± 0.5 | 23.4 ± 0.4** | 18.9 ± 1.1**
Liver
Absolute | 1.13 ± 0.04 | 0.98 ± 0.04** | 0.98 ± 0.04** | 0.99 ± 0.02** | 0.89 ± 0.02** | 0.83 ± 0.01**
Relative | 43.88 ± 0.80 | 39.18 ± 1.35* | 37.67 ± 1.09** | 39.32 ± 0.91* | 37.93 ± 0.51** | 44.20 ± 2.99
Lung
Absolute | 0.18 ± 0.01 | 0.21 ± 0.01 | 0.23 ± 0.01* | 0.24 ± 0.01** | 0.29 ± 0.01** | 0.36 ± 0.05**
Relative | 7.08 ± 0.15 | 8.33 ± 0.32 | 8.73 ± 0.33 | 9.61 ± 0.62* | 12.62 ± 0.51** | 19.31 ± 3.73**
L. Testis
Absolute | 0.098 ± 0.002 | 0.104 ± 0.001 | 0.099 ± 0.004 | 0.084 ± 0.009 | 0.089 ± 0.003 | 0.070 ± 0.002**
Relative | 3.834 ± 0.074 | 4.180 ± 0.114 | 3.812 ± 0.149 | 3.322 ± 0.311 | 3.807 ± 0.088 | 3.731 ± 0.314
Female
Necropsy body wt | 20.8 ± 0.1 | 20.3 ± 0.5 | 20.1 ± 0.5 | 20.0 ± 0.6 | 17.4 ± 0.4** | 13.0 ± 1.6**
Liver
Absolute | 0.93 ± 0.03 | 0.81 ± 0.02** | 0.80 ± 0.03** | 0.75 ± 0.03** | 0.69 ± 0.03** | 0.61 ± 0.06**
Relative | 44.56 ± 1.13 | 40.09 ± 0.31** | 39.75 ± 0.82** | 37.40 ± 1.12** | 39.73 ± 0.70** | 46.88 ± 1.36
Lung
Absolute | 0.19 ± 0.01 | 0.19 ± 0.00 | 0.22 ± 0.01* | 0.23 ± 0.01** | 0.29 ± 0.01** | 0.33 ± 0.02**
Relative | 9.34 ± 0.38 | 9.49 ± 0.37 | 11.14 ± 0.24* | 11.77 ± 0.59** | 16.80 ± 0.58** | 25.67 ± 1.53**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Increased incidences of nonneoplastic lesions of the lung occurred in exposed male and female mice (Table 20). The incidences of minimal to moderate alveolar histiocytic cellular infiltration were significantly increased in males and females exposed to 5 mg/m^3^ or greater and consisted of varying numbers of histiocytes (macrophages) within the alveolar spaces and septa. The incidences of minimal to mild cytoplasmic vacuolization of the bronchiolar epithelium were significantly increased in males exposed to 2.5 or 10 mg/m^3^ and females exposed to 5 mg/m^3^. The lesion was characterized by the presence of poorly defined clear spaces within the cytoplasm of bronchiolar epithelial cells. The incidences of minimal to mild alveolar/bronchiolar epithelium karyomegaly were significantly increased in males and females exposed to 5 mg/m^3^ or greater. Karyomegaly consisted of scattered, hypertrophied epithelial cells with single large and sometimes multiple, atypical nuclei in the terminal bronchioles, alveolar ducts, and alveoli. The incidences of minimal to moderate interstitial fibrosis were increased in all groups of mice exposed to 10 mg/m^3^ or greater. Fibrosis consisted of multifocal to coalescing areas in which the alveolar architecture was effaced or obscured by fibroblasts and/or collagen within which were accumulations of histiocytes. Minimal to mild acute inflammation occurred in 40 mg/m^3^ males and females that died before the end of the study. Minimal acute inflammation was also observed in some females exposed to 5, 10, or 20 mg/m^3^. Acute inflammation consisted of perivascular and, to a lesser extent, peribronchiolar edema mixed with infiltrates of neutrophils.

Table 20 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Mice in the Two-week Inhalation Study of Cobalt Metal

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
Male
Lung^a^ | 5 | 5 | 5 | 5 | 5 | 5
Alveolus, Infiltration Cellular, Histiocyte^b^ | 0 | 2 (1.0)^c^ | 5** (1.0) | 5** (1.4) | 5** (2.4) | 5** (2.0)
Bronchiole, Epithelium, Vacuolization, Cytoplasmic | 0 | 4* (1.0) | 3 (1.0) | 5** (1.6) | 3 (1.0) | 3 (1.3)
Alveolar/bronchiolar Epithelium, Karyomegaly | 0 | 0 | 4* (1.0) | 5** (1.0) | 5** (1.8) | 4* (1.5)
Interstitium, Fibrosis | 0 | 0 | 0 | 3 (1.0) | 5** (2.2) | 3 (2.7)
Inflammation, Acute | 0 | 0 | 0 | 0 | 0 | 3 (1.7)
Nose | 5 | 5 | 5 | 5 | 5 | 5
Inflammation, Acute | 0 | 0 | 1 (1.0) | 5** (2.4) | 5** (1.6) | 5** (1.8)
Olfactory Epithelium, Atrophy | 0 | 5** (1.0) | 5** (1.0) | 5** (1.8) | 5** (1.8) | 4** (2.0)
Olfactory Epithelium, Necrosis | 0 | 2 (1.0) | 3 (1.0) | 0 | 5** (1.2) | 5** (1.4)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 4* (1.0) | 5** (1.0) | 4* (1.0) | 5** (1.2) | 5** (1.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 4* (1.0) | 4* (1.0) | 2 (1.0)
Female
Lung | 5 | 5 | 5 | 5 | 5 | 5
Alveolus, Infiltration Cellular, Histiocyte | 0 | 2 (1.0) | 5** (1.4) | 5** (1.6) | 5** (2.6) | 5** (2.4)
Bronchiole, Epithelium, Vacuolization, Cytoplasmic | 0 | 2 (1.0) | 4* (1.0) | 3 (1.7) | 2 (1.0) | 1 (1.0)
Alveolar/bronchiolar Epithelium, Karyomegaly | 0 | 3 (1.0) | 4* (1.0) | 5** (1.2) | 4* (1.3) | 4* (1.0)
Interstitium, Fibrosis | 0 | 0 | 0 | 2 (1.0) | 5** (2.8) | 2 (3.5)
Inflammation, Acute | 0 | 0 | 2 (1.0) | 1 (1.0) | 3 (1.0) | 2 (1.5)
Nose | 5 | 5 | 5 | 5 | 5 | 5
Acute Inflammation | 0 | 0 | 5** (2.0) | 5** (2.6) | 5** (2.4) | 5** (2.2)
Olfactory Epithelium, Atrophy | 0 | 5** (1.4) | 5** (1.6) | 5** (1.8) | 5** (2.2) | 3 (2.0)
Olfactory Epithelium, Necrosis | 0 | 3 (1.0) | 5** (1.0) | 2 (1.5) | 4* (1.5) | 3 (1.7)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 5** (1.0) | 5** (1.0) | 5** (1.2) | 4* (1.0) | 4* (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 3 (1.0) | 1 (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Increased incidences of nonneoplastic lesions of the nose occurred in exposed groups of male and female mice (Table 20). The incidences of minimal to moderate acute inflammation were significantly increased in males exposed to 10 mg/m^3^ or greater and females exposed to 5 mg/m^3^ or greater. There was no increase in severity.

with increasing exposure concentration. Acute inflammation occurred in the respiratory and olfactory regions of the nasal cavity and was characterized by accumulation of proteinaceous fluid, mucus, and neutrophilic cell debris in the nasal passages. Occasionally, there were low numbers of neutrophils within the mucosa and lamina propria. The incidences of minimal to mild olfactory epithelium atrophy were significantly increased in all exposed groups except the 40 mg/m^3^ females. Atrophy often accompanied necrosis and was characterized by loss of olfactory epithelial cells with decreased height of the epithelium. The remaining olfactory cells were often disorganized, flattened to cuboidal, or respiratory-type ciliated columnar and replaced the olfactory epithelial cells. In some areas, there were clusters or nests of sensory-type cells within the remaining olfactory epithelium; this was interpreted as a regenerative response. The incidences of minimal to mild olfactory epithelium necrosis were significantly increased in males exposed to 20 or 40 mg/m^3^ and females exposed to 5 or 20 mg/m^3^. Necrosis was characterized by segmental vacuolization, disorganization, and loss of epithelial cells in the dorsal meatus of the Level II nasal section and the lateral and ventral aspects of the ethmoid turbinates in Level III with full-thickness sloughing of the epithelium in some areas. The incidences of minimal cytoplasmic vacuolization of the respiratory epithelium were significantly increased in all exposed groups of males and females. Cytoplasmic vacuolization was characterized by the presence of poorly defined clear spaces within the cytoplasm of respiratory epithelial cells in Levels I and II. The incidences of minimal squamous metaplasia of the respiratory epithelium were significantly increased in males exposed to 10 or 20 mg/m^3^. Squamous epithelial metaplasia involved lateral walls, turbinates, and ventral septa in Levels I and II. In affected sites, the normal single layer of tall columnar, ciliated epithelial cells was replaced by one to three layers of flattened (squamous) epithelial cells that lacked cilia.

#### Tissue Burden Studies

Tissue weights and concentrations were determined in male and female mice at terminal kill and in additional female mice held for 3 weeks after the exposure. Data were generated on male and female mice in all exposure groups; however, relatively small numbers of samples (n = 1 to 2) were available in 40 mg/m^3^ females due to decreased survival.

Male and female mouse lung weights increased with increasing exposure concentration, reaching weights that were up to 1.5- to 2-fold greater than those of the chamber controls at terminal kill (Table I-9). In female mice that were held for the 3-week recovery period, lung weights of exposed groups recovered such that they were similar to those of the chamber controls at the end of the recovery period. In both males and females, treatment-related decreases in the weights of all other tissues occurred. Because of the significant changes in lung weight, lung cobalt burdens rather than lung concentrations were evaluated for toxicokinetic parameters.

At terminal kill, cobalt concentrations and burdens increased with exposure concentration in all tissues examined (Table I-9). Cobalt concentrations in tissues decreased in the order of lung > liver > kidney > serum > heart approximately equal to femur > blood > testes (males). Tissue cobalt burdens in male mouse tissues decreased in the order of lung > liver > kidney > heart > femur > testes. With the exception of testes, all tissues examined represented sites where cobalt could accumulate at concentrations greater than observed in the blood or serum. Mice of both sexes accumulated large amounts of cobalt in the liver. While lung cobalt burdens were generally higher than liver cobalt burdens at exposures of 20 mg/m^3^, liver and lung burdens were similar in females exposed to 20 mg/m^3^ or less, and liver burdens were greater than lung burdens in 40 mg/m^3^ males and females. Normalized tissue burdens generally remained the same or decreased with increasing exposure concentration.

Kinetic analysis of data from female mice exposed to 20 mg/m^3^ or less indicated elimination half-lives of 4.1 to 7.3 days (blood), 2.9 to 3.7 days (serum), or 5.5 to 6.6 days (lung) (Table I-10); in general, half-lives decreased with increasing exposure concentration. Lung cobalt deposition rates and predicted steady-state lung cobalt burdens increased in proportion to exposure concentrations of 2.5 and 5 mg/m^3^, but the increases were less than proportional at greater exposure concentrations.

Exposure Concentration Selection Rationale: Significant mortality was observed in male and female mice exposed to 40 mg/m^3^ in the 2-week study. There were significant decreases in body weights in 20 mg/m^3^ males (9%) and females (16%). Significantly increased incidences of alveolar infiltration (histiocytic) were observed in the lung of males and females exposed to 5 mg/m^3^ or greater. However, the average severity grade was minimal in the 5 and 10 mg/m^3^ groups, and the increases in lung weights in the 10 mg/m^3^ groups were not considered sufficiently severe to preclude the use of this concentration. Hence, 10 mg/m^3^ was selected as the highest exposure concentration for the 3-month inhalation study in mice.

### Three-month Study

One 2.5 mg/m^3^ female mouse was accidentally killed during the first week of the study; all other mice survived to the end of the study (Table 21). The final mean body weights and mean body weight gains of males and females exposed to 10 mg/m^3^ were significantly less than those of the chamber controls (Table 21 and Figure 4). Abnormal breathing was noted in approximately 50% of males and females exposed to 10 mg/m^3^. At necropsy, tan lungs were noted in mice exposed to 5 or 10 mg/m^3^.

Table 21 Survival and Body Weights of Mice in the Three-month Inhalation Study of Cobalt Metal^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 23.7 ± 0.2 | 37.7 ± 0.8 | 14.0 ± 0.7
0.625 | 10/10 | 23.7 ± 0.3 | 38.2 ± 0.6 | 14.5 ± 0.4 | 101
1.25 | 10/10 | 23.7 ± 0.2 | 37.9 ± 0.8 | 14.2 ± 0.8 | 101
2.5 | 10/10 | 23.8 ± 0.2 | 37.0 ± 0.5 | 13.3 ± 0.4 | 98
5 | 10/10 | 23.7 ± 0.2 | 37.0 ± 0.9 | 13.4 ± 0.8 | 98
10 | 10/10 | 23.8 ± 0.2 | 32.5 ± 0.5** | 8.7 ± 0.5** | 86
Female
0 | 10/10 | 20.5 ± 0.3 | 30.9 ± 1.0 | 10.4 ± 1.1
0.625 | 10/10 | 20.0 ± 0.3 | 31.6 ± 1.1 | 11.6 ± 1.3 | 102
1.25 | 10/10 | 20.2 ± 0.4 | 31.4 ± 0.9 | 11.2 ± 0.7 | 102
2.5 | 9/10^c^ | 19.8 ± 0.2 | 30.1 ± 0.7 | 10.1 ± 0.7 | 97
5 | 10/10 | 20.1 ± 0.3 | 29.0 ± 1.1 | 8.9 ± 1.0 | 94
10 | 10/10 | 19.8 ± 0.2 | 26.8 ± 1.0** | 7.0 ± 1.0* | 87

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 1.

Figure 4

Growth Curves for Mice Exposed to Cobalt Metal by Inhalation for Three Months

On days 26 and 40, microsomal suspensions of liver samples from special study female mice not used for tissue burden studies were prepared and assayed for A4H, EROD, and PROD activities (Table J-2). There were no consistent trends in A4H, EROD, or PROD activities relative to exposure concentrations at either time point or from day 26 to day 40. A4H activities were significantly increased in the 5 and 10 mg/m^3^ groups on day 40. EROD activities were significantly increased in the 5 and 10 mg/m^3^ groups at both time points.

Similar to effects noted in rats, statistically significant increases were observed in hemoglobin concentration and erythrocyte count of 10 mg/m^3^ males and in the erythrocyte count of 10 mg/m^3^ females at 14 weeks (Table F-2). These changes in comparison to the rats, however, were minimal (<5%).

Absolute and relative lung weights of males exposed to 2.5 mg/m^3^ or greater and females exposed to 5 or 10 mg/m^3^ were significantly greater than those of the chamber controls (Table 22 and Table G-4). Absolute and relative liver weights of males exposed to 10 mg/m^3^ and females exposed to 2.5 mg/m^3^ or greater were significantly less than those of the chamber controls. Absolute and relative kidney weights of males and females exposed to 5 or 10 mg/m^3^ were significantly less than those of the chamber controls. Absolute and relative testes weights of males exposed to 5 or 10 mg/m^3^ were significantly less than those of the chamber controls.

Table 22 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 37.7 ± 0.8 | 38.2 ± 0.6 | 37.6 ± 0.8 | 37.0 ± 0.5 | 37.0 ± 0.9 | 32.5 ± 0.5**
R. Kidney
Absolute | 0.31 ± 0.01 | 0.32 ± 0.01 | 0.32 ± 0.01 | 0.32 ± 0.00 | 0.29 ± 0.01** | 0.23 ± 0.01**
Relative | 8.360 ± 0.192 | 8.441 ± 0.122 | 8.333 ± 0.237 | 8.507 ± 0.047 | 7.714 ± 0.145** | 7.176 ± 0.131**
Liver
Absolute | 1.48 ± 0.04 | 1.53 ± 0.04 | 1.51 ± 0.07 | 1.49 ± 0.04 | 1.42 ± 0.05 | 1.15 ± 0.03**
Relative | 39.217 ± 0.586 | 40.049 ± 0.671 | 39.753 ± 1.032 | 40.301 ± 0.698 | 38.159 ± 0.723 | 35.457 ± 0.668**
Lung
Absolute | 0.20 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.23 ± 0.01* | 0.27 ± 0.01** | 0.30 ± 0.01**
Relative | 5.416 ± 0.116 | 6.051 ± 0.235 | 5.737 ± 0.147 | 6.234 ± 0.088** | 7.436 ± 0.262** | 9.142 ± 0.177**
R. Testis
Absolute | 0.118 ± 0.002 | 0.119 ± 0.002 | 0.114 ± 0.002 | 0.114 ± 0.002 | 0.104 ± 0.003** | 0.033 ± 0.001**
Relative | 3.136 ± 0.058 | 3.131 ± 0.037 | 3.019 ± 0.078 | 3.073 ± 0.056 | 2.825 ± 0.082** | 1.004 ± 0.025**
Female
n | 10 | 10 | 10 | 9 | 10 | 10
Necropsy body wt | 30.9 ± 1.0 | 31.6 ± 1.1 | 31.4 ± 0.9 | 30.1 ± 0.7 | 29.0 ± 1.1 | 26.8 ± 1.0**
R. Kidney
Absolute | 0.21 ± 0.01 | 0.22 ± 0.00 | 0.21 ± 0.01 | 0.20 ± 0.00 | 0.17 ± 0.00** | 0.16 ± 0.00**
Relative | 6.887 ± 0.184 | 6.849 ± 0.155 | 6.661 ± 0.126 | 6.689 ± 0.254 | 6.031 ± 0.132** | 6.142 ± 0.185**
Liver
Absolute | 1.46 ± 0.06 | 1.51 ± 0.07 | 1.46 ± 0.05 | 1.30 ± 0.03* | 1.16 ± 0.04** | 1.01 ± 0.03**
Relative | 47.051 ± 0.808 | 47.552 ± 0.952 | 46.455 ± 1.046 | 43.092 ± 0.773** | 39.831 ± 0.459** | 38.045 ± 1.246**
Lung
Absolute | 0.21 ± 0.01 | 0.22 ± 0.00 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.28 ± 0.01** | 0.33 ± 0.01**
Relative | 6.904 ± 0.227 | 6.884 ± 0.176 | 7.300 ± 0.274 | 7.555 ± 0.184 | 9.787 ± 0.241** | 12.602 ± 0.487**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Males exposed to 10 mg/m^3^ exhibited significant decreases in the weights of the cauda epididymis, epididymis, and testis; testis weight was also significantly decreased in the 5 mg/m^3^ group (Table 23 and Table H-4). Spermatids per testis were significantly decreased in 5 and 10 mg/m^3^ males, and spermatids per gram testis were significantly decreased in 10 mg/m^3^ males. Sperm motility and total sperm per epididymis and per gram epididymis were significantly decreased in 5 and 10 mg/m^3^ males; sperm motility was also significantly decreased in 2.5 mg/m^3^ males. Findings in the 10 mg/m^3^ males were associated with histopathologic changes. In female mice, the estrous cycle was significantly longer in the 10 mg/m^3^ group (Table H-5). The Markov transition matrix analyses indicated no significant differences in estrous cyclicity between the exposed and chamber control groups of females (Table H-5 and Table H-6; Figure H-2).

Table 23 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 37.7 ± 0.8 | 37.0 ± 0.5 | 37.0 ± 0.9 | 32.5 ± 0.5**
L. Cauda epididymis | 0.0217 ± 0.0014 | 0.0210 ± 0.0008 | 0.0231 ± 0.0018 | 0.0168 ± 0.0006*
L. Epididymis | 0.0603 ± 0.0022 | 0.0578 ± 0.0019 | 0.0614 ± 0.0035 | 0.0429 ± 0.0021**
L. Testis | 0.1185 ± 0.0017 | 0.1132 ± 0.0023 | 0.1027 ± 0.0036** | 0.0316 ± 0.0014**
Spermatid measurements
Spermatid heads (10^6^/testis) | 22.34 ± 0.84 | 22.22 ± 0.65 | 18.90 ± 1.20* | 0.53 ± 0.10**
Spermatid heads (10^6^/g testis) | 210.84 ± 6.85 | 227.74 ± 7.16 | 205.67 ± 7.43 | 24.27 ± 4.78**
Epididymal spermatozoal measurements
Sperm motility (%) | 86.0 ± 1.1 | 82.0 ± 0.8* | 82.2 ± 1.1* | 2.6 ± 1.2**
Sperm (10^6^/cauda epididymis) | 11.55 ± 0.39 | 10.53 ± 0.43 | 9.62 ± 0.49** | 0.71 ± 0.06**
Sperm (10^6^/g cauda epididymis) | 551.1 ± 37.9 | 505.9 ± 23.3 | 439.9 ± 40.3* | 43.4 ± 3.7**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test (cauda epididymis weight) or Shirley’s test (spermatid and epididymal spermatozoal measurements).

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body and tissue weights) or Shirley’s test (spermatid and epididymal spermatozoal measurements).

^a^ Data are presented as mean ± standard error.

Increased incidences of nonneoplastic lesions of the lung in exposed male and female mice included alveolus infiltration cellular, histiocyte; alveolus proteinosis; alveolar/bronchiolar epithelium karyomegaly; bronchiole epithelium hyperplasia and cytoplasmic vacuolization; and hemorrhage; the severities of the lesions increased with increasing exposure concentration (Table 24). Alveolar histiocytic cellular infiltration occurred in the lung of every exposed male and female mouse and was characterized by the presence of low to moderate numbers of histiocytes (macrophages) within alveolar spaces and septa. In some alveoli, the histiocytes were swollen and contained phagocytosed erythrocytes and/or eosinophilic material similar to that in the alveolar spaces. In mice exposed to 2.5 mg/m^3^ or greater, the intracytoplasmic material appeared golden brown to grey. Minimal to mild alveolar proteinosis occurred in all males and females exposed to 5 or 10 mg/m^3^ and was characterized by the accumulation of variable amounts of homogenous globular, granular, or fibrillar eosinophilic material within the alveolar spaces. Alveolar/bronchiolar epithelium karyomegaly occurred in all mice exposed to 5 or 10 mg/m^3^ and was characterized by the presence of scattered, hypertrophied cells with single large and, sometimes multiple, atypical nuclei in the epithelium of the terminal bronchioles, alveolar ducts, and immediately adjacent alveoli. Minimal to moderate bronchiole epithelium hyperplasia occurred in every mouse exposed to 2.5 mg/m^3^ or greater and was characterized by proliferation and hypertrophy of the epithelial cells lining terminal bronchioles with involvement of the alveolar ducts and adjacent alveolar septa in more severe cases. At affected sites, there was piling up of the pleomorphic cells in three to eight disorganized layers. The proliferating epithelial cells generally contained clear cytoplasmic vacuoles; this change was diagnosed as minimal to marked bronchiole epithelium cytoplasmic vacuolization, and it occurred in every exposed mouse. Several males and females exposed to 5 or 10 mg/m^3^ had minimal hemorrhage characterized by low numbers of red blood cells within a few alveolar spaces.

Table 24 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Mice in the Three-month Inhalation Study of Cobalt Metal

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Male
Lung^a^ | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte^b^ | 0 | 10** (1.0)^c^ | 10** (1.0) | 10** (1.0) | 10** (2.0) | 10** (3.0)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 10** (1.0) | 10** (1.9) | 10** (3.0)
Bronchiole, Epithelium, Vacuolization Cytoplasmic | 0 | 10** (1.0) | 10** (1.0) | 10** (1.5) | 10** (2.7) | 10** (3.9)
Alveolus, Proteinosis | 0 | 0 | 0 | 0 | 10** (1.0)^c^ | 10** (2.0)
Alveolar/bronchiolar, Epithelium, Karyomegaly | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (3.0)
Hemorrhage | 0 | 1 (1.0) | 0 | 1 (1.0) | 7** (1.1) | 6** (1.0)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 8** (1.4) | 10** (2.5)
Olfactory Epithelium, Degeneration | 0 | 2 (1.0) | 10** (1.0) | 10** (1.0) | 10** (2.0) | 10** (3.0)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 1 (1.0) | 5* (1.0) | 2 (1.0) | 3 (1.3)
Respiratory Epithelium, Degeneration | 0 | 0 | 6** (1.0) | 9** (1.0) | 10** (1.9) | 10** (2.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 2 (1.0) | 5* (1.0) | 10** (1.3) | 10** (1.9)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 8** (2.1) | 10** (3.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Metaplasia, Squamous | 0 | 10** (1.8) | 10** (1.8) | 10** (1.9) | 10** (1.9) | 10** (2.1)
Female
Lung | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (2.1) | 10** (3.0)
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 0 | 10** (1.0) | 10** (1.9) | 10** (3.0)
Bronchiole, Epithelium, Vacuolization Cytoplasmic | 0 | 10** (1.0) | 10** (1.0) | 10** (1.1) | 10** (2.6) | 10** (3.9)
Alveolus, Proteinosis | 0 | 0 | 0 | 0 | 10** (1.0) | 10** (1.8)
Alveolar/bronchiolar, Epithelium, Karyomegaly | 0 | 0 | 0 | 0 | 10** (1.7) | 10** (3.0)
Hemorrhage | 0 | 0 | 0 | 0 | 8** (1.0) | 2 (1.0)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Chronic Active | 0 | 0 | 0 | 1 (1.0) | 10** (2.5) | 10** (2.4)
Olfactory Epithelium, Degeneration | 0 | 1 (1.0) | 7** (1.0) | 9** (1.0) | 10** (2.5) | 10** (2.9)
Olfactory Epithelium, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 0 | 0
Respiratory Epithelium, Degeneration | 0 | 0 | 1 (1.0) | 8** (1.0) | 10** (1.9) | 10** (1.9)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 9** (1.0) | 10** (2.0) | 10** (2.0)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 10** (2.2) | 10** (2.9)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Metaplasia, Squamous | 0 | 10** (1.3) | 10** (1.4) | 10** (1.6) | 10** (1.8) | 10** (2.2)

* Significantly different ( P≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the nose, increased incidences of nonneoplastic lesions in exposed male and female mice included chronic active inflammation, olfactory epithelium degeneration and hyperplasia, respiratory epithelium degeneration, and squamous metaplasia, and turbinate atrophy; the severities of these lesions generally increased with increasing exposure concentration (Table 24).

Incidences of chronic active inflammation were significantly increased in the 5 and 10 mg/m^3^ groups of males and females. Chronic active inflammation was observed in all three nasal sections of the nasal cavity and consisted of infiltrates of neutrophils, lymphocytes, macrophages, and plasma cells within the lamina propria and to a lesser extent the epithelium of the turbinates and nasal septum.

In some cases, the nasal passages contained proteinaceous fluid mixed with variable numbers of degenerate neutrophils, macrophages, and cellular debris. Incidences of olfactory epithelium degeneration were significantly increased in males and females exposed to 1.25 mg/m^3^ or greater. Degeneration was a focal or multifocal lesion that variably involved the epithelium lining the dorsal meatus, turbinates, or nasal septa. In affected sites, there was disorganization of the epithelium with vacuolization, individual cell death, and/or loss of epithelial cells and decrease in the height of the epithelium and in some cases a decrease in the size of the olfactory nerve bundles in the lamina propria. Scattered incidences of olfactory epithelium hyperplasia occurred primarily in exposed groups of males; the lesion was characterized by clusters or nests of proliferating cells within or just adjacent to the olfactory epithelium and sometimes with extension into the lamina propria around glandular ducts. The cells sometimes formed rosettes and had scant cytoplasm and large, round to oval nuclei. Incidences of minimal to mild respiratory epithelium degeneration were significantly increased in males exposed to 1.25 mg/m^3^ or greater and females exposed to 2.5 mg/m^3^ or greater. Respiratory epithelium degeneration involved the turbinates and/or lateral walls of the Level I and II nasal sections. In affected sites, the epithelium appeared disorganized and there was variable epithelial cell vacuolation with loss of cilia, individual cell death, and loss of the epithelial cells. Incidences of minimal to mild respiratory epithelium squamous metaplasia were significantly increased in males and females exposed to 2.5 mg/m^3^ or greater; the lesion involved the transitional epithelium of the lateral wall and the lateral surface and tips of the nasoturbinates and was often associated with proteinaceous fluid in the nasal passages. In affected sites, the normally ciliated, columnar epithelium was replaced by one or two layers of squamous epithelium. Incidences of turbinate atrophy were significantly increased in the 5 and 10 mg/m^3^ groups of males and females. Turbinate atrophy occurred in all three histologic sections of the nose. Microscopically, turbinate atrophy appeared as more space in the nasal passages because the individual turbinates were short, blunt, and/or narrow due to attenuation and/or loss of turbinate bone and other structures (glands, vessels, nerve bundles, and interstitial tissue) in the lamina propria.

The incidences of squamous metaplasia were significantly increased in the larynx of all exposed groups of males and females, and severities of the lesion increased with increasing exposure concentration (Table 24). Squamous metaplasia occurred in the epithelium overlying the submucosal glands at the base of the epiglottis and was characterized by replacement of ciliated columnar epithelium with one to a few layers of flattened, nonciliated, squamous epithelial cells.

The incidence of marked germinal epithelium degeneration in the testes was significantly increased in males exposed to 10 mg/m^3^ (Table 25). Testes diagnosed with germinal epithelium degeneration had greatly decreased overall cross-sectional diameter compared to chamber control testes. All or most seminiferous tubules had irregular to somewhat flattened outlines with markedly decreased or completely absent germinal epithelium, vacuolated Sertoli cells, and aspermia; intraluminal clumps of sloughed germinal cells and amorphous mineralized debris were current in the lumina of the seminiferous tubules.

Table 25 Incidences of Selected Nonneoplastic Lesions of the Genital System in Male Mice in the Three-month Inhalation Study of Cobalt Metal

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Testes^a^ | 10 | 10 | 10 | 10 | 10 | 10
Germinal Epithelium, Degeneration^b^ | 2 (1.0)^c^ | 0 | 0 | 0 | 1 (1.0) | 10** (4.0)
Epididymis | 10 | 10 | 10 | 9 | 10 | 10
Exfoliated Germ Cell | 0 | 0 | 0 | 0 | 0 | 10** (2.7)
Hypospermia | 0 | 0 | 0 | 0 | 0 | 10** (2.9)
Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 0 | 9** (1.0)
Atrophy | 0 | 0 | 0 | 0 | 0 | 10** (1.0)

** Significantly different (P ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the epididymis, the incidences of exfoliated germ cells, hypospermia, cytoplasmic vacuolization, and atrophy were significantly increased in males exposed to 10 mg/m^3^ (Table 25). Mild to moderate germ cell exfoliation was characterized by sloughed,

degenerate germinal epithelial cells (spermatocytes, spermatogonia, and spermatids), as well as amorphous debris in the body and tail of the epididymal duct. Hypospermia, most likely the consequence of loss of the germinal epithelium, was characterized by mild to moderate decreases in the numbers of mature spermatozoa in the body and tail of the epididymal ducts. Cytoplasmic vacuolization of duct epithelium was a subtle finding of minimal severity noted predominantly in the tail of the epididymis and characterized by increased numbers of ductal epithelial cells that were swollen by a single, large, clear cytoplasmic vacuole. Atrophy was a subtle change noted in the head region of the epididymal duct. In chamber control males, the epididymal duct was lined by densely packed, tall, columnar epithelial cells that appeared pseudostratified due to the occurrence of the basal nuclei at different levels in the cells. In animals exposed to 10 mg/m^3^, the epithelial cells lining the head were not as tall and the basal nuclei were less numerous and less crowded and generally spaced evenly along the basement membrane in a single layer.

#### Tissue Burden Studies

Lung and liver weights and lung, blood, and liver cobalt concentrations were determined in female mice (Table I-11). During the exposure period, lung weights of the 5 and 10 mg/m^3^ groups were significantly greater than those of the chamber controls starting on study day 12 and generally remained elevated compared to the chamber controls until the end of the postexposure period. Increased lung weights were occasionally observed at 2.5 mg/m^3^. Because of the significant changes in lung weights with exposure concentration, lung cobalt burdens rather than lung cobalt concentrations were evaluated for toxicokinetic parameters.

Lung cobalt concentrations and burdens increased with increasing exposure concentration and were increased over chamber controls. Lung cobalt concentrations in chamber control animals were near or below the LOD at all time points. By day 40, lung cobalt concentrations in all exposed groups appeared to be approaching steady state and did not change significantly through the end of exposure (day 89) before steadily decreasing during the recovery period (Table I-11). Lung cobalt burdens increased rapidly within the first 5 to 26 days, but by days 12 to 40, the rate of increase slowed as lung burdens asymptotically approached steady state with the higher concentrations taking longer to approach steady state. During the recovery period, lung cobalt burdens decreased very rapidly during the first week, after which lung clearance of cobalt slowed significantly. Normalized lung cobalt burdens tended to increase with exposure concentration up to 5 mg/m^3^ but were lower in animals exposed to 10 mg/m^3^ than in animals exposed to 5 mg/m^3^, indicating a lack of a nonproportional accumulation at 10 mg/m^3^.

Blood cobalt concentrations in the chamber control animals were at or below the LOD at all time points (Table I-11). During the 3-month exposure, blood cobalt concentrations generally increased in proportion to exposure concentration at all time points and were increased over chamber controls in all groups at all exposure time points and remained elevated through the later postexposure time points. Within each exposure concentration, blood cobalt concentrations appeared to be at or near steady state by study day 12. However during the recovery period, blood cobalt concentrations fell very rapidly to concentrations that were near or below the LOD in an exposure concentration-related manner. Accordingly, because of the rapid and extensive elimination of cobalt from the blood, it was not possible to demonstrate dose proportionality from blood concentration data collected during the recovery period.

Liver weights of the 5 and 10 mg/m^3^ groups were significantly less than that of the chamber control group on day 26; similar, although not statistically significant decreased liver weights in these exposed groups were observed on day 40 (Table I-11). Liver cobalt concentrations in chamber control animals were at or below the LOD at both time points. During the 3-month exposure, liver cobalt concentrations and burdens generally increased with exposure concentration and were increased compared to the chamber controls at both time points. Liver cobalt concentrations and total liver cobalt burdens for exposed animals were higher at all exposure concentrations on day 26 compared to day 40 (except for cobalt concentration in animals exposed to 10 mg/m^3^).

Pulmonary clearance of cobalt during the recovery period showed a well-defined two-phase elimination profile (Table I-12). The rapid phase exhibited half-lives ranging from 1.4 to 3.2 days and was followed by a slower lung clearance phase with half-lives of 27 to 39 days; there was no clear relationship to exposure concentration in either phase. A two-compartment clearance model could not be fit to the lung cobalt burden data collected during the 3-month study due to the lack of data collected prior to 5 days of exposure, however a one-compartment model provided an adequate fit to these data (Table I-13). The results indicated that half-lives ranged from 2.4 to 17 days (increased with increasing exposure concentration) for animals exposed to 5 mg/m^3^ or less. The half-life in animals exposed to 10 mg/m^3^ was 122 days, but the standard errors for the clearance rate constant and subsequently the calculated half-life were high (>80%) making these data unreliable.

Exposure Concentration Selection Rationale: Based on reductions in body weights and moderate severity of nose and lung lesions in the 10 mg/m^3^ groups in the 3-month study, this exposure concentration was considered too high to be used in the 2-year study. Hence, 5 mg/m^3^ was selected as the highest exposure concentration for the 2-year inhalation study in mice.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 26 and in the Kaplan-Meier survival curves (Figure 5). Survival of males exposed to 2.5 or 5 mg/m^3^ was significantly less than that of the chamber control group.

Table 26 Survival of Mice in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 5 | 13 | 12 | 17
Natural deaths | 6 | 6 | 9 | 8
Animals surviving to study termination | 39 | 31 | 29^c^ | 25^d^
Percent probability of survival at end of study^a^ | 78 | 62 | 58 | 50
Mean survival (days)^b^ | 715 | 695 | 672 | 668
Survival analysis^e^ | P = 0.004 | P = 0.102 | P = 0.035 | P = 0.003
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 9 | 12 | 19 | 21
Natural deaths | 5 | 2 | 4 | 3
Animals surviving to study termination | 36 | 36^f^ | 27 | 26
Percent probability of survival at end of study | 72 | 70 | 54 | 52
Mean survival (days) | 686 | 695 | 680 | 668
Survival analysis | P = 0.019 | P = 1.000 | P = 0.110 | P = 0.061

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ Includes one animal that died during the last week of the study.

^d^ Includes three animals that died during the last week of the study.

^e^ The result of the life table trend test^174^ is in the chamber control column, and the results of the life table pairwise comparisons^173^ with the chamber controls are in the exposed group columns.

^f^ Includes two animals that died during the last week of the study.

Figure 5

Kaplan-Meier Survival Curves for Mice Exposed to Cobalt Metal by Inhalation for Two Years

#### Body Weights and Clinical Findings

Mean body weights of 5 mg/m^3^ males and females were at least 10% less than those of the chamber control groups after weeks 85 and 21, respectively (Table 27, Table 28 and Figure 6). Abnormal breathing and thinness were noted in exposed male and female mice.

Table 27 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of Cobalt Metal

Day | Chamber Control | | 1.25 mg/m^3^ | | | 2.5 mg/m^3^ | | | 5 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 23.6 | 50 | 23.5 | 99 | 50 | 23.1 | 98 | 50 | 23.2 | 98 | 50
8 | 25.4 | 50 | 25.1 | 99 | 50 | 24.9 | 98 | 50 | 24.9 | 98 | 50
15 | 26.5 | 50 | 26.0 | 98 | 50 | 25.5 | 96 | 50 | 26.1 | 98 | 50
22 | 27.7 | 50 | 27.1 | 98 | 50 | 27.0 | 97 | 50 | 26.9 | 97 | 50
29 | 28.8 | 50 | 28.3 | 98 | 50 | 28.2 | 98 | 50 | 28.2 | 98 | 50
36 | 30.1 | 50 | 29.5 | 98 | 50 | 29.3 | 98 | 50 | 29.2 | 97 | 50
43 | 31.1 | 50 | 30.5 | 98 | 50 | 30.1 | 97 | 50 | 30.0 | 96 | 50
50 | 32.4 | 50 | 31.8 | 98 | 50 | 31.2 | 96 | 50 | 30.8 | 95 | 50
57 | 33.2 | 50 | 32.9 | 99 | 50 | 32.3 | 98 | 50 | 31.9 | 96 | 50
64 | 34.3 | 50 | 34.0 | 99 | 50 | 33.3 | 97 | 50 | 33.0 | 96 | 50
71 | 35.5 | 50 | 35.1 | 99 | 50 | 34.1 | 96 | 50 | 33.6 | 95 | 50
78 | 36.4 | 50 | 35.9 | 99 | 50 | 35.0 | 96 | 50 | 34.1 | 94 | 50
85 | 37.4 | 50 | 37.1 | 99 | 50 | 35.9 | 96 | 50 | 35.0 | 94 | 50
113 | 40.8 | 50 | 41.1 | 101 | 50 | 39.6 | 97 | 50 | 37.7 | 93 | 50
141 | 43.5 | 50 | 44.0 | 101 | 50 | 42.7 | 98 | 50 | 40.0 | 92 | 50
169 | 45.7 | 50 | 45.8 | 100 | 50 | 45.0 | 99 | 50 | 42.3 | 93 | 50
197 | 47.4 | 50 | 47.8 | 101 | 50 | 47.1 | 100 | 50 | 44.7 | 94 | 50
225 | 49.1 | 50 | 49.0 | 100 | 50 | 48.6 | 99 | 50 | 45.5 | 93 | 50
253 | 50.0 | 50 | 50.0 | 100 | 50 | 50.2 | 100 | 50 | 47.5 | 95 | 49
281 | 51.1 | 50 | 50.8 | 100 | 50 | 50.9 | 100 | 50 | 48.1 | 94 | 49
309 | 51.5 | 50 | 51.6 | 100 | 50 | 51.8 | 101 | 50 | 49.1 | 95 | 49
337 | 52.1 | 50 | 52.2 | 100 | 50 | 52.3 | 101 | 50 | 49.7 | 96 | 49
365 | 52.9 | 50 | 52.8 | 100 | 50 | 52.9 | 100 | 49 | 50.3 | 95 | 49
393 | 53.3 | 50 | 53.4 | 100 | 50 | 53.3 | 100 | 48 | 50.9 | 96 | 49
421 | 53.6 | 50 | 53.5 | 100 | 50 | 54.2 | 101 | 47 | 51.3 | 96 | 49
449 | 53.5 | 50 | 53.6 | 100 | 50 | 54.0 | 101 | 47 | 51.5 | 96 | 48
477 | 53.8 | 50 | 53.9 | 100 | 49 | 54.5 | 101 | 45 | 51.4 | 96 | 47
505 | 54.0 | 50 | 53.5 | 99 | 49 | 54.3 | 101 | 45 | 51.1 | 95 | 47
533 | 54.2 | 50 | 53.4 | 99 | 49 | 54.5 | 101 | 44 | 49.9 | 92 | 47
561 | 54.3 | 49 | 52.8 | 97 | 48 | 54.1 | 101 | 44 | 49.5 | 91 | 45
589 | 53.2 | 49 | 51.8 | 97 | 46 | 52.6 | 99 | 43 | 48.8 | 92 | 40
617 | 53.6 | 49 | 52.2 | 98 | 43 | 51.5 | 96 | 42 | 47.6 | 89 | 38
645 | 53.4 | 48 | 53.1 | 100 | 39 | 51.3 | 96 | 39 | 46.3 | 87 | 36
659 | 53.8 | 45 | 52.4 | 98 | 39 | 50.4 | 94 | 36 | 44.2 | 82 | 35
673 | 52.7 | 45 | 52.3 | 99 | 38 | 50.0 | 95 | 35 | 42.5 | 81 | 34
687 | 52.4 | 43 | 52.0 | 99 | 37 | 49.0 | 94 | 34 | 40.9 | 78 | 32
701 | 51.8 | 42 | 51.8 | 100 | 36 | 47.5 | 92 | 32 | 40.1 | 77 | 29
715 | 51.2 | 40 | 51.8 | 101 | 34 | 47.0 | 92 | 31 | 39.5 | 77 | 26
Mean for Weeks
1–13 | 31.0 | – | 30.5 | 99 | – | 30.0 | 97 | – | 29.8 | 96 | –
14–52 | 47.9 | – | 48.0 | 100 | – | 47.6 | 99 | – | 45.0 | 94 | –
53–103 | 53.2 | – | 52.8 | 99 | – | 51.9 | 98 | – | 47.2 | 89 | –

Table 28 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of Cobalt Metal

Day | Chamber Control | | 1.25 mg/m^3^ | | | 2.5 mg/m^3^ | | | 5 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt.(g) | Wt. (% of Controls) | No. of Survivors
1 | 19.8 | 50 | 19.7 | 99 | 50 | 19.6 | 99 | 50 | 19.6 | 99 | 50
8 | 21.3 | 50 | 21.0 | 99 | 50 | 21.1 | 99 | 50 | 21.0 | 99 | 50
15 | 22.1 | 50 | 21.6 | 98 | 50 | 21.9 | 99 | 50 | 21.8 | 99 | 50
22 | 23.2 | 50 | 22.6 | 97 | 50 | 22.9 | 99 | 50 | 23.0 | 99 | 50
29 | 23.9 | 50 | 23.7 | 99 | 50 | 23.9 | 100 | 50 | 23.5 | 98 | 50
36 | 24.9 | 50 | 24.6 | 99 | 50 | 25.0 | 100 | 50 | 24.2 | 97 | 50
43 | 25.6 | 50 | 25.7 | 100 | 50 | 25.8 | 101 | 50 | 25.0 | 98 | 50
50 | 26.2 | 50 | 26.7 | 102 | 50 | 26.9 | 103 | 50 | 26.0 | 99 | 50
57 | 27.3 | 50 | 27.7 | 102 | 50 | 28.0 | 103 | 50 | 26.9 | 98 | 50
64 | 28.6 | 50 | 28.7 | 100 | 50 | 29.1 | 102 | 50 | 27.4 | 96 | 50
71 | 29.1 | 50 | 29.9 | 103 | 50 | 30.3 | 104 | 50 | 28.5 | 98 | 50
78 | 29.7 | 50 | 31.0 | 104 | 50 | 31.3 | 106 | 50 | 29.2 | 98 | 50
85 | 30.6 | 50 | 32.3 | 105 | 50 | 32.6 | 106 | 50 | 29.5 | 96 | 50
113 | 34.6 | 50 | 37.0 | 107 | 50 | 37.0 | 107 | 50 | 32.2 | 93 | 50
141 | 38.6 | 50 | 40.8 | 106 | 50 | 40.9 | 106 | 50 | 35.0 | 91 | 50
169 | 41.8 | 50 | 43.4 | 104 | 50 | 43.8 | 105 | 50 | 37.6 | 90 | 50
197 | 44.3 | 50 | 46.2 | 104 | 50 | 46.3 | 105 | 50 | 39.7 | 90 | 50
225 | 47.4 | 49 | 48.6 | 103 | 50 | 48.0 | 101 | 50 | 41.0 | 87 | 50
253 | 49.7 | 49 | 50.8 | 102 | 50 | 50.4 | 101 | 50 | 43.1 | 87 | 50
281 | 53.2 | 49 | 53.1 | 100 | 50 | 51.9 | 98 | 50 | 44.1 | 83 | 50
309 | 56.5 | 49 | 55.5 | 98 | 50 | 53.9 | 95 | 50 | 45.1 | 80 | 50
337 | 59.1 | 49 | 57.5 | 97 | 50 | 56.0 | 95 | 50 | 46.7 | 79 | 50
365 | 60.4 | 49 | 59.2 | 98 | 50 | 57.7 | 96 | 50 | 47.7 | 79 | 49
393 | 62.6 | 48 | 61.1 | 98 | 49 | 59.2 | 95 | 50 | 48.8 | 78 | 49
421 | 64.6 | 47 | 62.4 | 97 | 49 | 60.7 | 94 | 50 | 50.1 | 78 | 49
449 | 65.6 | 47 | 62.5 | 95 | 49 | 61.1 | 93 | 50 | 50.3 | 77 | 49
477 | 66.7 | 47 | 62.9 | 94 | 49 | 61.2 | 92 | 49 | 49.7 | 75 | 49
505 | 65.9 | 46 | 62.9 | 95 | 48 | 61.0 | 93 | 49 | 49.7 | 75 | 47
533 | 66.3 | 45 | 62.8 | 95 | 47 | 60.9 | 92 | 48 | 50.1 | 76 | 45
561 | 65.1 | 45 | 64.3 | 99 | 45 | 61.1 | 94 | 46 | 49.6 | 76 | 43
589 | 64.9 | 44 | 62.6 | 96 | 45 | 60.5 | 93 | 42 | 48.5 | 75 | 41
617 | 63.2 | 43 | 61.9 | 98 | 44 | 60.8 | 96 | 38 | 46.8 | 74 | 38
645 | 62.0 | 43 | 60.0 | 97 | 43 | 58.2 | 94 | 37 | 47.5 | 77 | 34
659 | 61.9 | 40 | 60.2 | 97 | 41 | 58.3 | 94 | 35 | 44.7 | 72 | 34
673 | 60.7 | 40 | 60.7 | 100 | 39 | 56.3 | 93 | 35 | 44.8 | 74 | 30
687 | 59.1 | 40 | 59.5 | 101 | 38 | 56.2 | 95 | 33 | 43.8 | 74 | 28
701 | 59.1 | 37 | 58.6 | 99 | 37 | 56.0 | 95 | 31 | 42.0 | 71 | 28
715 | 58.5 | 37 | 57.3 | 98 | 36 | 56.3 | 96 | 27 | 40.6 | 70 | 26
Mean for Weeks
1–13 | 25.6 | – | 25.6 | 101 | – | 26.0 | 102 | – | 25.0 | 98 | –
14–52 | 47.2 | – | 48.1 | 102 | – | 47.6 | 101 | – | 40.5 | 87 | –
53–103 | 62.9 | – | 61.2 | 97 | – | 59.1 | 94 | – | 47.2 | 75 | –

Figure 6

Growth Curves for Mice Exposed to Cobalt Metal by Inhalation for Two Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the lung, nose, larynx, trachea, and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Lung: The incidences of alveolar/bronchiolar adenoma in males exposed to 2.5 mg/m^3^ and females exposed to 5 mg/m^3^ and the incidences of alveolar/bronchiolar carcinoma and alveolar adenoma or carcinoma (combined) in all exposed groups of male and female mice were significantly greater than those in the chamber controls (Table 29, Table C-1, Table C-2, Table D-1, and Table D-2). The incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) occurred with positive trends and exceeded the historical control ranges for inhalation studies and all routes of administration (Table 29, Table C-3, and Table D-3). In addition, significantly increased incidences of multiple alveolar/bronchiolar carcinoma occurred in all exposed groups of males and females.

Table 29 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Mice in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Number Examined Microscopically | 50 | 49 | 50 | 50
Alveolar/bronchiolar Epithelium, Hyperplasia^a^ | 0 | 46** (1.0)^b^ | 49** (1.6) | 50** (2.3)
Alveolar/bronchiolar Epithelium, Vacuolization Cytoplasmic | 0 | 49** (1.1) | 47** (1.9) | 48** (3.1)
Alveolar Epithelium, Hyperplasia | 4 (2.3) | 29** (1.7) | 24** (1.8) | 43** (2.0)
Bronchiole, Epithelium, Hyperplasia | 4 (2.5) | 7 (1.3) | 9 (1.3) | 11* (1.5)
Bronchiole, Epithelium, Erosion | 0 | 4 (1.0) | 10** (1.3) | 2 (1.0)
Proteinosis | 2 (1.0) | 46** (1.7) | 49** (3.1) | 50** (3.9)
Alveolus, Infiltration Cellular, Histiocyte | 10 (1.8) | 49** (1.8) | 48** (2.5) | 48** (3.1)
Inflammation, Suppurative | 1 (1.0) | 2 (2.0) | 6* (1.5) | 16** (2.3)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | 1 | 0
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^d^ | 7/50 (14%) | 11/49 (22%) | 15/50 (30%) | 3/50 (6%)
Adjusted rate^e^ | 14.7% | 24.5% | 35.9% | 7.3%
Terminal rate^f^ | 5/39 (13%) | 7/31 (23%) | 14/29 (48%) | 2/25 (8%)
First incidence (days) | 684 | 571 | 660 | 571
Poly-3 test^g^ | P = 0.254N | P = 0.176 | P = 0.016 | P = 0.226N
Alveolar/bronchiolar Carcinoma, Multiple | 3 | 18** | 24** | 36**
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 11/50 (22%) | 38/49 (78%) | 42/50 (84%) | 46/50 (92%)
Adjusted rate | 22.8% | 79.4% | 87.6% | 93.8%
Terminal rate | 8/39 (21%) | 24/31 (77%) | 25/29 (86%) | 22/25 (88%)
First incidence (days) | 561 | 551 | 382 | 425
Poly-3 test | P<0.001 | P<0.001 | P<0.001 | P<0.001
Alveolar/bronchiolar Adenoma or Carcinoma^i^
Overall rate | 16/50 (32%) | 41/49 (84%) | 43/50 (86%) | 47/50 (94%)
Adjusted rate | 33.0% | 85.0% | 89.7% | 95.9%
Terminal rate | 11/39 (28%) | 26/31 (84%) | 26/29 (90%) | 23/25 (92%)
First incidence (days) | 561 | 551 | 382 | 425
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Female
Number Examined Microscopically | 49 | 50 | 50 | 50
Alveolar/bronchiolar Epithelium, Hyperplasia | 0 | 49** (1.1) | 49** (1.9) | 50** (2.7)
Alveolar/bronchiolar Epithelium, Vacuolization Cytoplasmic | 0 | 48** (1.1) | 49** (1.9) | 48** (3.5)
Alveolar Epithelium, Hyperplasia | 2 (2.5) | 27** (1.6) | 26** (1.4) | 41** (1.4)
Bronchiole, Epithelium, Hyperplasia | 0 | 3 (1.0) | 12** (1.1) | 26** (1.2)
Bronchiole, Epithelium, Erosion | 0 | 0 | 4 (1.0) | 3 (1.0)
Proteinosis | 0 | 45** (1.4) | 50** (2.6) | 50** (3.9)
Alveolus, Infiltration Cellular, Histiocyte | 10 (1.7) | 49** (1.6) | 50** (2.5) | 49** (3.1)
Inflammation, Suppurative | 0 | 3 (1.3) | 2 (1.0) | 15** (1.7)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | 0 | 1
Alveolar/bronchiolar Adenoma (includes multiple)^j^
Overall rate | 3/49 (6%) | 9/50 (18%) | 8/50 (16%) | 10/50 (20%)
Adjusted rate | 6.9% | 19.9% | 18.9% | 24.5%
Terminal rate | 3/36 (8%) | 7/35 (20%) | 6/27 (22%) | 6/26 (23%)
First incidence (days) | 731 (T) | 505 | 626 | 593
Poly-3 test | P = 0.037 | P = 0.067 | P = 0.087 | P = 0.024
Alveolar/bronchiolar Carcinoma, Multiple | 1 | 7* | 20** | 24**
Alveolar/bronchiolar Carcinoma (includes multiple)^k^
Overall rate | 5/49 (10%) | 25/50 (50%) | 38/50 (76%) | 43/50 (86%)
Adjusted rate | 11.3% | 53.8% | 78.9% | 87.7%
Terminal rate | 3/36 (8%) | 18/35 (51%) | 19/27 (70%) | 21/26 (81%)
First incidence (days) | 583 | 537 | 457 | 478
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Alveolar/bronchiolar Adenoma or Carcinoma^l^
Overall rate | 8/49 (16%) | 30/50 (60%) | 41/50 (82%) | 45/50 (90%)
Adjusted rate | 18.0% | 63.7% | 84.6% | 91.6%
Terminal rate | 6/36 (17%) | 22/35 (63%) | 21/27 (78%) | 22/26 (85%)
First incidence (days) | 583 | 505 | 457 | 478
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 39/300 (13.0% ± 4.2%), range 8%–20%; all routes: 145/950 (15.3% ± 6.2%), range 2%–26%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical incidence for inhalation studies: 59/300 (19.7% ± 3.4%), range 16%–24%; all routes: 132/950 (13.9% ± 7.1%), range 4%–24%.

^i^ Historical incidence for inhalation studies: 90/300 (30.0% ± 5.5%), range 26%–40%; all routes: 263/950 (27.7% ± 5.7%), range 16%–40%.

^j^ Historical incidence for inhalation studies: 16/299 (5.4% ± 3.7%), range 2%–12%; all routes: 54/949 (5.7% ± 3.6%), range 0%–12%.

^k^ Historical incidence for inhalation studies: 13/299 (4.4% ± 4.3%), range 0%–10%; all routes: 38/949 (4.0% ± 3.6%), range 0%–14%.

^l^ Historical incidence for inhalation studies: 28/299 (9.4% ± 4.8%), range 2%–16%; all routes: 90/949 (9.5% ± 4.8%), range 2%–22%.

Alveolar/bronchiolar adenomas were small, generally nodular masses that distorted the alveolar architecture and compressed the adjacent parenchyma. Most adenomas consisted of interlacing papillary fronds and folds which projected into alveolar spaces and were lined by well differentiated cuboidal to low columnar epithelium supported by scant fibrovascular stroma (Figure 28). Other more solid appearing adenomas were composed of closely packed nests or cords of polygonal to cuboidal, lightly eosinophilic cells that completely filled the alveolar spaces. Alveolar/bronchiolar carcinomas were discrete to locally infiltrative, compressive, nodular to irregularly shaped masses that effaced the alveolar parenchyma and ranged in diameter from 1 to over 10 millimeters. Smaller carcinomas were relatively well differentiated neoplasms that were morphologically similar to adenomas but were distinguished by their slightly greater cellular pleomorphism and architectural disorganization. Larger carcinomas were clearly malignant neoplasms which were composed of poorly differentiated, pleomorphic anaplastic cells with a variety of growth patterns ranging from complex papillary, tubular, and/or glandular, and less commonly, solid sheets (Figure 29, Figure 30, and Figure 31). Many lungs that had carcinomas also had multiple, small nests of neoplastic cells randomly scattered throughout the lung parenchyma and occasionally on the pleura. Among the exposed mice with lung carcinomas, metastases occurred in various other organs including the liver, kidney, heart, nose, trachea, pancreas, cecum, adrenal cortex/medulla, coagulating gland, epididymis, testes, lymph nodes, thymus, skin, and skeletal muscle.

Figure 28

Low Magnification of an Alveolar/Bronchiolar Adenoma in the Lung of a Male B6C3F1/N Mouse Exposed to 2.5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The adenoma (arrows) has distinctly demarcated from the surrounding alveolar parenchyma and is composed of uniformly cuboidal cells arranged as papillary structures.

Figure 29

Low Magnification of an Alveolar/Bronchiolar Carcinoma in the Lung of a Male B6C3F1/N Mouse Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The carcinoma (arrows) has invaded and almost completely effaced the lung lobe. Note the pleomorphic appearance of the neoplasm.

Figure 30

Higher Magnification of Figure 29 (H&E)

Note the pleomorphic arrangement of the neoplastic cells that form poorly and well-defined papillary structures composed of cuboidal to columnar cells in one area of the neoplasm and in a solid sheet in another area.

Figure 31

Alveolar/Bronchiolar Carcinoma in the Lung of a Female B6C3F1/N Mouse Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Note the highly anaplastic nature of this carcinoma with marked variation in cellular and size and shape, pleomorphic sometimes bizarre and multilobulated nuclei and numerous mitotic figures.

Point mutations in Kras (67%), Egfr (17%), and Tp53 (19%) were noted in the alveolar/bronchiolar carcinomas in mice chronically exposed to cobalt metal dust, and none were found in spontaneously arising alveolar/bronchiolar carcinomas in chamber control mice. The results for the molecular analyses are presented in Appendix K.

A spectrum of nonneoplastic lesions occurred in the lungs of male and female mice (Table 29, Table C-4, and Table D-4). The incidences of alveolar/bronchiolar epithelium hyperplasia and cytoplasmic vacuolization, alveolar epithelium hyperplasia, proteinosis, and alveolus infiltration cellular histiocyte occurred with positive trends in male and female mice and were significantly increased in all exposed groups of males and females. The incidences of bronchiole epithelium hyperplasia occurred with positive trends in males and females and were significantly increased in males exposed to 5 mg/m^3^ and females exposed to 2.5 or 5 mg/m^3^. The incidence of bronchiole epithelium erosion was significantly increased in males exposed to 2.5 mg/m^3^. The incidences of suppurative inflammation were significantly increased in males exposed to 2.5 or 5 mg/m^3^ and females exposed to 5 mg/m^3^. In general, the severities of these nonneoplastic lesions increased with increasing exposure concentration.

Nonneoplastic lesions invariably occurred together and presented as a complex mixture of lesions that at times were difficult to separate as individual lesions. Alveolar/bronchiolar epithelium hyperplasia and alveolar/bronchiolar epithelium cytoplasmic vacuolization were changes that occurred in the epithelium of the periacinar region of the lung which encompassed the terminal bronchioles, associated alveolar ducts, and immediately adjacent alveoli. The primary change throughout the epithelium was cytoplasmic vacuolization of the epithelium of terminal bronchioles and associated alveolar ducts and immediately adjacent alveoli that was also observed to a lesser extent in the larger bronchioles and bronchi. Cells with cytoplasmic vacuolization were swollen, cuboidal to irregularly polygonal, and had finely vacuolated to diffusely clear cytoplasm with small hyperchromic nuclei (Figure 32); generally, there was a decrease or absence of the surface cilia and apical blebbing that are characteristic of the normal ciliated epithelium and mouse Clara cells. Focally to multifocally, the epithelium of the terminal bronchioles appeared thickened by disorganized proliferation and piling up of vacuolated, cuboidal to polygonal epithelial cells that frequently extended into the alveolar ducts and the adjacent alveoli; these changes were diagnosed as alveolar/bronchiolar epithelium hyperplasia (Figure 32). Hyperplasia of the alveolar epithelium occurred as focal, discrete, irregular, noncompressive proliferations of alveolar epithelial (Type II) cells distributed randomly within the parenchyma or adjacent to the terminal bronchioles with preservation of the underlying alveolar architecture. These foci consisted of several contiguous alveolar septa lined by uniformly small cuboidal cells with small, hyperchromatic nuclei (Figure 33); occasional karyomegalic cells were present. Hyperplasia of the bronchiole epithelium was characterized by proliferation of cuboidal to low columnar bronchiolar epithelial cells as few to multiple papillary structures that were supported by scant fibrous stroma and which projected into the lumens of the terminal bronchioles (Figure 34). Erosion of the bronchiole epithelium consisted of minimal, focal denudation of bronchiolar epithelial cells with associated minimal necrosis.

Figure 32

Alveolar/Bronchiolar Epithelial Hyperplasia in the Lung of a Female B6C3F1/N Mouse Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

There is disorganized proliferation and piling up of the epithelial cells with extension of the proliferating cells along the immediately adjacent alveolar septae (arrows). Note numerous macrophages and proteinaceous material within the alveoli.

Figure 33

Focal Alveolar Epithelial Hyperplasia in the Lung of a Male B6C3F1/N Mouse Exposed to 2.5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The alveolar septa are lined by cuboidal to polygonal alveolar epithelial (Type II) cells; the alveolar architecture is generally maintained. Note epithelial cells with large (karyomegaly) pleomorphic nuclei (arrows).

Figure 34

Focal Bronchiolar Epithelial Hyperplasia in a Terminal Bronchiole (Arrows) of a Male B6C3F1/N Mouse Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

The hyperplastic epithelium (arrows) forms multiple papillary structures that project into the lumen and are lined by cuboidal to low columnar epithelial cells and supported by scant amounts of fibrovascular stroma.

Alveoli contained a complex mixture of proteinaceous material (diagnosed as proteinosis) and inflammatory cells. Alveolar proteinosis in mice was morphologically similar to proteinosis in rats and was characterized by accumulation of variable amounts of brightly eosinophilic material within alveolar spaces and ducts with extension into the lumens of the bronchioles in the more extreme cases. The character of this material ranged from pale eosinophilic, flocculent to amorphous aggregates to brightly eosinophilic, dense, round to irregular clumps free within alveolar spaces or alveolar macrophages. In the more severe cases of proteinosis, there were single or aggregated slender, elongated, acicular to rectangular fractile, crystalline or spicule-like structures free within the alveoli or alveolar macrophages (Figure 35). Almost diffusely mixed with this proteinaceous material were increased numbers of histiocytes/macrophages that occurred as small, scattered aggregates to massive accumulations that on occasion completely occluded the alveoli in large regions of the lung. The histiocyte/macrophage infiltrates were mixtures of small to swollen macrophages to multinucleated giant cells. Many were distended with proteinaceous material or, especially in the lower exposure concentration groups, had cytoplasm that was lightly eosinophilic to gray, finely granular or foamy (amphophilic). Large histiocytes/macrophages and multinucleated giant cells contained the refractile, crystalline/specular-like structures. Accumulations of small histiocyte/macrophage infiltrates aggregated adjacent to alveolar/bronchiolar neoplasms (especially larger carcinomas). Also considered a component of this lesion were multifocal accumulations of plump foamy histiocytes/macrophages within the alveolar spaces; such cells were more frequent in the lower exposure concentration groups. Together, these histiocyte/macrophage infiltrates were diagnosed as histiocytic cellular infiltration of the alveolus (Figure 35). Mixed with the alveolar proteinaceous material and histiocyte/macrophage infiltrates were areas of prominent neutrophil accumulation that were diagnosed as suppurative inflammation. This occurred primarily in the male and female mice exposed to 5 mg/m^3^ and consisted of variably sized, localized accumulations of neutrophils and necrotic debris within alveoli. In areas of intense neutrophil accumulation, the alveolar septa were sometimes necrotic or even completely effaced; peribronchiolar edema, intraalveolar hemorrhage, and bacteria were occasionally observed in association with suppurative inflammation.

Figure 35

Alveolar Histiocytic Infiltrates in the Lung of a Male B6C3F1/N Mouse Exposed to 5 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

Alveoli contain numerous macrophages many of which are multinucleated and swollen with protein and slender needle-like crystalline material (arrows). Note larger crystals free within the alveoli. Note low numbers of neutrophils and lymphocytes within the alveoli.

Nose: A spectrum of nonneoplastic lesions occurred in exposed groups of males and females and the incidences of these lesions were generally significantly greater than those in the chamber control groups (Table 30, Table C-4, and Table D-4). For some lesions, the severities increased with increasing exposure concentration.

Table 30 Incidences of Nonneoplastic Lesions of the Nose, Larynx, and Trachea in Mice in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Nose^a^ | 50 | 49 | 50 | 50
Inflammation, Suppurative^b^ | 16 (1.1)^c^ | 32** (1.9) | 49** (2.7) | 50** (3.1)
Olfactory Epithelium, Atrophy | 3 (1.0) | 46** (1.2) | 42** (1.2) | 31** (1.2)
Olfactory Epithelium, Hyperplasia | 0 | 25** (1.2) | 17** (1.0) | 8** (1.1)
Olfactory Epithelium, Metaplasia, Respiratory | 5 (1.4) | 24** (1.3) | 44** (2.3) | 50** (3.1)
Olfactory Epithelium, Respiratory Metaplasia, Atypical | 0 | 14** (2.0) | 9** (1.1) | 1 (1.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 13 (1.2) | 29** (1.1) | 29** (1.1) | 7 (1.0)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 41** (1.2) | 39** (1.2) | 37** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 3 (1.0) | 45** (1.0) | 35** (1.1) | 33** (1.2)
Turbinate, Atrophy | 3 (1.3) | 25** (1.3) | 49** (2.1) | 50** (3.3)
Larynx | 48 | 47 | 49 | 50
Respiratory Epithelium, Metaplasia, Squamous | 7 (1.0) | 47** (1.0) | 49** (1.0) | 49** (1.0)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 20** (1.0) | 24** (1.0) | 32** (1.1)
Squamous Epithelium, Hyperplasia | 2 (1.0) | 5 (1.0) | 5 (1.0) | 8* (1.0)
Trachea | 48 | 47 | 48 | 50
Epithelium, Vacuolization Cytoplasmic | 0 | 14** (1.4) | 31** (1.6) | 37** (1.4)
Female
Nose | 50 | 50 | 50 | 50
Inflammation, Suppurative | 3 (1.0) | 47** (2.3) | 50** (3.1) | 50** (3.3)
Olfactory Epithelium, Atrophy | 4 (1.0) | 44** (1.2) | 39** (1.2) | 24** (1.2)
Olfactory Epithelium, Hyperplasia | 1 (1.0) | 22** (1.1) | 16** (1.0) | 8* (1.0)
Olfactory Epithelium, Metaplasia, Respiratory | 1 (1.0) | 26** (1.8) | 44** (2.7) | 50** (3.3)
Olfactory Epithelium, Respiratory Metaplasia, Atypical | 0 | 18** (1.6) | 14** (1.5) | 1 (1.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 12 (1.0) | 38** (1.1) | 40** (1.2) | 10 (1.0)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 40** (1.0) | 47** (1.1) | 47** (1.1)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 49** (1.2) | 49** (1.4) | 50** (1.5)
Turbinate, Atrophy | 0 | 44** (2.2) | 50** (2.9) | 50** (3.4)
Larynx | 47 | 50 | 50 | 47
Respiratory Epithelium, Metaplasia, Squamous | 2 (1.0) | 49** (1.0) | 50** (1.0) | 47** (1.1)
Respiratory Epithelium, Vacuolization Cytoplasmic | 0 | 24** (1.0) | 31** (1.0) | 34** (1.0)
Squamous Epithelium, Hyperplasia | 2 (1.0) | 13** (1.1) | 21** (1.0) | 21** (1.0)
Squamous Epithelium, Erosion | 1 (1.0) | 2 (1.0) | 7* (1.0) | 4 (1.0)
Trachea | 48 | 50 | 48 | 49
Epithelium, Vacuolization Cytoplasmic | 0 | 26** (1.4) | 37** (1.6) | 39** (1.8)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Suppurative inflammation in the nasal cavity of mice was morphologically similar to suppurative inflammation in the rats. It occurred primarily in the Level II nasal section and consisted of accumulations of neutrophils, proteinaceous fluid, and cellular debris in the nasal passages at all levels of the nose and was occasionally associated with fragments of plant material. Neutrophils sometimes infiltrated the nasal epithelium and lamina propria, and occasionally, the inflammatory process extended into the nasolacrimal duct, maxillary sinuses, and vomeronasal organ.

Atrophy of the olfactory epithelium was of minimal to mild severity and occurred in the epithelium of the dorsal meatus in Levels II and III and the ethmoturbinates of Level III. In general, olfactory epithelial atrophy in mice was morphologically similar to olfactory epithelial atrophy in the rats and was characterized by focal to diffuse hypocellularity and disorganization of the epithelium, often with increased extent of clear intercellular spaces with or without an overall decrease in height of the epithelium. There were variable decreases in the size and number of the nerve bundles and submucosal glands in the adjacent lamina propria. Hyperplasia of the olfactory epithelium was of minimal to mild severity and consisted of scattered focal proliferation of basal olfactory epithelial cells that extended through the basal lamina into the adjacent lamina propria often associated with Bowman’s gland ducts. The cells were sometimes clustered in small intraepithelial nests or extended into the lamina propria around the Bowman’s gland ducts.

Respiratory metaplasia of the olfactory epithelium was of minimal to mild severity and observed more frequently in the dorsal meatus of Level II and on the nasal septum and ethmoturbinates in Level III. These lesions consisted of replacement of olfactory epithelium by ciliated, cuboidal to tall columnar, respiratory-type epithelial cells. The metaplastic epithelium occurred as crypt-like folds and invaginations and extended into the ducts of the submucosal Bowman’s glands. In 1.25 and 2.5 mg/m^3^ animals of both sexes, there were focal, highly site-specific, often bilaterally symmetrical, exophytic lesions located on the dorsal surface of the dorsal scroll. These focal lesions seemingly arose in areas that resembled respiratory metaplasia. The lesions were slightly to prominently elevated above the surface of the ethmoturbinates and in extreme cases, formed synechia with opposing dorsal turbinates and the roof of the dorsal meatus. Morphology ranged from small, single, or few rosette- or gland-like structures, to larger more complex formations of glands lined by flattened to ciliated respiratory type epithelium (Figure 36). These unusual lesions were diagnosed as olfactory epithelium atypical respiratory metaplasia.

Figure 36

Bilateral Atypical Respiratory Epithelial Metaplasia in the Olfactory Epithelium of a Male B6C3F1/N Mouse Exposed to 1.25 mg/m^3^ Cobalt Metal by Inhalation for Two Years (H&E)

There is exophytic proliferation of tall ciliated columnar epithelial cells from the dorsal surface of the dorsal scrolls of the ethmoid turbinates with synechia formation between the turbinate scroll and the epithelium lining the dorsal meatus (arrows).

Hyaline droplet accumulation in the respiratory epithelium occurred with minimal severity and involved the respiratory epithelium adjacent to the junction with squamous epithelium lining the ventral aspects of the nasal passages in Levels I and II, adjacent to the incisive duct in Level II, and overlying the vomeronasal organ. Hyaline droplet accumulation consisted of intracytoplasmic, homogenous, eosinophilic, globular material in the cytoplasm of the respiratory epithelial cells.

Cytoplasmic vacuolization of the respiratory epithelium primarily occurred with minimal to mild severity and affected the respiratory epithelium of the dorsal to mid-septum and/or the dorsal meatus of Level I and occasionally Level II (lateral walls and metaplastic region of the dorsal meatus). The morphology of cytoplasmic vacuolization was similar to that observed in the bronchiolar epithelium. In affected sites, the normally tall, pseudostratified, ciliated, columnar epithelium was replaced by plump, variably ciliated, cuboidal to polygonal epithelial cells that had finely vacuolated to diffusely clear cytoplasm.

Squamous metaplasia of the respiratory epithelium of minimal to mild severity was generally similar to this lesion in the rat study. It occurred in the Level I and to a lesser extent, Level II sections along the dorsal to mid-septum and on the tips of the nasoturbinates and maxilloturbinates. Squamous metaplasia was characterized by replacement of the normally current single layer of ciliated columnar respiratory epithelium by nonkeratinized, flat, squamous epithelial cells.

Turbinate atrophy was a minimal to moderate change that was similar to this lesion in the rat study. It was characterized by often prominent attenuation of the bone and structures of the lamina propria including the glands, vessels, nerve bundles, interstitial stroma on the naso-, maxilla-, and ethmoturbinates and the medial septum at Levels I, II, III. This resulted in narrowing, shortening, distortion, and sometimes loss of the turbinates, as well as occasional adhesions of turbinate remnants to each other, the nasal septum, or the lateral walls. The nasal septum was often buckled, bent, and sometimes perforated.

Larynx: The incidences of respiratory epithelium squamous metaplasia and cytoplasmic vacuolization in all exposed groups of males and females were significantly greater than those in the chamber controls (Table 30, Table C-4, and Table D-4). The incidences of squamous epithelium hyperplasia were significantly increased in all exposed groups of females and in males exposed to 5 mg/m^3^. The incidence of squamous epithelium erosion was significantly increased in females exposed to 2.5 mg/m^3^. All of these laryngeal lesions were of minimal severity.

Respiratory epithelium squamous metaplasia involved the epithelium at the base of the epiglottis overlying the medial submucosal glands and consisted of one to a few layers of flattened, non-ciliated, low-cuboidal to squamous epithelial cells replacing the ciliated, tall, columnar epithelium that normally occurs in this location. Respiratory epithelium cytoplasmic vacuolization was a subtle focal to diffuse change that occurred in the epithelium lining the dorsal aspects and lateral walls of Levels II and III laryngeal sections and was morphologically similar to cytoplasmic vacuolization observed in the bronchiolar epithelium. The ciliated columnar epithelial cells normally seen in the sites were shorter (cuboidal), in general had lost their cilia, and had slightly vacuolated to clear cytoplasm. Squamous epithelium hyperplasia was a focal change most common in the epithelium along the medial aspects and tips of the vocal processes of the arytenoid cartilages and consisted of increased layers of lining epithelial cells from the normal two to three cell layers to four to six cell layers. Erosion was characterized by small focal areas of epithelial necrosis and loss of the superficial epithelium in areas of hyperplastic squamous epithelium.

Trachea: The incidences of minimal to mild epithelium cytoplasmic vacuolization were significantly increased in all exposed groups of males and females (Table 30, Table C-4, and Table D-4). Cytoplasmic vacuolization in the epithelium lining the trachea and the submucosal tracheal glands was morphologically similar to that observed in the bronchiolar and laryngeal epithelia.

Testes: The incidence of minimal to mild germinal epithelium degeneration in male mice exposed to 5 mg/m^3^ was significantly greater than that in the chamber controls (chamber control, 9/50; 1.25 mg/m^3^, 14/49; 2.5 mg/m^3^, 8/50; 5 mg/m^3^, 21/50; Table C-4). Germinal epithelium hyperplasia was generally a minimal to mild lesion usually affecting one to a few scattered seminiferous tubules. Affected tubules were characterized by partial to complete absence of spermatogenic cells often with concurrent swelling of the Sertoli cells with resultant hypocellularity and decreased height of the germinal epithelium. The lumens were generally empty but sometimes contained few spermatozoa, sloughed germinal epithelial cells, or cellular debris.

#### Tissue Burden Studies

Lung weights of female mice were significantly increased starting on day 4 in groups exposed to 2.5 or 5 mg/m^3^ and continuing until day 548 (Table I-14). At 1.25 mg/m^3^, lung weights were increased on days 366 and 548; because of these increases in lung weights, lung cobalt burdens rather than lung cobalt concentrations were evaluated for toxicokinetic parameters.

Cobalt concentrations and burdens in the lung increased with increasing exposure concentration and were significantly increased in all exposed groups of female mice at all time points compared to those in the chamber control group (Table I-14). Cobalt concentrations in the chamber control group were at or below the LOD at all time points. By day 184, lung cobalt concentrations for all exposed groups appeared to reach steady state and did not change significantly through day 548. Lung cobalt burdens increased rapidly by day 4, but by day 184, the rate of increase slowed as lung burdens asymptotically approached steady state. Analysis of lung cobalt burdens normalized to exposure concentration indicated that there were proportional increases between the 1.25 and 2.5 mg/m^3^ groups, but nonproportional increases were observed between the 2.5 and 5 mg/m^3^ groups. At the earlier time points, normalized lung cobalt burdens were lower in animals exposed to 5 mg/m^3^ than in those exposed to 2.5 mg/m^3^; however the opposite was true at the longer exposure durations, where normalized cobalt burdens were greater than proportional relative to the 2.5 mg/m^3^ group.

The lung cobalt burden data from the exposure phases of the 3-month and 2-year studies were modeled using a two-compartment model (Figure I-2). Rapid clearance phase half-lives were 1.2, 1.1, and 5.2 days, respectively, for the 1.25, 2.5, and 5 mg/m^3^ groups, indicating a slightly longer half-life in animals exposed to 5 mg/m^3^ (Table I-15). Cobalt deposition rates for the rapid clearance phase were 0.87, 1.84, and 1.18 μg cobalt/day at 1.25, 2.5, and 5 mg/m^3^, respectively. Slow clearance phase half-lives revealed the opposite trend, with half-lives of 409, 172, and 118 days with increasing exposure concentration. Cobalt deposition rates for the slow clearance phase were 0.027, 0.075, and 0.25 μg cobalt/day. The overall theoretical steady-state lung cobalt burdens, including both the rapid and slow clearance phases (L_SSa_ + L_SSb_), were approximately 17.8, 21.4, and 51.8 μg cobalt/lung in the 1.25, 2.5, and 5 mg/m^3^ groups, respectively; these data support the achievement of steady state in the 2.5 and 5 mg/m^3^ groups but not in the 1.25 mg/m^3^ group. The fractions of deposition in the slow clearance phase (F_B_) for the exposed groups were quite low, increasing from 0.031 to 0.176 as exposure concentration increased, corresponding to total slow phase lung cobalt clearances of 3.1% to 17.6%; clearances of total deposited cobalt during the rapid clearance phase ranged from 96.9% to 82.4% [(1−F_B_) × 100] with increasing exposure concentration.

## Genetic Toxicology

Results of the bacterial mutagenicity tests conducted with cobalt metal (the same lot of chemical that was used in the 2-year studies) are presented in Table E-1 and Table E-2. Cobalt metal (100 to 5,000 μg/plate) gave an equivocal response in Salmonella typhimurium strain TA100 in the absence of S9 activation mix; with 10% rat liver S9, doses up to 7,500 μg/plate did not induce an increase in mutant colonies in TA100. In S. typhimurium strain TA98 without S9, cobalt metal (100 to 3,500 µg/plate) was mutagenic, although the responses observed were weak and not well correlated with dose level; with S9, no mutagenic activity was observed. In Escherichia coli strain WP2 uvrA/pKM101, doses of cobalt metal up to 450 μg/plate were not associated with mutagenic activity, with or without S9. No increases in the frequencies of micronucleated normochromatic erythrocytes were observed in peripheral blood of male or female mice exposed to cobalt metal (0.625 to 10 mg/m^3^) for 3 months by inhalation (Table E-3). No significant alterations in the percentages of reticulocytes (polychromatic erythrocytes) were seen in male or female mice, suggesting that exposure to cobalt metal under these conditions did not cause bone marrow toxicity.