# Materials and Methods

## Procurement and Characterization of Cobalt Metal

Cobalt metal was produced by OMG Kokkola Chemicals Oy (Kokkola, Finland) and was provided by the Cobalt Development Institute via PEL Technologies in one lot (P32 3040-1) that was used in the 2-week, 3-month, and 2-year studies. Identity and purity analyses were performed by the study laboratory at Battelle Toxicology Northwest [Richland, WA; inductively coupled plasma/atomic emission spectroscopy (ICP/AES) analysis] and by the analytical chemistry laboratories at Pacific Northwest National Laboratory [Richland, WA; X-ray diffraction (XRD) and proton-induced X-ray emission (PIXE) analyses], AMIA Laboratories (The Woodlands, TX; XRD using Rietveld analysis), H&M Analytical Services, Inc. (Allentown, NJ; XRD with and without Rietveld analysis), Elemental Analysis, Inc. (Lexington, KY; PIXE), and Galbraith Laboratories (Knoxville, TN; coulometry for total carbon) (Appendix L). Reports on analyses performed in support of the cobalt metal studies are on file at the National Institute of Environmental Health Sciences.

Lot P32 3040-1 of the chemical, a silver-gray powder, was identified as cobalt metal by the analytical chemistry laboratories using XRD. XRD patterns were consistent with library reference patterns for cubic and hexagonal phases of cobalt. The purity of lot P32 3040-1 was determined by the analytical chemistry laboratories by determination of the carbon content using combustion/coulometric analysis by induction furnace with a carbon dioxide coulometer and by PIXE analyses to determine the presence of cobalt metal and trace element impurities with atomic numbers from 11 (sodium) to 53 (iodine) or 92 (uranium). The study laboratory quantitated the purity of the bulk chemical using ICP/AES. The carbon content was determined to be 0.09% ± 0.01%. PIXE analysis indicated trace elements of aluminum, sulfur, calcium, chromium, and iron. Chromium was consistently current at approximately 84 ppm; the other impurities were below the minimum detection limits. ICP/AES analysis indicated a purity of 98.2% ± 0.6% relative to a National Institute of Standards and Technology standard reference material [(SRM); cobalt SRM 3113, Gaithersburg, MD]. The overall purity of cobalt metal was determined to be greater than 98%.

To ensure stability, the bulk chemical was stored at room temperature in safety-coated amber glass containers with Teflon^®^-lined caps under a nitrogen headspace. Periodic reanalyses of the bulk chemical were performed by the study laboratory using ICP/AES; no degradation of the bulk chemical was detected.

## Aerosol Generation and Exposure System

During the 2-week studies, an auger feed device was used to meter cobalt metal into a Trost jet mill for aerosolization and particle size reduction. For the 3-month and 2-year studies, the generation system used a linear feed device to meter cobalt metal into the jet mill. Initial particle size reduction was accomplished within the Trost jet mill. From the jet mill, aerosol was directed to the main distribution line where it was diluted with humidified air then conveyed from the exposure control center to the exposure room where it passed through a cyclone separator to further reduce particle size. On exiting the cyclone, the aerosol-laden air was directed to either of two smaller branch lines. From the branch lines, aerosol was delivered to each exposure chamber by a sampling tube. The flow through the sampling tube was induced by a stainless steel ejector pump. The aerosol then entered the chamber inlet duct where it was further diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chambers so that uniform aerosol concentrations could be maintained throughout the chambers with the catch pans in place. The total volume of the chamber was 2.3 m^3^ with an active mixing volume of 1.7 m^3^. Tests showed that aerosol concentration could be reliably maintained homogenous within 8% throughout the chambers, provided the aerosol was uniformly mixed before passing through the chamber inlet and provided the test material did not react to a significant extent with animals, animal excrement, or the chamber interior.^164^

## Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table L-1 through Table L-3. The concentration of cobalt metal in the exposure chambers and room air was monitored using three real-time aerosol monitors (RAMs). Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and cobalt metal concentrations that were determined by analyzing tandem Teflon^®^-coated, glass-fiber filters collected daily from the exposure chambers. Cobalt was extracted from the filters and analyzed using ICP/AES. The ICP/AES instrument was calibrated against serially diluted NIST-traceable 10 mg/mL spectrometric standards of cobalt and the internal standard yttrium.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of Cobalt Metal

Two-week Studies | Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice | F344/NTac rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
12 days | 12 or 13 (male rats) days | 12 days
Average Age When Studies Began
5 to 6 weeks | 5 to 6 weeks | 5 to 6 weeks
Date of First Exposure
August 2, 2004 | Rats: March 7 (females) or 8 (males), 2005 Mice: March 7, 2005 | Rats: May 8, 2006 Mice: May 15, 2006
Duration of Exposure
6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 16 (rats) or 17 (mice) days | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 105 weeks
Date of Last Exposure
Rats: August 17, 2004 Mice: August 18, 2004 | Rats: June 6 (female) or 7 (males), 2005 Mice: June 8 (males) or 9 (females), 2005 | Rats: May 5–8, 2008 Mice: May 15, 2008
Necropsy Dates
Rats: August 17, 2004 Mice: August 18, 2004 | Rats: June 7 (females) or 8 (males), 2005 Mice: June 9 (males) or 10 (females), 2005 | Rats: May 5–8, 2008 Mice: May 12–16, 2008
Average Age at Necropsy
8 weeks | 19 to 20 weeks | Rats: 109 to 110 weeks Mice: 109 to 111 weeks
Size of Study Groups
5 males and 5 females (core study) 5 females (tissue burden study) | Rats: 10 males and 10 females (core study) 10 males (clinical pathology) 32 to 36 females (special study) Mice: 10 males and 10 females (core study) 32 to 36 females (special study) | 50 males and 50 females (core study) 35 females (lung burden study)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies | Same as 2-week studies
Animals per Cage
1 | 1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods and urine collection, changed weekly | Irradiated NTP-2000 wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods, changed weekly | Same as 3-month studies
Water
Tap water (Richland, WA municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 2-week studies | Same as 2-week studies
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed weekly, rotated daily | Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed weekly, rotated weekly in chambers | Same as 3-month studies
Cageboard
Untreated paper cage pan liner (Techboard, Shepherd Specialty Papers, Kalamazoo, MI), changed daily | Same as 2-week studies | Same as 2-week studies
Chamber Air Supply Filters
Single HEPA (open stock), charcoal (RSE, Inc., New Baltimore, MI), Purafil (Environmental Systems, Lynnwood, WA), all new at study start | Same as 2-week studies, except new at beginning of 2-week studies and changed as needed | Same as 2-week studies, except HEPA filter changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE); chambers changed weekly; excreta pans changed daily | Same as 2-week | Same as 2-week studies
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Temperature: 72° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Temperature: 72° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour
Exposure Concentrations
0, 2.5, 5, 10, 20, or 40 mg/m^3^ | Rats: 0, 0.625, 1.25, 2.5, or 5 mg/m^3^ Mice: 0, 0.625, 1.25, 2.5, 5, or 10 mg/m^3^ | 0, 1.25, 2.5, or 5 mg/m^3^
Type and Frequency of Observation
Observed once daily; core study animals were weighed on days 1, 5, and 12 and at the end of the studies; clinical findings were recorded once daily and at terminal kill. | Observed twice daily; core study animals were weighed initially, on day 9 (male rats) or 10, weekly thereafter, and at the end of the studies; clinical findings were recorded on day 9 (male rats) or 10, weekly thereafter, and at the end of the studies. | Observed twice daily; core study animals weighed initially, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill; clinical findings were recorded initially and every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies | Same as 2-week studies
Necropsy
Necropsies were performed on all core study rats and mice. Following blood collection, the right femur, heart, right kidney, liver (right lateral and caudate lobes), right lung lobe, and right testis were collected from core study rats and mice and weighed. In addition, whole liver, whole lung and left lung plus mainstem bronchi were weighed. For tissue burden study rats and mice, the lungs with mainstem bronchi were removed and weighed and the right and left lung lobes were collected and weighed individually. Samples were stored in plastic containers at approximately −70°C until analyzed for cobalt metal. | Necropsies were performed on core study and special study rats and mice. For core study animals, organs weighed were heart, right kidney, liver, lung, right testis, thymus, and thyroid gland (rats). | Necropsies were performed on all animals.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology male rats and 10 special study female rats on days 3 and 23 and from core study animals at the end of the studies for hematology and clinical chemistry (rats). Hematology: hematocrit; packed cell volume; hemoglobin; erythrocyte, reticulocyte, and platelet counts; total nucleated cells; Howell-Jolly bodies (mice); mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, cholesterol, triglyceride, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts | None
Histopathology
Histopathology was performed on core study 0, 20 (rats), and 40 (rats and mice) mg/m^3^ animals. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: left kidney, liver (left and median lobes), and thyroid gland (rats and mice), brain (rats), and urinary bladder (male rats). The left lung and nose were examined in all core study animals. | Complete histopathology was performed on core study 0 (rats and mice), 5 (rats), and 10 (mice) mg/m^3^ animals. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mesenteric, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mesenteric, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 1.25 (rats), 2.5, 5, or 10 (mice) mg/m^3^ groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for 12 days during the last 2 weeks of the study from females exposed to 0, 1.25 (rats), 2.5, 5, or 10 (mice) mg/m^3^. | None
Tissue Burden Studies
Urine was collected from core study rats for 16 hours beginning day 12; volume and creatinine and cobalt metal concentrations were determined. Blood was collected from the retroorbital sinus of core study rats and mice and two female tissue burden study rats and mice per group on the last day of exposure and from three female tissue burden study rats and mice per group 3 weeks postexposure; blood and serum were analyzed for cobalt metal concentration. Following blood collection, the right femur, heart, right kidney, liver (right lateral and caudate lobes), right lung lobe, and right testis were collected from core study animals and weighed. In addition, whole liver, whole lung, and left lung plus mainstem bronchi were removed and weighed and the right and left lung lobes were collected and weighed individually. Tissues were analyzed for cobalt metal concentration. | Lungs and blood (retroorbital sinus) were collected from three special study female rats and mice per exposure group on days 5, 12, 26, 40, 61, and 89 and on days 7, 14, 28, and 42 postexposure. Liver (right lateral and caudate lobes) was also collected on days 26 and 40. Liver and lungs were weighed; blood, liver, and lungs were analyzed for cobalt metal concentration. | On days 1, 2, 3, 4, 184, 366, and 548, lungs were removed from five female lung burden study rats and mice per group, weighed, and analyzed for cobalt metal concentration.
Cytochrome P450 Activities
None | On days 26 and 40, liver samples from special study rats and mice not used for the tissue burden studies were collected and acetanilide-4-hydroxylase, 7-ethoxyresorufin-O-deethylase, and 7-pentoxyresorufin-O-deethylase activities were determined. | None
Mutation Analysis of Alveolar/bronchiolar Carcinomas
None | None | DNA was extracted from the formalin-fixed, paraffin-embedded, rat and mouse alveolar/bronchiolar carcinomas. The samples were subjected to semi-nested PCR to amplify hot spot regions of Kras, Egfr, and Tp53. The lyophilized polymerase chain reaction products were sequenced, and the resulting electropherograms were compared to identify mutations in alveolar/bronchiolar carcinomas that either arose spontaneously or due to exposure to cobalt metal.

## Chamber Atmosphere Characterization

Particle size distribution was determined once prior to the 3-month and 2-year studies, once during the 2-week studies, twice during the 3-month studies, and monthly during the 2-year studies. Impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor and the stages (glass coverslips lightly coated with silicone to prevent particle bounce) were analyzed using ICP/AES after cobalt was extracted from the slides. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis.^165^ The resulting estimates of the mass median aerodynamic particle diameter and the geometric standard deviation of each set of samples are given in Table L-4 through Table L-7.

Buildup and decay rates for chamber aerosol concentrations were determined with (all studies) and without (3-month and 2-year studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 9.4 minutes. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week and 3-month studies and every 3 to 4 months during the 2-year studies. Chamber concentration uniformity was maintained throughout the studies. The persistence of cobalt metal in the exposure chambers after aerosol delivery ended was determined by monitoring the concentration overnight in the 40 mg/m^3^ rat and mouse chambers in the 2-week studies, the 5 mg/m^3^ rat and 10 mg/m^3^ mouse chambers in the 3-month studies, and the 5 mg/m^3^ rat and mouse chambers in the 2-year studies, with and without (except for the 2-week studies) animals present in the chambers. The average cobalt metal concentration decreased to 1% of the target concentration within 15 (2-week studies), 17 to 18 (3-month studies), or 19 (2-year studies) minutes.

Stability studies of the test material in the generation and exposure system were performed before and during the studies by the study laboratory and the analytical chemistry laboratories. In these studies, XRD analyses consistently indicated two primary phases of cobalt in the samples, cubic and hexagonal, and minimal detectable concentrations of cobalt oxides. Low and acceptable levels of trace element inorganic impurities were detected in these stability samples using PIXE and ICP/AES assays.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY) for the 2-week and 3-month studies. For the 2-year studies, male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc., and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years, NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP to evaluate different rat models. The F344/NTac rat was used in four subchronic and two chronic studies (cobalt metal and bromodichloroacetic acid) between 2005 and 2006.^166^ The current cobalt metal study is the first of the NTP 2-year studies using the F344/NTac rat to be reported.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the studies, serologic analyses were performed on five male and five female sentinel rats and mice housed in the control chamber using the protocols of the NTP Sentinel Animal Program (Appendix N).

Groups of five male and five female rats and mice were exposed to cobalt metal particulate aerosol by inhalation at concentrations of 0, 2.5, 5, 10, 20, or 40 mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 16 (rats) or 17 (mice) days. Additional groups of five female rats and mice were exposed to the same concentrations for 16 (rats) or 17 (mice) days for tissue burden studies. Feed and water were available ad libitum, except feed was withheld during exposure periods and urine collection. Rats and mice were housed individually. Clinical findings were recorded once daily and at terminal kill for core study rats and mice. The core study animals were weighed on days 1, 5, and 12 and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

As part of the tissue burden studies, surviving core study rats were placed in metabolism cages on day 12 for a 16-hour urine collection. Urine samples were collected over ice. Volume was measured, and creatine concentration was determined. Remaining samples were stored at approximately −70°C until analyzed for cobalt metal concentration using ICP/AES following open digestion in a heat block. The parameters measured are listed in Table 1.

For tissue burden studies, blood was collected from the retroorbital sinus of all surviving core study rats and mice and two female tissue burden study rats and mice per group on the last day of exposure and from three female tissue burden study rats and mice per group 3 weeks postexposure. Blood was divided between a collection tube containing EDTA and a serum tube without anticoagulant. Blood and serum samples were stored at approximately −70°C for analysis of cobalt metal concentration. Following blood collection, the right femur, heart, right kidney, liver (right lateral and caudate lobes), right lung lobe, and right testis were collected from core study rats and mice and weighed. In addition, whole liver, whole lung, and left lung plus mainstem bronchi were weighed. For tissue burden study rats and mice, the lungs with mainstem bronchi were removed and weighed and the right and left lung lobes were collected and weighed individually. Samples were stored in plastic containers at approximately −70°C until analyzed for cobalt metal. For analyses, blood, serum, femur (femurs were boiled in water, extraneous tissue scraped off, and dried for at least 48 hours before digestion), heart, kidney, and testis samples were prepared in acid-leached Parr bomb digestion liners (Parr Instrument Co., Moline, IL) using an Imperial II radiant heat oven (Lab-line Instruments, Inc., Melrose Park, IL), and liver and lung samples were prepared in microwave digestion liners and a microwave sample preparation station (CEM Corp., Matthews, NC) with internal standard (10 μg yttrium; 0.1 μg gallium) and HNO_3_:HCl (1:1). Digests were quantitatively transferred to plastic containers and diluted to an appropriate volume with deionized water before analysis using ICP/AES (IRIS Intrepid ICP/AES spectrometer, Thermo Elemental, Franklin, MA) (kidney, liver, lung) or ICP/mass spectrometry (MS) (Agilent 7500cc ICP/MS, Agilent Technologies, Palo Alto, CA) (blood, serum, femur, heart, and testis).

Necropsies were performed on all core study rats and mice. The heart, left kidney, liver, lung, left testis, thymus, and thyroid gland were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned, and stained with hematoxylin and eosin. Histopathologic examinations were performed on core study chamber control animals, 20 mg/m^3^ rats, and 40 mg/m^3^ rats and mice. The left kidney, left and median liver lobes, and thyroid gland of rats and mice, the brain of rats, and the urinary bladder of male rats were examined to a no-effect level; the left lobe of the lung and the nose were examined in all core study groups. Table 1 lists the tissues and organs examined.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to cobalt metal and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 or 13 days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Serologic analyses were performed during the studies using the protocols of the NTP Sentinel Animal Program (Appendix N).

Groups of 10 male and 10 female rats and mice were exposed to particulate aerosols of cobalt metal by inhalation at concentrations of 0, 0.625, 1.25, 2.5, 5, or 10 (mice only) mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 14 weeks. Additional groups of 10 male rats (clinical pathology study) and 32 to 36 female rats and mice (special study) were exposed to the same concentrations for 14 weeks. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded weekly beginning day 9 (male rats) or 10 and at the end of the studies. Core study animals were weighed initially, weekly beginning day 9 (male rats) or 10, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Blood was collected from the retroorbital sinus of male clinical pathology rats and 10 female special study rats on days 3 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats) analyses. Blood for hematology was placed in tubes containing potassium EDTA, and blood for clinical chemistry was placed in tubes containing a separator gel. Hematology analyses were performed on an Abbott Cell-Dyn 3700 analyzer (Abbott Diagnostics Systems, Abbott Park, IL), except manual hematocrit determinations were performed using a microcentrifuge (Hereaus Holding Gmbh., Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needhum Heights, MA). Platelet, leukocyte, and erythrocyte morphology and nucleated erythrocytes were assessed using smears stained with a Romanowsky-type aqueous stain in a Wescor 7100 aerospray slide stainer (Wescor, Inc., Logan, UT). Reticulocytes were stained with new methylene blue and counted using the Miller disc method.^167^ Samples for clinical chemistry were centrifuged, and parameters were measured using a Roche Hitachi 912 system (Roche Diagnostic Corp., Indianapolis, IN). Table 1 lists the clinical pathology parameters measured.

Lungs and blood (retroorbital sinus) were collected from three special study female rats and mice per exposure group on days 5, 12, 26, 40, 61, and 89 and on days 7, 14, 28, and 42 postexposure. On days 26 and 40, livers were also collected. Liver and lungs were weighed. Blood, liver (right lateral and caudate lobes), and lungs were analyzed for cobalt metal concentrations as described for the 2-week studies, except all samples for analysis were placed in microwave sample digestion vessels.

On days 26 and 40, the remaining liver samples from special study rats and mice were collected and stored at approximately −70°C until analyses for cytochrome P450 activities. Microsomal suspensions were prepared using the Pearce Method.^168^ The concentration of protein in each suspension was determined using the microtiter plate method of the Coomassie^®^ Plus Protein Assay (Pierce Chemical Co., Rockford, IL) with bovine serum albumin as the standard. Acetanilide-4-hydroxylase (A4H), 7-ethoxyresorufin-O-deethylase (EROD), and 7-pentoxyresorufin-O-deethylase (PROD) were determined in microsomal proteins isolated from frozen liver samples according to established procedures.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats exposed to 0, 1.25, 2.5, or 5 mg/m^3^ and mice exposed to 0, 2.5, 5, or 10 mg/m^3^. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study and special study animals. The heart, right kidney, liver, lung, right testis, thymus, and thyroid gland (rats) of core study animals were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on core study 0, 5 (rats), and 10 (mice) mg/m^3^ groups of rats and mice; tissues were examined to a no-effect level in the remaining groups. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^169^ and Boorman et al.^170^

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats and mice were exposed to cobalt metal by inhalation of particulate aerosol at concentrations of 0, 1.25, 2.5, or 5 mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for up to 105 weeks. Additional groups of 35 lung burden study female rats and mice were exposed to the same concentrations of cobalt metal for up to 79 weeks.

Rats were 3 to 4 weeks old on receipt, and mice were 4 to 5 weeks old. The animals were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were approximately 5 to 6 weeks old and mice approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix N).

Rats and mice were housed individually. Feed and water were available ad libitum, except feed was withheld during animal exposures. Chambers and racks were rotated weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix M.

### Clinical Examinations and Pathology

All animals were observed twice daily. Core study animal body weights were recorded on day 1, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill. Clinical findings were recorded every 4 weeks through week 93, then every 2 weeks, and at terminal kill.

Complete necropsies and microscopic examinations were performed on all core study rats and mice; selected necropsies were performed on lung burden study animals. At necropsy, organs and tissues were examined for grossly visible lesions, and all (core study) major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1. For extended evaluation of renal proliferative lesions in male rats, kidneys were step sectioned at 1 mm intervals, and three to eight additional sections were obtained from each kidney.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included larynx, lung, and nose of rats and mice; adrenal medulla and pancreas of rats; kidney and testis of male rats; and spleen of female rats.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^169^ and Boorman et al.^170^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^171^

### Mutation Analysis of Alveolar/bronchiolar Carcinomas

After histopathology examination, formalin-fixed, paraffin-embedded (FFPE) blocks from alveolar/bronchiolar carcinomas that arose either spontaneously (in chamber controls) or due to cobalt metal exposure were selected from rats and mice for mutation analysis of commonly altered genes in lung cancer (Kras, Egfr and Tp53). DNA was extracted from the FFPE tissues and subjected to a seminested polymerase chain reaction (PCR) to amplify hot spot regions of Kras, Egfr and Tp53. The lyophilized PCR products were sequenced, and the resulting electropherograms were compared to identify mutations in alveolar/bronchiolar carcinomas that arose spontaneously or due to exposure to cobalt metal. The results are presented in Appendix K.

### Lung Burden Study

Five female lung burden rats and mice per group were randomly selected and sent to necropsy immediately after exposure on days 1, 2, 3, 4, 184, 366, and 548. The lungs were removed, weighed, and stored at approximately −70°C until analyzed for cobalt metal concentration using an ICP/AES method similar to that described for the 2-week studies.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^172^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^173^ method for testing two groups for equality and Tarone’s^174^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-7, Table B-1, Table B-7, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^175-177^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^175^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^175^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1 mice.^178^ Bailer and Portier^175^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^179^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1−P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^180^ and Williams.^181,182^ Hematology; clinical chemistry; urine, blood, serum, and tissue cobalt metal concentrations; cytochrome P450 activities; spermatid and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^183^ (as modified by Williams^184^) and Dunn.^185^ Jonckheere’s test^186^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^187^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^188^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^189^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^190-192^ In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. The current study is the only inhalation study in F344/NTac rats in the historical control database; therefore only historical control incidences for all routes and all vehicles are used for F344/NTac rats in this Technical Report.

## Quality Assurance Methods

The 2-week, 3-month, and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58^193^). In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of cobalt metal was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^194,195^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^196^ and the somatic mutation theory of cancer.^197,198^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^199^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^200,201^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^202,203^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^204^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.