# Introduction

## Chemical and Physical Properties

Cobalt is a brittle, hard, silver-gray transition metal with ferromagnetic properties. Heating cobalt metal causes oxidation to the mixed oxide, Co (II, III) oxide (Co_3_O_4_); above 900°C, Co (II) oxide (CoO) is the end product. Cobalt metal combines with sulfur, phosphorus, and carbon when heated.^1^ It readily concentrates under oxidizing conditions with manganese oxides.^2^ Cobalt salts have a distinctive brilliant blue color. Cobalt metal exists in two allotropic forms, hexagonal and cubic, both of which are stable in air and water at room temperature.^3^

## Production and Use

Cobalt metal is widely used in the production of cemented tungsten-cobalt (hard metal) and as an alloying element in superalloys, magnetic and hard-facing alloys, cobalt-containing high-strength steels, electrodeposited alloys, and other alloys with special properties.^1,2^ Extra fine cobalt metal powder is an important raw material used in production of cemented carbides, diamond tools, and metal welding and spraying components.^4^ The major uses of cemented carbide-coated tools are metal-cutting operations and mining and quarrying.^5^ It is also used in the manufacture of cobalt salts, and in nuclear medicine, where the isotope ^60^Co is used as a gamma-ray source.^3^ Cobalt is an effective catalyst for many organic reactions, particularly in hydrotreating catalysts, which have molybdenum and cobalt sulfides as active components. It is also used as a target material in electrical x-ray generators^1,6-10^ and in several other military and industrial applications.^9^

Although the United States is the world’s largest consumer of cobalt,^11^ it does not have well-established primary cobalt mining facilities. In 2006, the aggregated national production volume was between 100 and 500 million pounds,^12^ and in 2010 the aggregated national production volume reported to EPA was 23,384,002 pounds.^13^ Comparatively, United States cobalt production between 1964 and 1971 ranged from 690,000 to 1,215,000 pounds.^14^ Import volumes (metric tons) of cobalt into the United States have remained fairly steady during the past years: 10,700 in 2008; 7,680 in 2009; 11,100 in 2010; 10,600 in 2011; and an estimated 11,000 in 2012.^15^

## Environmental and Human Exposure

Occupational exposure to cobalt occurring during the production of cobalt powder is a major concern due to the occurrence of hard metal disease and is primarily via inhalation of dusts, fumes, or mists containing cobalt, targeting the skin and the respiratory tract, during the production, processing, and use of hard metal.^9^ The USEPA’s 2006 IUR records estimated the number of workers likely exposed to cobalt via industrial manufacturing, processing, and use to be ≥1,000 in 1 to 99 worksites.^12^

In the environment, cobalt is the 33rd most abundant element, composing approximately 0.0025% of the weight of the earth’s crust and is present naturally in the soil in varying concentrations ranging from approximately 1 to 40 ppm with an average level of 7 ppm. It occurs naturally in the groundwater and sediments and is mainly derived from erosion of volcanic rocks in the mountains. Exposure of the general population is mainly through breathing air, drinking water, or skin contact with soil, water, cobalt alloys, or other substances that contain cobalt.^9^

Cobalt is also an essential trace element because it is an integral component of cyanocobalamin (vitamin B_12_), the only metal-containing vitamin. Vitamin B_12_ is found in meat and dairy products. Vitamin B_12_ acts as a coenzyme in many enzymatic reactions, most notably in a methyl transfer reaction that converts homocysteine to methionine. It also acts as a coenzyme in a reaction that converts l-methylmalonylcoenzyme A (CoA) to succinyl-CoA.^16^ Vitamin B_12_ is also a part of some enzymes involved in hematopoiesis, and a deficiency can lead to pernicious anemia.^17^ Conditions such as iron deficiency anemia can lead to increased absorption of cobalt from the gastrointestinal tract, and simultaneous administration of cobalt and iron can reduce the amount of cobalt absorbed.^18,19^

## Regulatory Status

Cobalt is included in the Unregulated Contaminant Monitory Rule contaminant list; its minimum reporting level is 1 µg/L for the reporting period of January 1, 2013, to December 31, 2015.^20^ Total cobalt is also listed as a hazardous constituent for municipal solid waste landfills,^21^ and is on the groundwater monitoring list.^22^ Cobalt became regulated under the toxic chemical release reporting: community right-to-know on January 1, 1987.^23^ The American Conference of Governmental Industrial Hygienists (ACGIH)^24^ has given cobalt a classification of A3, confirmed animal carcinogen with unknown relevance to humans, and established an 8-hour time-weighted average (TWA) of 0.02 mg/m^3^ for occupational exposure. Occupational Safety and Health Administration (OSHA)^25^ has promulgated an 8-hour permissible exposure limit of 0.1 mg/m^3^, and the National Institute for Occupational Safety and Health recommends an 8-hour TWA of 0.05 mg/m.^3,26^ The Minimal Risk Level (MRL) is based on the no-observed-adverse-effect level of 0.0053 mg cobalt/m^3^ for decreased respiratory function in exposed workers.^27^ A MRL of 1 × 10^−4^ mg/kg per day has been derived for chronic-duration inhalation exposure (> 365 days) to cobalt.^9^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

There are numerous studies showing that cobalt is absorbed rapidly following inhalation exposure in animals and distributed to various tissues with significant levels in the lungs.^28-35^ Following inhalation exposure of rats to 0.0004 to 0.2 ppm (0.001 to 0.5 mg/m^3^) pure cobalt 24 hours per day for 3 months, a dose-dependent distribution and accumulation of cobalt was reported in the thyroid gland, spleen, liver, kidney, and lung.^35^ In SD-Jcl rats exposed to 0.880 ppm (2.12 mg/m^3^) cobalt aerosol 5 hours/day for 4 days, the average cobalt content of the lung and blood 2 hours after the last exposure was 6.42 μg/g and 28.94 μg/L, respectively. The values 28 days after exposure were 0.09 μg/g (1.5 nmol/g) and 0.40 μg/L (6.8 nM), respectively, for lung and blood. The clearance of cobalt in both blood and lung was biphasic with half-lives in the lung of 52.8 and 156 hours and in the blood of 52.8 and 172.8 hours, for the first and second phases, respectively.^33^ In miniature swine following inhalation exposure to 0.04 to 0.41 ppm (0.1 to 1.0 mg/m^3^) pure cobalt powder 6 hours/day, 5 days/week for 3 months, cobalt was excreted mostly by the kidney.^31,36^

Cobalt levels in rat urine 24 hours following intratracheal instillation of a tungsten carbide-cobalt mixture were approximately threefold higher compared to instillation of cobalt powder at the same dose.^37^ It was later confirmed that this was not due to higher bioavailability but due to rapid urinary excretion following exposure to the tungsten carbide-cobalt mixture.^38^ The mean lung cobalt concentration in rats given cobalt was two times more than that of rats given a tungsten carbide-cobalt mixture at 48 hours following exposure; by day 7, mean levels had decreased significantly to almost the same level in all exposed rats.^38^

The chemical form of a cobalt compound can affect the absorption of cobalt following oral exposure. In rats following oral exposure to cobalt chloride, the absorption was 13% to 34%, whereas the absorption following administration of insoluble cobalt oxide was in the range of 1% to 3%.^19,30,34,39-42^ Although no species difference was observed for absorption of cobalt oxide,^40^ absorption of soluble cobalt compounds was greater in rats (13% to 34%) than in cows (1% to 2%) and guinea pigs (4% to 5%).^19,30,34,39-42^ Absorption was 3- to 15-fold greater in younger animals than in adults.^43^ The absorbed cobalt was distributed primarily to the liver; appreciable levels were also found in the kidney, heart, stomach, and intestines.^39^ In studies where rats were exposed orally to cobalt sulfate or cobalt chloride for longer terms, significant increases in cobalt concentration were reported in the myocardium, muscle and serum, liver, kidney, brain, and testes.^41,44-47^ Fecal excretion of cobalt is the primary route of elimination in animals following oral exposure and varies depending on the dose and the type of cobalt given; no difference in elimination has been noted between species.^30,40,48-51^

### Humans

Workers exposed to cobalt dust and fumes in the production of cobalt powder had mean concentrations of 5 to 48 µg/L in blood and 19 to 438 µg/L in urine compared to blood and urine concentrations in the range from 0.1 to 2 µg/L in nonoccupationally exposed persons.^52^ Following inhalation exposure to insoluble cobalt compounds such as cobalt metal and cobalt oxide, three-phase elimination kinetics were observed in humans. The half-life for the first phase, likely representing mucociliary clearance in the tracheobronchial region, was approximately 2 to 44 hours.^53,54^ The second phase with a half-life of approximately 10 to 78 days may represent macrophage-mediated clearance of cobalt particles from the lung.^54,55^ The third phase clearance with a half-life on the order of years may represent long-term clearance from the lung.^40,54-56^ Using control-aerosol experiments in humans, it has been shown that about 40% of the initial lung burden of inhaled cobalt oxide was retained for a period of 6 months after exposure.^57^ About 33% of the initial lung burden was found in the urine with 28% in feces 6 months after exposure.

The absorption of cobalt in humans following oral exposure varied (18% to 97% of the dose) depending on the type and dose of the cobalt compound and other nutritional status. Fecal excretion of cobalt is the primary route of elimination in humans following oral exposure and varies depending on the dose and the type of cobalt given (3% to 99%).^30,40,48-51,58,59^

Following dermal exposure to hard metal dust (approximately 5% to 15% cobalt metal, 85% to 95% tungsten carbide) for 90 minutes, urinary levels of cobalt increased by about an order of magnitude compared to preexposure samples, demonstrating that dermal absorption occurs.^60^ Cobalt was detected in the fingernails of volunteers who placed their fingers in a cobalt dust solution 10 minutes/day for 7 days.^61^

## Toxicity

The major targets of cobalt toxicity in animals include the respiratory, cardiovascular, hematopoietic, and immune systems. Other targets for cobalt toxicity in animals include the endocrine system, the nervous system, the liver, and the kidney.

### Respiratory System

Inhalation studies of metallic cobalt aerosols and cobalt salts have identified respiratory tract hyperplasia, pulmonary fibrosis, alveolar septa thickening with collagen, elastic tissue, fibroblasts, pleuritis, firm dust lesions, and emphysema as sensitive effects of cobalt on respiratory tissues.^26,31,33,36,62-67^ Exposure of rats and mice to cobalt sulfate heptahydrate by inhalation (up to 30 mg of cobalt sulfate/m^3^) for 13 weeks showed degeneration of the olfactory epithelium, squamous metaplasia of the respiratory epithelium, and inflammation in the nose; inflammation, necrosis, and inflammatory polyps (rats) of the larynx; metaplasia of the trachea (mice); and fibrosis, histiocytic infiltrates, bronchiolar epithelial regeneration, and epithelial hyperplasia in the alveoli of the lung.^66,68,a^ The most sensitive tissue was found to be the larynx.

a ERRATUM: An error was identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

Following inhalation exposure to cobalt-containing particles, the primary target of toxicity in humans is the respiratory tract. Occupational exposure of humans to cobalt metal or cobalt-containing hard metal primarily affects the respiratory system, including decreased pulmonary function, asthma, interstitial lung disease, wheezing, and dyspnea; these effects were reported at occupational exposure levels ranging from 0.015 to 0.13 mg cobalt/m.^3,27,69-92^ These effects have been noted in workers employed in cobalt metal refineries, as well as hard metal workers, diamond polishers, and ceramic dish painters.

### Cardiovascular System

Cardiomyopathies appear to be another primary effect of cobalt-induced toxicity in both animals and humans.^9^ Rats exposed to cobalt sulfate heptahydrate for 13 weeks showed marginal increases in the severity of cardiomyopathy; no such findings were reported in mice.^66,68^ Studies suggest that cardiomyopathies may occur by impairment of oxidation of pyruvate or fatty acids^93^ or by stimulation of carotid body chemoreceptors, thereby mimicking the action of hypoxia.^94-96^

In the 1960s, several breweries added cobalt salts to beer to stabilize foam; this resulted in exposures of 0.04 to 0.14 mg/kg.^9^ Soon after this, an epidemic of “beer-drinkers’ cardiomyopathy” occurred in people who drank 8 to 25 pints/day, resulting in severe cardiovascular system effects, including cardiomyopathy and death.

This cardiomyopathy was evidenced by fragmentation and degeneration of myofibers, enlargement of the heart, and aggregates of abnormal mitochondria.^9,97-99^ The mitochondrial changes are indicative of disturbances in energy production or utilization possibly related to cobalt effects on lipoic acid. Cobalt irreversibly chelates lipoic acids under aerobic conditions.^100^ Lipoic acid is a required cofactor for oxidative decarboxylation of pyruvate to acetyl CoA and of α-ketoglutarate to succinate.^101^

Other observations in people who drank the cobalt-treated beer were gastrointestinal effects (nausea, vomiting) and hepatic necrosis.^102-104^ The epidemic ceased when the addition of cobalt salts to beer was discontinued.

### Hematopoietic System

Exposure to cobalt also affects the hematopoietic system by increasing levels of erythrocytes and hemoglobin in both humans and animals.^9^ Palmes et al.^105^ demonstrated increased levels of hemoglobin in rats and guinea pigs, but not dogs, exposed to cobalt hydrocarbonyl by inhalation. Polycythemia has been reported in rats, but not mice, exposed to airborne cobalt sulfate heptahydrate.^66,68^ Other studies corroborate the above findings of increases in hemoglobin and erythrocyte levels and decreases in blood phospholipids, cholesterol, and β-lipoproteins in rats exposed to metallic cobalt aerosol via inhalation.^35^ Of particular note is an 8-week study in rats that reported dose- and time-related increases in erythrocyte number following oral administration of cobalt chloride.^106^

The most sensitive endpoint following oral exposure to cobalt in humans appears to be an increase in erythrocyte numbers (polycythemia).^9^ This effect has been noted in both normal subjects and in patients who were anemic as a result of being anephric.

### Immune System

Cobalt may exert its effects through interactions with the immune system, mainly resulting in contact sensitization. In guinea pigs, nickel and cobalt sensitization appear to be interrelated and mutually enhancing, though cross-reactivity has not been reported to occur.^107^

The most commonly observed effect following dermal exposure is dermatitis, as demonstrated by a large number of human studies. Patch tests and intradermal injections demonstrate that the dermatitis is probably caused by an allergic reaction to cobalt, with the cobalt ion functioning as a hapten.^84,85,108-115^ Exposure to inhaled cobalt chloride aerosols can precipitate an asthmatic attack in sensitized individuals, suggesting cobalt sensitization is one mechanism by which cobalt-induced asthma may be produced.^84^ IgE and IgA antibodies specific to cobalt have been reported in humans.^84,85,115^ There is evidence that cobalt sensitivity in humans may be regulated by T-lymphocytes.^116^ A human helper T-lymphocyte cell line specific for cobalt (CoCl_2_) has been established.^117^ Cobalt may also interact directly with immunologic proteins, such as antibodies or Fc receptors, resulting in immunosensitization.^118^

### Endocrine System

A study in female mice exposed to 26 mg cobalt/kg per day in drinking water for up to 45 days produced histopathologic changes to the thyroid.^119^ Cobalt significantly stimulated serum testosterone in mice treated orally with 23 mg cobalt chloride/kg, although no dose-response relationship was present.^120^ There have also been reports of increased incidences of pheochromocytoma, a tumor of the adrenal medulla, in female rats exposed to 3.0 mg cobalt sulfate/m^3^(1.14 mg cobalt/m^3^) for 2 years.^121,122,b^

b ERRATUM: An error was identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

### Nervous System

In a study in OFA Sprague Dawley rats, exposure-related delays in hearing, swimming ability, and development of muscle strength and locomotor system were reported in the offspring of dams that were exposed to 0, 25, 50, or 100 mg/kg body weight cobalt sulfate by gavage throughout gestation.^123^ Occupational exposure to cobalt metal in humans has been reported to cause several effects on the nervous system, including memory loss (Wechsler Memory Scale-Revised), nerve deafness, and decreased visual acuity.^124,125^ However, these studies had small numbers of subjects (n=38 or 1), and exposure characterization was not reported.

### Liver

No histologic effects on the liver were found in pigs exposed to cobalt metal dust up to 1.0 mg/m^3^ for 3 months.^31^ Hyperemia of the liver and cytoplasmic changes in hepatocytes (clumpy cytoplasm located along the cell membrane) were noted in rats following oral administration of a single dose of 68.2 mg cobalt fluoride/kg or a single dose of 157.3 mg cobalt oxide/kg.^126^ Increased liver weight (17%) was found in rats exposed to 10 mg cobalt chloride/kg per day for 5 months.^127^ No morphologic or enzymatic changes were noted in the livers of rats exposed to 2.5 to 30.2 mg cobalt chloride/kg by gavage or to cobalt chloride in the drinking water for 3 to 7 months.^128-130^ However, in previous NTP studies, rats and mice exposed by inhalation to cobalt sulfate heptahydrate ([struck: 50 or] up to 200 mg cobalt sulfate [struck: heptahydrate]/m^3^) [struck: or greater] for 16 days demonstrated lesions in the liver, including necrosis and congestion (rats only) [struck: in the liver].^66,68,c^

c ERRATUM: Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration, the effects on specific study animals, and the number of studies evaluated was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

### Kidney

Significant increases were noted in the relative kidney weight in male rats exposed by inhalation to cobalt sulfate heptahydrate (0.3 to 30 mg/m^3^ of cobalt sulfate) for 13 weeks.^66,68^ No effects were observed upon histologic examination of the kidneys in rats or mice following exposure to cobalt sulfate heptahydrate at concentrations of up to 200 mg cobalt sulfate/m^3^ for 16 days, up to 30 mg cobalt sulfate/m^3^ for 13 weeks, or up to 3.0 mg cobalt sulfate/m^3^ for 2 years.^66,68,121,122^ No histologic effects on the kidney were found in pigs exposed to up to 1.0 mg cobalt/m^3^ for 3 months.^31,d^

d ERRATUM: Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

## Reproductive and Developmental Toxicity

### Experimental Animals

Exposure to cobalt-containing aerosols has been shown to affect reproductive endpoints in rats and mice. A decrease in sperm motility in mice was found following exposure to cobalt sulfate heptahydrate at concentrations of 3 to 30 mg cobalt sulfate [struck: heptahydrate]/m^3^ for 13 weeks, and a significant increase in the length of the estrous cycle was reported in female mice exposed to cobalt sulfate heptahydrate at concentrations of 30 mg cobalt sulfate/m^3^ for 13 weeks.^66,68^ Testicular atrophy was reported in rats exposed by inhalation to 50 mg cobalt sulfate [struck: heptahydrate]/m^3^, 6 hours per day for 16 days, but not in rats exposed to 30 mg/m^3^ for 13 weeks. Testicular atrophy was, however, observed in mice exposed to 30 mg/m^3^ per day for 13 weeks.^66,68^ No testicular effects were observed in rats or mice exposed to cobalt sulfate heptahydrate at concentrations of up to 3.0 mg cobalt sulfate/m^3^ for 2 years.^121,122^ These findings are consistent with studies following oral exposure to soluble cobalt chloride for 2 to 3 months in the diet or drinking water. These studies reported testicular degeneration and atrophy in rats exposed to cobalt chloride in the diet^128,131-133^ and in mice exposed to cobalt chloride for 3 weeks in drinking water.^134,135,e^

e ERRATUM: Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

No studies were found in the literature regarding developmental effects in animals following inhalation exposure to cobalt. In a perinatal study design where rat dams were administered 0, 12, 24, or 48 mg/kg of cobalt chloride via oral gavage from gestation day 14 through lactation day 21, offspring displayed stunted growth (all cobalt dose levels) and decreased survival (24 and 48 mg/kg).^136^ No external malformations were observed in the pups. No measurements were collected on the dams, although the authors stated that toxic signs were previously observed in male and female rats administered 24 or 48 mg/kg. The effects on the offspring occurred at levels that also caused maternal toxicity (reduced body weight and food consumption and altered hematological measurements); no teratogenic effects were noted. These authors also reported that rabbits exposed to 20, 100, or 200 mg/kg cobalt sulfate from gestation days 6 to 20 exhibited excessive dose-related maternal toxicity (death and total resorptions). Fetuses in the 20 mg/kg group (only cobalt group available for examination) evaluated at term displayed apparent delays in ossification and increases in percentage of fetuses with retarded body weight. Szakmáry et al.^123^ reported that exposure of pregnant rats to cobalt sulfate did not result in changes in fetal death rates, maternal body weight gain, average litter size, or average fetal or placental weights; however, a dose-related trend was seen for the percent of fetuses with retarded body weights. Increased incidences of axial skeletal anomalies were also observed in rat fetuses exposed to 25 to 100 mg/kg cobalt sulfate.^123^ In contrast, no effects on fetal growth or survival were found following exposure of rats to cobalt chloride during gestation days 6 to 15.^137^ However, the difference in results between the two studies may be explained, at least in part, by exposure concentration, with cobalt sulfate exposure being almost double that of cobalt chloride. There are also reports of preimplantation losses following administration of cobalt in male mice.^138^

Exposure of mice to cobalt chloride during gestation days 8 to 12 was reported to have no effect on fetal growth or mortality.^139^ There were no changes in litter size, postimplantation losses, or average fetal or placental weights in a study that exposed pregnant mice to 50 mg cobalt sulfate/kg body weight per day; there was an increase in the percent of fetuses with retarded body weights.^123^ These authors also reported that rabbits exposed to 20 mg/kg cobalt sulfate showed nearly complete maternal lethality and complete fetal loss. In addition, there were significant increases in mortality and fetal resorption, as well as an increase in fetuses with retarded body weight.

### Humans

No reports were found in the literature on the reproductive effects in humans following inhalation or oral exposure to cobalt. Pregnant women were treated with cobalt chloride to raise hematocrit and hemoglobin levels that are often depressed during pregnancy. Doses up to 0.6 mg cobalt/kg per day for 3 months were given during the final trimester.^129^ No developmental effects were reported in the infants, although examination was limited only to the reporting of obvious birth defects.

## Carcinogenicity

### Experimental Animals

In 2-year inhalation studies of soluble cobalt sulfate heptahydrate, pronounced effects on the respiratory tract, including hyperplasia, inflammation, fibrosis, metaplasia, and increased incidences of cancer in rats and mice were reported.^121,122^ Increased incidences of alveolar/bronchiolar neoplasms occurred in male rats exposed to 3.0 mg cobalt sulfate/m^3^ and in female rats exposed to 1 or 3 mg cobalt sulfate/m^3^.^f^ Neoplasms occurred in both sexes with significantly positive trends. Male and female mice exposed to 3 mg/m^3^ showed increases in alveolar/bronchiolar neoplasms; neoplasms in the lung occurred with significantly positive trends. The findings also demonstrated an increased incidence of pheochromocytoma, a neoplasm of the adrenal medulla, in female rats exposed to 3.0 mg/m^3^ for 2 years without any other endocrine effects. The NTP concluded that under the conditions of the 2-year studies, there was some evidence of carcinogenic activity of cobalt sulfate heptahydrate in male F344/N rats based on increased incidences of alveolar/ bronchiolar neoplasms. Marginal increases in the incidences of pheochromocytomas of the adrenal medulla may have been related to exposure to cobalt sulfate heptahydrate. There was clear evidence of carcinogenic activity in female F344/N rats based on increased incidences of alveolar/bronchiolar neoplasms and pheochromocytomas of the adrenal medulla in groups exposed to cobalt sulfate heptahydrate. There was clear evidence of carcinogenic activity of cobalt sulfate heptahydrate in male and female B6C3F1 mice based on increased incidences of alveolar/bronchiolar neoplasms. Molecular analyses of lung neoplasms were also performed in the study; findings showed an exposure concentration-dependent increase in Kras mutations, thereby suggesting a mechanism of tumorigenesis.

f ERRATUM: Errors were identified in the NTP Technical Report on Cobalt Metal (Technical Report 581). Text clarifying the form of cobalt used to calculate the exposure concentration was added in the HTML and PDF versions of this report; the new information is italicized. [July 3, 2022]

Parenteral exposure to cobalt has also been found to induce neoplasms in rodents.^140-145^ One study reported sarcomas in rats at the site of injection of cobalt salts or cobalt metal powder.^1^ In another study, rats of an unspecified strain were given a single injection of 0.28 mg cobalt metal powder in fowl serum into the thigh muscle.^142,143^ Within 2 weeks, atypical myoblasts were observed,^143^ and between 5 and 12 months, malignant neoplasms developed at the injection site in 17 of 30 rats; 11 of the neoplasms were rhabdomyosarcomas.^142^ Similar neoplastic responses to injections of cobalt sulfide and cobalt oxide were noted in an unspecified strain of rats but not in mice.^140^ Shabaan et al.^145^ noted fibrosarcomas in male Wistar rats 8 months to 1 year after administration of 40 mg cobalt chloride/kg per day by subcutaneous injection for 10 days.

### Humans

Few epidemiological studies of cancer risk in cobalt metal-exposed workers exist.^146^ A high incidence of pulmonary cancer was found in English cobalt metal miners; however, the etiology was not known.^65^ Epidemiological studies of cobalt metal miners in the United States, Canada, Zaire, and other countries found no association between cobalt metal and neoplasm rates; however, cobalt metal was the cause of hard metal respiratory disease.^147^ In a mortality study of a cohort of 1,143 workers in an electrochemical plant producing cobalt metal and sodium (110 were engaged in cobalt metal production) for at least a year during 1950 to 1980, an increased number of deaths from lung cancers were observed in those producing cobalt metal; however, smoking may have been a factor.^148^ Confounding by nickel and arsenic exposures and the limited size of the exposed population were identified as some limitations.^146^ The follow-up (1981 to 1988) did not support the proposed relationship between lung cancer and cobalt metal exposure.^149^

The 12th Report on Carcinogens lists cobalt sulfate and cobalt-tungsten carbide powders and hard metals as reasonably anticipated to be human carcinogens based on sufficient evidence of carcinogenicity from studies in experimental animals.^150^ IARC^1^ has listed cobalt compounds as possibly carcinogenic to humans (Group 2B) based on sufficient evidence for cobalt metal and cobalt oxides and limited evidence for cobalt chloride and cobalt sulfate. However, to date, there are no chronic studies reported on cobalt metal dust in rodents.

## Genetic Toxicity

There is a paucity of data on the genetic toxicity of metallic cobalt, likely due to the assumption that its biological activity is mediated by its ionic forms. However, it has been shown that at least some of the biological activities of the metal cannot be attributed to its ionic forms.^151^ The focus of this review is on the genetic toxicity of cobalt metal and not on its ionic or hard metal forms. For reviews of cobalt and cobalt compound toxicities, see De Boeck et al.^152^, Lison et al.^153^, Simonsen et al.^154^

Two studies published in 1997 showed that cobalt powder causes DNA damage in cultured mammalian cells. In one study, non-cytotoxic doses of cobalt powder were added to cultured human lymphocytes and a dose-dependent increase in DNA single strand breaks was noted at concentrations of 4.5 μg/mL and above.^155^ Sodium formate, a hydroxyl radical scavenger, was shown to lower the levels of cobalt-induced DNA damage in this study. The second study examined induction of DNA strand breaks and micronuclei in human lymphocytes exposed in culture to pure cobalt powder (up to 12 μg/mL).^156^ The authors reported dose-related increases in DNA migration (using the comet assay) and dose-related increases in micronucleated lymphocytes (using the cytokinesis block method). Another study from the same laboratory, focused on measuring the genetic toxicity of cobalt combined with various metallic carbide particles, found induction of DNA strand breaks by cobalt alone to be so variable that results from the testing of the combination materials could not be clearly evaluated.^157^ However, induction of micronucleated lymphocytes by cobalt alone or in combination with tungsten carbide, chromium carbide, niobium carbide, and molybdenum carbide occurred in a dose-related fashion^157^; none of the four individual carbides induced micronuclei in the absence of cobalt.

Several lines of investigation suggest that cobalt interferes with DNA repair processes (for a review, see Hartwig et al.^158^). One way that proteins interact with DNA is through zinc-finger domains. Proteins in the base excision repair (BER) and nucleotide excision repair (NER) pathways, as well as transcription factors such as p53, contain zinc-finger domains. Biochemical studies have shown that cobalt can take the place of zinc in such domains; for example, cobalt will complex within the bacterial BER enzyme, formamidopyrimidine-DNA glycosylase,^159^ and a peptide containing the zinc-finger domain of XPA will accept cobalt.^160^ The substitution of cobalt for zinc appears to have negative consequences, as cobalt impaired the ability of XPA purified from mouse cells to bind DNA specifically through its zinc-finger domain.^161^ In the NER pathway, XPA plays a critical role in the initial detection of DNA that has been distorted by various chemical modifications that are known to induce mutations, such as oxidized bases and bulky adducts. In another approach, De Boeck et al.^162^ investigated the interference of cobalt with the repair of mutagen-induced DNA damage using the Comet assay. Cultured human lymphocytes were exposed to MMS alone, or to MMS followed by a non-genotoxic dose of 1.2 μg/mL cobalt metal. In the presence of cobalt, there was an increase in the persistence of MMS-induced DNA damage, suggesting that cobalt inhibited the repair of MMS-induced DNA lesions.

Taken together, results from these in vitro studies suggest that cobalt particles can affect the integrity of DNA by producing activated oxygen species and/or by inhibiting DNA repair pathways.

To assess the genotoxic effects of cobalt dust on workers from cobalt refineries, where the average dust concentration was 20 mg/m^3^, 35 workers were examined for lymphocyte DNA damage using the comet assay and for lymphocyte micronucleus frequencies. No significant effects were observed for either of these endpoints in exposed workers compared to matched controls.^163^

## Study Rationale

Cobalt metal dust was nominated for toxicology and carcinogenesis studies by the United Auto Workers and the Cobalt Development Institute based on the widespread occupational exposure and the occurrence of occupational disease, i.e., hard metal disease, associated with exposure to cobalt and its compounds, including cobalt metal-tungsten carbide. The carcinogenicity of a soluble cobalt compound, cobalt sulfate heptahydrate, in experimental animals exposed by inhalation was previously assessed by NTP.^122^ Limited data were available to assess the chronic toxicity and carcinogenic potential of inhaled insoluble cobalt compounds, particularly cobalt metal dust. Inhalation was selected as the route of exposure because this is the most common route of exposure to cobalt metal dust in occupational settings in humans.