# Appendix O Summary of Peer Review Panel Comments

On October 29, 2013, the draft Technical Report on the toxicology and carcinogenesis studies of cobalt metal received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M. Behl, NIEHS, introduced the studies on cobalt metal. The United Auto Workers and the Cobalt Development Institute nominated cobalt metal for toxicology and carcinogenesis studies, with support from OSHA and NIOSH. The nomination was based on widespread occupational exposure and occurrence of hard metal disease associated with exposure to cobalt and its compounds. Dr. Behl presented results of mutagenicity studies and described the nonneoplastic and neoplastic lesions observed in the studies.

The proposed conclusions for the 2-year inhalation studies were clear evidence of carcinogenic activity of cobalt metal in male and female F344/NTac rats and male and female B6C3F1/N mice.

NTP contract pathologist Dr. A.R. Pandiri of Experimental Pathology Laboratories, Inc., described the molecular analyses of Kras, Egfr, and Tp53 mutations in rat and mouse alveolar/bronchiolar carcinomas in these studies. He presented data demonstrating that mutations within Kras were higher than within Egfr and Tp53 genes in both rat and mouse alveolar/bronchiolar carcinomas resulting from chronic inhalation exposure to cobalt metal.

Dr. Cullen noted receipt and distribution to the panel of written comments from Dr. S. Verberckmoes of Umicore S.A. and Dr. R. Danzeisen of the Cobalt Development Institute. Dr. Cullen opened the floor for oral public comments.

Dr. Danzeisen commented on the draft Technical Report by telephone. Dr. Danzeisen noted that the Cobalt Development Institute nominated cobalt metal for NTP testing. She anticipated that NTP studies on cobalt metal would lead to an industry self-classification of cobalt metal by the inhalation route, pending the outcome of the Peer Review Panel’s deliberations. She felt that the study was well designed and conducted, but the particle size used was very small compared to that in typical human exposure scenarios. She said the high concentration used was relatively high as reflected in the early reductions in body weights. There was no no-observed-adverse-effect level, which made it more difficult to extrapolate the findings for risk assessment. Her group agreed with the NTP conclusion that there was clear evidence of carcinogenicity, but suggested limiting the conclusions to indicate that the evidence was by inhalation exposure and in the respiratory tract. The NTP findings were in line with her group’s thinking and evidence from past human epidemiologic studies that cobalt causes cancer in the lung by causing local inflammation leading to reparative mechanisms. She noted that the systemic cancers were seen only in rats and not in mice, and are not relevant for humans and human risk assessment. She remarked that the systemic cobalt levels were highest in the liver, at times even exceeding lung levels, but the liver had no neoplasms. The cobalt levels achieved in the tissues seemed disconnected with adverse effects, particularly neoplasms. She found this supported her group’s hypothesis that there is local inflammation leading to reparative mechanisms, hyperplasia, and subsequently cancer. She stressed that the Cobalt Development Institute has strong evidence that cobalt is not a mutagen and agrees with the NTP review that oxidative stress causes interaction with the DNA.

Dr. Gordon, the first primary reviewer, indicated that the NTP’s cobalt metal particle inhalation studies were very well designed and conducted and yielded important information regarding the carcinogenicity of a less soluble form of cobalt that complements the previous NTP studies with the soluble form. He said considerable data suggest that the soluble and insoluble forms can have differences in long-term toxicity or potency; therefore, he commended the testing of cobalt metal in the NTP bioassay program. He found the choices of exposure concentrations to be generally acceptable, but an additional low concentration would have been appropriate for both the rat and mouse 2-year studies. On the basis of some of the 3-month endpoints (e.g., larynx), there may have been sufficient data to justify using a lower exposure-concentration, which would enhance the relevance of the exposure concentrations. The multiple alveolar/bronchiolar carcinomas with exposure-concentration response in rats and mice, and the statistical significance of the tumors, provide additional evidence of the carcinogenicity of the particles in the lung. He indicated that if the concentration was lower, a clearer exposure concentration-related response might have been seen. He suggested particle size be addressed earlier in the report. He noted that a stainless steel jet mill was used to break up the cobalt metal into respirable particle sizes; the report should explain the resulting chromium contamination of the bulk chemical and note contamination was minimal. The potential for cobalt metal to be carcinogenic is strengthened by the similar lung tumors seen with the soluble form of cobalt. He inquired about a potential miscalculation in the normalization of the exposure concentration of cobalt sulfate heptahydrate to elemental cobalt. He noted that the cobalt metal particles might have been more potent than the soluble form, which would support the mode of action suggested by the public commenter. He agreed with the conclusion of clear evidence in the lung. He noted that the other conclusions, except for the cystic keratinizing epitheliomas, may not warrant the higher ratings and should perhaps be lowered.

Dr. Cory-Slechta, the second primary reviewer, noted that the studies were very well designed and conducted. Given that cobalt can be taken up by the nasal mucosa and into the brain, she said there should have been analysis of brain tissue.

Dr. Regan, the third primary reviewer, said the studies were well designed and had no interpretation differences at the clear evidence of carcinogenicity level. Regarding the equivocal evidence of carcinogenicity in the renal tubule adenomas and carcinomas, she asked about the lack of preneoplastic lesions in the kidneys. She asked what triggered the extended evaluation of the kidneys. She asked whether there was any evidence of the amphophilic-vacuolar carcinomas that have been found to be spontaneous; if so, then that should be taken into account. Regarding the pancreatic islet tumors, she said there was an increase in incidence compared to the historical control data, but the historical control data were not appropriate for this particular study because of the strain used. Thus, she proposed that the pancreatic islet tumors were ranked too high but agreed with the conclusions for all of the other tumor types.

Dr. Zacharewski, the fourth primary reviewer, asked whether the Kras, Egfr, and Tp53 mutations mapped to any specific consequences in terms of the activity of those proteins subsequent to the mutation. He also inquired whether any additional studies could have been done to demonstrate that the mutation actually had functional significance to the protein itself. He asked whether there was any correlation between a mutation and a tumor outcome in terms of aggressiveness, metastatic ability, etc.

Dr. Barlow asked why no mutations were found in the concurrent controls, despite a robust response in the historical animals. He also noted that there was a well-known and direct mechanism for the development of adrenal medullary tumors and asked for comment from the study pathologist.

Dr. Parker endorsed more large-scale sequencing efforts to allow for more accurate identification of genetic mutations and assessment of other types of mutations, such as indels, as opposed to just point mutations.

Dr. Cullen asked if cardiomyopathy was observed in the study. Dr. Behl replied that there was no evidence of cardiomyopathy in these studies. She said that cardiomyopathy was observed in a female rat in the 13-week cobalt sulfate heptahydrate study.

Responding to Dr. Gordon’s review, Dr. Behl agreed with his comments about nonneoplastic lesions in the larynx. She explained that when NTP has different exposure concentrations in two species in studies involving inhalation chambers, it has elected to go with one less concentration rather than adding an additional group. Hence, a lower concentration was not used. She noted that the particle size used was consistent with the rat respirable range (see pages 29, 30, and 275). Regarding the dosing calculation Dr. Gordon had questioned, she explained that the exposure concentration in the cobalt sulfate heptahydrate study was based on the mass percentage of cobalt in anhydrous cobalt sulfate. Dr. Gordon asked for better justification for the conclusion related to cystic keratinizing epitheliomas, suggesting perhaps that it should have been equivocal. Dr. Behl explained the basis for the some evidence call in the females. Because cystic keratinizing epitheliomas are rare and are part of a continuum of lung lesions, their occurrence was included as a chemical-related effect in the conclusions. Dr. R.A. Herbert, NIEHS, added that in the nonneoplastic lesions, there was some evidence of squamous cell hyperplasia within the lung and evidence of a progression from nonneoplastic lesions to benign lesions to carcinomas, leading to the some evidence conclusion.

Responding to Dr. Cory-Slechta’s comment, Dr. Behl said the brain tissue was examined, and there was no evidence of neoplasms. Dr. Cory-Slechta said neoplasms might not have been expected, although there were likely nonneoplastic lesions, such as white matter injury. Dr. Herbert said there was no evidence of nonneoplastic or neoplastic lesions. Dr. D.E. Malarkey, NIEHS, said NTP is very interested in improving evaluation of the brain, having recently invoked a new method for its analysis.

Dr. Herbert responded first to Dr. Regan’s question about what triggers an extended review in the kidney. He said the renal tubule adenomas are usually small tumors, and an extended review is triggered if there is an indication from the data that there could be an effect. Dr. Regan asked if there was a specific level used. Dr. Herbert said there was not. Dr. Barlow asked how often the extended review yields additional results that affect the conclusions. Dr. Herbert did not have data on that issue at the time. Dr. Regan asked whether any amphophilic-vacuolated renal tubule neoplasms were observed in the male rat study. Dr. Herbert said none were seen in this study and indicated that NTP has not traditionally made a distinction between the amphophilic-vacuolated type and other types of renal tubular neoplasms in studies. He noted that one publication indicates such tumors are spontaneous, but the toxicologic pathology community does not generally accept this distinction. Dr. Regan mentioned that there are other publications on the topic. She asked how NTP could know that such a tumor type did not occur, if NTP does not distinguish that tumor type. Dr. Herbert indicated he had looked at all of the tumors, and that no amphophilic-vacuolated renal tubular neoplasms occurred in the study. Dr. Behl responded to Dr. Regan’s comments about pancreatic islet tumors in the females and said the call equivocal evidence of carcinogenicity was primarily based on the increase in malignant neoplasms at the 5 mg/m^3^ dose, as well as supporting evidence from the males (e.g., significant trend and pairwise comparisons in the top two exposure concentrations).

Dr. Pandiri responded to Dr. Zacharewski’s comments. Dr. Pandiri said the selection of the hot spot exons in all three genes was based on extensive literature review of human lung cancer as well as rodent models of chemical-induced pulmonary carcinogenesis. Dr. Pandiri indicated that immunohistochemistry could be used to demonstrate the alterations in protein expression within the molecular pathways associated with the mutated genes.

Regarding Dr. Barlow’s question about why no Kras mutations were observed in the spontaneous alveolar/bronchiolar carcinomas from the concurrent chamber controls, Dr. Pandiri speculated that there were in fact mutations present, but perhaps not in the exons examined.

In response to Dr. Parker’s question about the primary focus being on point mutations, Dr. Pandiri said point mutations account for the majority of genetic changes seen in some of the well-known carcinogenesis studies in the literature. Dr. Pandiri agreed that massive parallel sequencing of the cancer genes in tumor tissue is a more powerful tool for detecting mutations and differentiating chemical-induced tumors from spontaneous tumors. He also informed the committee that NTP is currently running a pilot project using exome sequencing and RNA-seq technologies for evaluating chemically induced and spontaneous hepatocellular carcinomas from previous NTP chronic bioassays.

Dr. Malarkey responded to Dr. Gordon’s comments regarding the cystic keratinizing epitheliomas and indicated that they are very rare in most species, so it is a significant finding when present. Even though they are benign, this tumor type would be considered in the levels of evidence of carcinogenic activity, especially because it can progress to a malignant tumor. Dr. Malarkey also responded to Dr. Barlow’s question concerning how extended reviews of the kidneys are triggered and how often the extended reviews yielded additional results that affect the conclusions. He noted that when the response is weak, follow-up serial sections might confirm a finding.

Dr. Cory-Slechta moved to accept the conclusions as written, and Dr. Gordon seconded. The Peer Review Panel voted unanimously to accept the conclusions on cobalt metal as written in the draft report.