# Appendix N Sentinel Animal Program

## N.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected, allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and tested in-house during week 2 of the study or sent to BioReliance Corporation (Rockville, MD) (end of the 3-month studies and at 6, 12 and 18 months of the 2-year studies) or the Research Animal Diagnostic Laboratory (RADIL), University of Missouri (Columbia, MO) (end of 2-year studies) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex except at the following collection time points:

Two-week study (rats): Start of study collections–four males and five females

Two-year study (rats): 6, 12, 18 month collections–0 males and 10 females

Fecal samples were collected from five male and five female mice.

Table N-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Two-week Study
In-House Antibody Testing
Mycoplasma pulmonis | Study termination
PVM (Pneumonia virus of mice) | Study termination
RCV/SDA (Rat coronavirus/sialodacryoadenitis virus) | Study termination
RPV (Rat parvovirus) | Study termination
Sendai | Study termination
Three-month Study
In-House Antibody Testing
M. pulmonis | 2 weeks
PVM | 2 weeks
RCV/SDA | 2 weeks
RPV | 2 weeks
Sendai | 2 weeks
ELISA
PVM | Study termination
RCV/SDA | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
Two-year Study
In-House Antibody Testing
M. pulmonis | 2 weeks
PVM | 2 weeks
RCV/SDA | 2 weeks
RPV | 2 weeks
Sendai | 2 weeks
ELISA
Mycoplasma arthritidis | 18 months
M. pulmonis | 18 months
PVM | 6, 12, and 18 months
RCV/SDA | 6, 12, and 18 months
Sendai | 6, 12, and 18 months
Immunofluorescence Assay
KRV (Kilham’s rat virus) | Study termination
Multiplex Fluorescent Immunoassay
M. pulmonis | Study termination
Parvo NS-1 | Study termination
Parvovirus | 6, 12, and 18 months
PVM | Study termination
RCV/SDA | Study termination
RMV (Rat minute virus) | Study termination
RPV | Study termination
RTV (Rat theilovirus) | Study termination
Sendai | Study termination
TMEV GDVII (Theiler’s murine encephalomyelitis virus– mouse poliovirus, strain GDVII) | Study termination
H-1 (Toolan’s H-1) | Study termination
Mice
Two-week Study
In-House Antibody Testing
MHV (Mouse hepatitis virus) | Study termination
MPV (Mouse parvovirus) | Study termination
M. pulmonis | Study termination
PVM | Study termination
Sendai | Study termination
TMEV GDVII | Study termination
Three-month Study
In-House Antibody Testing
MHV | 2 weeks
MPV | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
TMEV GDVII | 2 weeks
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
MAd-FL (Mouse adenovirus) | Study termination
MHV | Study termination
MMV VP2 (Mouse minute virus viral protein 2) | Study termination
MPV VP2 (Mouse parvovirus viral protein 2) | Study termination
PVM | Study termination
Reovirus | Study termination
Sendai | Study termination
TMEV GDVII | Study termination
Immunofluorescence Assay
Ectromelia virus | Study termination
EDIM | Study termination
Two-year Study
In-House Antibody Testing
GDVII | 2 weeks
MHV | 2 weeks
MPV | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
ELISA
Ectromelia virus | 6, 12, and 18 months
EDIM | 6, 12, and 18 months
LCM | 6, 12, and 18 months
MAd-1 | 6, 12, and 18 months
MHV | 6, 12, and 18 months
MMV VP2 | 6, 12, and 18 months
MPV VP2 | 6, 12, and 18 months
PVM | 6, 12, and 18 months
Reovirus | 6, 12, and 18 months
Sendai | 6, 12, and 18 months
TMEV GDVII | 6, 12, and 18 months
Immunofluorescence Assay
EDIM | 6 months and study termination
LCM | 6 months
MHV | 18 months
PVM | 6 months
Reovirus | 6 and 18 months
TMEV GDVII | 6 months
Multiplex Fluorescent Immunoassay
Ectromelia virus | Study termination
EDIM | Study termination
LCM | Study termination
MHV | Study termination
MMV | Study termination
Mouse norovirus | Study termination
MPV | Study termination
M. pulmonis | Study termination
Parvo NS-1 | Study termination
PVM | Study termination
Reovirus | Study termination
Sendai | Study termination
TMEV GDVII | Study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## N.2 Results

All test results were negative.