# Appendix L Chemical Characterization and Generation of Chamber Concentrations

## L.1 Procurement and Characterization of Cobalt Metal

Cobalt metal was produced by OMG Kokkola Chemicals Oy (Kokkola, Finland) and was provided by the Cobalt Development Institute via PEL Technologies in one lot (P32 3040-1) that was used in the 2-week, 3-month, and 2-year studies. Identity and purity analyses were performed by the study laboratory at Battelle Toxicology Northwest [Richland, WA; inductively coupled plasma/atomic emission spectroscopy (ICP/AES) analysis] and by the analytical chemistry laboratories at Pacific Northwest National Laboratory [Richland, WA; X-ray diffraction (XRD) and proton-induced X-ray emission (PIXE) analyses], AMIA Laboratories (The Woodlands, TX; XRD using Rietveld analysis), H&M Analytical Services, Inc. (Allentown, NJ; XRD with and without Rietveld analysis), Elemental Analysis, Inc. (Lexington, KY; PIXE), and Galbraith Laboratories (Knoxville, TN; coulometry for total carbon). Reports on analyses performed in support of the cobalt metal studies are on file at the National Institute of Environmental Health Sciences.

Lot P32 3040-1 of the chemical, a silver-gray powder, was identified as cobalt metal by the analytical chemistry laboratories using XRD. XRD patterns were consistent with library reference patterns (Joint Center for Powder Diffraction Studies/International Centre for Diffraction Data) for cubic and hexagonal phases of cobalt; Rietveld analysis indicated two crystalline forms of cobalt metal, cubic at 13.9% and hexagonal at 85.9%, and cobalt oxide at 0.2%. A representative XRD pattern is presented in Figure L-1.

The purity of lot P32 3040-1 was determined by the analytical chemistry laboratories by determination of the carbon content using combustion/coulometric analysis by induction furnace (Leco Corporation, St. Joseph, MI) with a carbon dioxide coulometer (Coulometrics, Inc., Wheat Ridge, CO) and by PIXE analyses using system A to determine the presence of cobalt metal and trace element impurities with atomic numbers from 11 (sodium) to 53 (iodine) or 92 (uranium). The study laboratory quantitated the purity of the bulk chemical using ICP/AES by system B.

A) The PIXE systems included the use of purchased elemental standards, a 2.5 MeV H^+^ ion beam with an incident angle of 45° and an exit angle of 39°, a 160 µm thick graphite disk attenuator, a 0.05 µC charge, and a beam current of 0.2 nA.

B) For ICP/AES, samples were dissolved in trace metal grade concentrated HCl:HNO_3_ (1:1) and analyzed for cobalt (230.786 nm) and yttrium (internal standard) (224.306 nm). Analyses were performed on a Thermo Elemental IRIS Intrepid Inductively Coupled Plasma-Atomic Emission Spectrometer (Thermo Elemental, Franklin, MA), and the results were normalized against those of cobalt reference standards obtained from the National Institute of Standards and Technology (NIST).

For lot P32 3040-1, the carbon content was 0.09% ± 0.01%. PIXE analysis by system A indicated trace elements of aluminum, sulfur, calcium, chromium, and iron. Chromium was consistently current at approximately 84 ppm; the other impurities were below the minimum detection limits. ICP/AES analysis by system B indicated a purity of 98.2% ± 0.6% relative to a NIST standard reference material [(SRM); cobalt SRM 3113, Gaithersburg, MD]. The overall purity of cobalt metal was determined to be greater than 98%.

To ensure stability, the bulk chemical was stored at room temperature in safety-coated amber glass containers with Teflon^®^-lined caps under a nitrogen headspace. Periodic reanalyses of the bulk chemical were performed by the study laboratory using ICP/AES by system B; no degradation of the bulk chemical was detected.

## L.2 Aerosol Generation and Exposure System

Schematic diagrams of the cobalt metal generation and distribution systems used during the 2-week studies and the 3-month and 2-year studies are shown in Figure L-2 and Figure L-3, respectively. During the 2-week studies, an auger feed device (Tuf-Flex, Model 102 powder feeder; Schenk AccuRate, Inc., Whitewater, WI) was used to meter cobalt metal into a Trost jet mill (Garlock, Inc., Newtown, PA) for aerosolization and particle size reduction. For the 3-month and 2-year studies, the generation system used a linear feed device (Figure L-4) designed and built by Battelle to meter cobalt metal into the jet mill. The linear feed device consisted of a slide bar, a body, a delivery tube, and a test article reservoir. A motor-driven brush (not shown in Figure L-3 and Figure L-4), mounted above and extending into the reservoir, gently rotated and continually stirred the cobalt metal held within the reservoir; this action aided the metering port filling process.

The compressed air driven slide bar slid back and forth during generation. As the slide bar moved to the filling position, the metering port on the shuttle bar was aligned with the reservoir opening and was filled with a small metered amount of test article. A stainless steel screen at the bottom of the metering port held the material within the port. A slight vacuum was applied to the metering port to assist with filling. As the slide bar moved to the dispersing position, the metering port was aligned with a compressed air port in the body. A puff of air from the port dispersed the test article from the metering port. The output of the linear feeder was regulated by adjusting the shuttle bar cadence.

Initial particle size reduction was accomplished within the Trost jet mill. Opposing nitrogen and air gas streams drove the jet mill. All components of the generation system were housed within a glove box located within the exposure control center.

From the jet mill, aerosol was directed to the main distribution line where it was diluted with humidified air then conveyed from the exposure control center to the exposure room where it passed through a cyclone separator to further reduce particle size. On exiting the cyclone, the aerosol-laden air was directed to either of two smaller branch lines. The main distribution and branch lines were made of stainless steel, bonded and grounded to prevent the buildup of electrostatic charge. The distribution line pressure was continuously monitored and maintained slightly negative to the exposure room.

From the branch line, aerosol was delivered to each exposure chamber by a sampling tube. The flow through the sampling tube was induced by a stainless steel ejector pump designed and fabricated at Battelle. The flow rate and configuration of the ejector pumps were chosen to optimize the efficiency of the delivery system. The aerosol then entered the chamber inlet duct where it was further diluted with conditioned chamber air to achieve the desired exposure concentration.

During exposure periods, there was a small excess of aerosol in each branch line over that needed to maintain chamber concentrations. This additional aerosol was available for making adjustments to the chamber aerosol delivery flow rates and was controlled using house vacuum regulated by a filter-protected flow meter. A second flow control system was available during off-exposure periods. This system consisted of a vacuum transducer pump (Air-Vac Engineering Company, Inc., Seymour, CT) of higher flow capacity positioned in parallel with each branch line flow meter control assembly that became operational only during critical shut-down periods. This backup pump was intended to create sufficient vacuum in the branch line to overcome the negative pressure in the chambers and prevent the flow of aerosol-laden air from the branch line to the chambers as the air supply to each chamber ejector pump was shut off. A high-efficiency particulate air (HEPA) filter was placed before the endline flow control assembly of each branch to remove aerosol from the airstream prior to exhausting from the room.

The study laboratory designed the inhalation exposure chambers (Lab Products, Inc., Seaford, DE) so that uniform aerosol concentrations could be maintained throughout the chambers with the catch pans in place. The total volume of the chamber was 2.3 m^3^ with an active mixing volume of 1.7 m^3^. There were three levels of caging, each level split into two tiers that were offset from each other and from the chamber walls. Drawer-like stainless steel cage units composed of individual animal cages were suspended in the space above each tier. Stainless steel catch pans for the collection of urine and feces were suspended below each cage unit.

Incoming air that contained a uniform mixture of test chemical was diverted so that it flowed vertically along the inner surfaces of the chambers. Eddies were formed at each tier as the aerosol flowed past the catch pans. Stagnant zones that would normally exist above each pair of catch pans were cleared by exhaust flow through the space between the tiers. Aerosol reaching the lowest level was deflected across the bottom tiers by metal strips in the space between the catch pan and the wall. Tests showed that aerosol concentration could be reliably maintained homogenous within 8% throughout the chambers, provided the aerosol was uniformly mixed before passing through the chamber inlet and provided the test material did not react to a significant extent with animals, animal excrement, or the chamber interior.^164^

## L.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table L-1 through Table L-3. The concentration of cobalt metal in the exposure chambers and room air was monitored using three real-time aerosol monitors (RAMs) (Model RAM-1; MIE, Inc., Bedford, MA). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two exposure chambers. The output (voltage) of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and cobalt metal concentrations that were determined by analyzing tandem Pallflex TX40HI20WW (Pall Corporation, Ann Arbor, MI) Teflon^®^-coated, glass-fiber filters collected daily from the exposure chambers. Cobalt was extracted from the filters with 1:1 HCl:HNO_3_ and analyzed using ICP/AES by system B.

The ICP/AES instrument was calibrated against serially diluted NIST-traceable 10 mg/mL spectrometric standards of cobalt and the internal standard yttrium. Quality control standards and a reagent blank were analyzed after calibration, after approximately every tenth sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

## L.4 Chamber Atmosphere Characterization

Particle size distribution was determined once prior to the 3-month and 2-year studies, once during the 2-week studies, twice during the 3-month studies, and monthly during the 2-year studies. Impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor (In-Tox Products, Moriarty, NM) and the stages (glass coverslips lightly coated with silicone to prevent particle bounce) were analyzed using ICP/AES by system B after cobalt was extracted from the slides with 1:1 HCl:HNO_3_. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis.^165^ The resulting estimates of the mass median aerodynamic particle diameter and the geometric standard deviation of each set of samples are given in Table L-4 through Table L-7. All samples were within the 1 to 3 µm range required by the protocol.

Buildup and decay rates for chamber aerosol concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 9.4 minutes. For rats and mice in the 2-week studies, T_90_ values ranged from 9 to 11 minutes with animals present; T_10_ values ranged from 7 to 10 minutes. For rats and mice in the 3-month studies, T_90_ values ranged from 10 to 14 minutes without animals present and from 11 to 14 minutes with animals present; T_10_ values ranged from 8 to 10 minutes without animals and were 9 minutes with animals present. For rats in the 2-year studies, T_90_ values ranged from 10 to 13 minutes without animals present and from 9 to 10 minutes with animals present; T_10_ values ranged from 7 to 10 minutes without animals present and from 9 to 10 minutes with animals present. For mice, T_90_ values ranged from 10 to 13 minutes without animals present and from 11 to 13 minutes with animals present; T_10_ values ranged from 6 to 9 minutes without animals present and from 9 to 10 minutes with animals present. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week and 3-month studies and every 3 to 4 months during the 2-year studies. Aerosol concentrations were measured using the on-line monitor with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Concentrations were measured at 12 chamber sample ports; one in front and one in back for each of six possible cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of cobalt metal in the exposure chambers after aerosol delivery ended was determined by monitoring the concentration overnight in the 40 mg/m^3^ rat and mouse chambers in the 2-week studies, the 5 mg/m^3^ rat and 10 mg/m^3^ mouse chambers in the 3-month studies, and the 5 mg/m^3^ rat and mouse chambers in the 2-year studies, with and without (except for the 2-week studies) animals present in the chambers. The average cobalt metal concentration decreased to 1% of the target concentration within 15 (2-week studies), 17 to 18 (3-month studies), or 19 (2-year studies) minutes.

Stability studies of the test material in the generation and exposure system were performed before and during the studies by the study laboratory and the analytical chemistry laboratories. Before the start of each study, a cobalt powder sample was taken from the aerosol distribution line using a Gore-Tex lined polyester filter bag (Sturtevant, Inc., Hanover, MA). Before (except for the 2-week studies) and during each study, microporous filters were collected from the 2.5 and 40 mg/m^3^ (2-week studies), 0.625, 5, and 10 (mice only) mg/m^3^ (3-month studies), or 1.25 and 5 mg/m^3^ (2-year studies) exposure chambers and the aerosol distribution line. All microporous filters were obtained from Pall Corporation; samples for all XRD and ICP/AES analyses were collected on 25 mm A/E glass-fiber filters (1 µm pore size:330 µm thickness) and those for PIXE analyses were collected on 25 mm Zefluor™ polytetrafluoroethylene filters (1 µm pore size:165 µm thickness) for the 3-month studies or 25 mm GH Polypro filters for the 2-year studies. On each sample collection day, a sample of the bulk cobalt metal was collected before filling the reservoir, and a sample of the test article from the generator reservoir was collected at the end of the generation day; additional test material was added to the generator each day. In-system test article stability was assessed using multiple but similar XRD systems as well as PIXE by system A and ICP/AES by system B. The XRD systems included a Siemens D5000^Θ/Θ^ (Siemens, Munich, Germany) or Philips PW1800 or 3020 (Panalytical, Inc., Westborough, PA) diffractometer using Cu radiation at 40 to 50 KV/30 to 300 mA. Angular ranges varied from 15°, 20°, 30°, or 35° to 65°, 70°, 78°, 80°, or 90°; stepsizes were 0.01°, 0.02°, or 0.05°, and counting times were 1.2, 4.8, 10, 70, or 100 seconds.

For the 2-week studies, XRD analyses of the bulk chemical, filter samples, and material from the generator reservoir indicated two primary crystal forms of cobalt, cubic and hexagonal, with no detection of known cobalt oxides. XRD with Rietveld analysis of samples from the distribution line, bulk chemical, and generator reservoir indicated the presence of two crystal forms of cobalt, approximately 15% to 18% cubic and 78% to 79% hexagonal, and approximately 4% to 5% cubic cobalt oxide. Due to the unexpected presence of significant amounts of cobalt oxide in these samples, they were reanalyzed using XRD with standards containing cobalt metal as well as cobalt oxide (CoO) added at 0%, 1%, or 2% by weight. No cobalt oxide was detected in the distribution line or bulk chemical samples; cobalt oxide was detected in the generator reservoir sample, but it was less than 1% relative to the cobalt oxide standard. Bulk chemical, generator reservoir, and filter samples were analyzed using ICP/AES by system B to determine if inorganic impurities were introduced into the test atmosphere by the exposure generation system. Samples were analyzed for aluminum, arsenic, beryllium, cadmium, chromium, cobalt, copper, iron, manganese, molybdenum, nickel, lead, and tin. All measured trace element impurities were present at less than 0.05% by weight relative to cobalt.

Before the 3-month studies, XRD analyses indicated two crystal forms of cobalt (cubic and hexagonal) in all analyzed samples. Cobalt oxides were not detected and were less than 1% in the powder and filter samples relative to cobalt oxide standards. XRD coupled with Rietveld analysis of similar samples collected during the 3-month studies with animals in the exposure chambers detected cobalt oxide (Co_3_O_4_) at approximately 1.6% and 1.7%, respectively, with an uncertainty of approximately ± 2%. Comparison of the XRD patterns of these samples relative to those of cobalt oxide standards analyzed at the same time indicated less than 1% CoO and less than 1% Co_3_O_4_. No cobalt oxides were detected in the filter samples.

Before the 3-month studies, PIXE analysis for trace elements using system A indicated no inorganic impurities in the distribution line or exposure chamber filter samples or in the generator reservoir bulk samples. In similar PIXE analyses conducted during the 3-month studies with animals in the exposure chambers, no inorganic impurities were detected in the bulk chemical samples from the generator reservoir. Relative to cobalt concentrations in the same samples, chromium was detected in the aerosol distribution line and the 0.625 and 5 mg/m^3^ exposure chamber filter samples at levels of 0.13%, 0.21%, and 0.11%, respectively, and iron was detected in the 0.625 mg/m^3^ chamber filter sample at a level of 0.25%.

Before the 2-year studies, XRD with Rietveld analysis indicated the presence of two crystal forms of cobalt in all of the analyzed samples; cubic at 14% to 25% and hexagonal at 74% to 84%. Cobalt oxide (Co_3_O_4_) was detected at 1% to 2% in the bulk and generator samples and at 2% to 3% in the chamber and distribution line filter samples (with an uncertainty of approximately ± 2%). Comparison of the XRD patterns of these samples to those of cobalt oxide standards analyzed at the same time indicated less than 1% CoO and less than 1% Co_3_O_4_. Powder (bulk and generator reservoir) and filter (exposure chamber and distribution line) samples were collected for PIXE analyses for trace element impurities using system A; analyses detected chromium in three filter samples (distribution line, 5 mg/m^3^ rat chamber, and 1.25 mg/m^3^ mouse chamber) and chlorine in one filter sample (1.25 mg/m^3^ mouse chamber) at less than 0.1% relative to cobalt. An additional set of powder (bulk, generator reservoir, and distribution line) samples were collected and similarly analyzed by PIXE; chlorine was detected in all three of these powder samples and silicon was detected in the powder from the distribution line at less than 0.1% relative to cobalt.

At the beginning of the 2-year studies, XRD with Rietveld analysis indicated the presence of two crystal forms of cobalt in all of the analyzed samples, cubic at approximately 27% to 31% and hexagonal at 66% to 72%. Cobalt oxide (Co_3_O_4_) was detected at approximately 2% and 3% (with an uncertainty of approximately ± 3%) in the bulk and generator reservoir samples and chamber and distribution line filter samples, respectively. Comparison of the XRD patterns of these samples to those of cobalt oxide standards analyzed at the same time indicated less than 1% CoO and less than 1% Co_3_O_4_. PIXE analysis for trace element impurities by system A indicated the presence of silicon in the generator reservoir powder samples at 0.4% relative to cobalt. The bulk and generator reservoir samples were reanalyzed using ICP/AES by system B following microwave acid digestion in HNO_3_/HCl/HF. The following element impurities were detected at less than 0.1% relative to cobalt: silicon in the bulk and generator powder samples, chlorine in all powder and filter samples, vanadium in the 5 mg/m^3^ mouse chamber filter sample, and potassium and chromium in the 1.25 mg/m^3^ rat chamber filter sample.

XRD reanalyses of test chemical stability in the exposure system were performed at 1year and at the end of the 2-year studies. Two crystal forms of cobalt were present in all analyzed samples, cubic at 21% to 24% and hexagonal at 73% to 78%. Cobalt oxide (Co_3_O_4_) was detected in the bulk and generator samples at approximately 2% to 3% and in the chamber and distribution line filter samples at approximately 2% to 5% with an uncertainty of approximately ± 2%; comparison of the XRD patterns of these samples to those of cobalt oxide standards analyzed at the same time indicated less than 1% CoO and less than 1% Co_3_O_4_.

Table L-1 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Cobalt Metal

Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
2.5 | 134 | 2.5 ± 0.2
5 | 131 | 4.9 ± 0.4
10 | 134 | 9.7 ± 1.1
20 | 131 | 19.7 ± 2.0
40 | 57 | 40.1 ± 3.4
Mouse Chambers
2.5 | 145 | 2.5 ± 0.2
5 | 141 | 4.9 ± 0.4
10 | 145 | 9.7 ± 1.3
20 | 141 | 19.6 ± 2.0
40 | 145 | 40.1 ± 4.2

^a^ Mean ± standard deviation.

Table L-2 Summary of Chamber Concentrations in the Three-month Inhalation Studies of Cobalt Metal

Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
0.625 | 760 | 0.61 ± 0.04
1.25 | 750 | 1.23 ± 0.07
2.5 | 760 | 2.5 ± 0.1
5 | 749 | 5.0 ± 0.3
Mouse Chambers
0.625 | 782 | 0.61 ± 0.04
1.25 | 772 | 1.23 ± 0.07
2.5 | 782 | 2.5 ± 0.1
5 | 771 | 5.0 ± 0.3
10 | 782 | 10.0 ± 0.5

^a^ Mean ± standard deviation.

Table L-3 Summary of Chamber Concentrations in the Two-year Inhalation Studies of Cobalt Metal

Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
1.25 | 5,644 | 1.24 ± 0.07
2.5 | 5,647 | 2.50 ± 0.10
5 | 5,707 | 5.01 ± 0.18
Mouse Chambers
1.25 | 5,723 | 1.24 ± 0.06
2.5 | 5,719 | 2.49 ± 0.11
5 | 5,664 | 5.01 ± 0.20

^a^ Mean ± standard deviation.

Table L-4 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Chambers in the Two-week Inhalation Studies of Cobalt Metal

Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
2.5 | 1.86 | 1.76
5 | 1.79 | 1.73
10 | 1.92 | 1.74
20 | 1.94 | 1.77
40 | 1.92 | 1.79

Table L-5 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Chambers in the Three-month Inhalation Studies of Cobalt Metal

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
March 2005 | 0.625 | 1.69 | 1.94
| 1.25 | 1.73 | 1.84
| 2.5 | 1.84 | 1.76
| 5 | 1.86 | 1.76
| 10^a^ | 2.00 | 1.79
April 2005 | 0.625 | 1.61 | 1.97
| 1.25 | 1.71 | 1.83
| 2.5 | 1.76 | 1.75
| 5 | 1.77 | 1.74
| 10 | 1.98 | 1.80
May 2005 | 0.625 | 1.66 | 1.97
| 1.25 | 1.72 | 1.81
| 2.5 | 1.96 | 1.78
| 5 | 1.90 | 1.78
| 10 | 1.91 | 1.77

^a^ Mice only.

Table L-6 Summary of Aerosol Size Measurements for the Rat Exposure Chambers in the Two-year Inhalation Study of Cobalt Metal

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
May 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 2.0 | 1.7
June 2006 | 1.25 | 1.6 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
July 2006 | 1.25 | 1.6 | 1.9
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
August 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.9 | 1.7
| 5 | 1.8 | 1.7
September 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.9 | 1.7
October 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 2.0 | 1.7
| 5 | 1.8 | 1.7
November 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.6
| 5 | 1.9 | 1.7
December 2006 | 1.25 | 1.6 | 1.7
| 2.5 | 1.9 | 1.7
| 5 | 1.8 | 1.7
January 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.9 | 1.7
| 5 | 1.7 | 1.7
February 2007 | 1.25 | 1.5 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.6 | 1.7
March 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 2.0 | 1.8
| 5 | 1.8 | 1.8
April 2007 | 1.25 | 1.5 | 1.8
| 2.5 | 1.8 | 1.7
| 5 | 1.7 | 1.7
May 2007 | 1.25 | 1.6 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.7 | 1.7
June 2007 | 1.25 | 1.6 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
July 2007 | 1.25 | 1.5 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.7 | 1.7
August 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
September 2007 | 1.25 | 1.6 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
October 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.8
| 5 | 1.8 | 1.7
November 2007 | 1.25 | 1.6 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.6 | 1.8
December 2007 | 1.25 | 1.6 | 1.8
| 2.5 | 1.6 | 1.7
| 5 | 1.8 | 1.7
January 2008 | 1.25 | 1.5 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
February 2008 | 1.25 | 1.4 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
March 2008 | 1.25 | 1.5 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
April 2008 | 1.25 | 1.6 | 1.9
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.8
May 2008 | 1.25 | 1.6 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
Range | 1.25 | 1.4–1.7 | 1.7–1.9
| 2.5 | 1.6–2.0 | 1.6–1.8
| 5 | 1.6–2.0 | 1.7–1.8

Table L-7 Summary of Aerosol Size Measurements for the Mouse Exposure Chambers in the Two-year Inhalation Study of Cobalt Metal

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
May 2006 | 1.25 | 1.8 | 1.7
| 2.5 | 2.1 | 1.7
| 5 | 2.0 | 1.7
June 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
July 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 2.0 | 1.7
August 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.9 | 1.7
September 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.9 | 1.6
| 5 | 2.0 | 1.7
October 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 2.0 | 1.7
November 2006 | 1.25 | 1.6 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 2.0 | 1.6
December 2006 | 1.25 | 1.7 | 1.7
| 2.5 | 1.6 | 1.7
| 5 | 1.7 | 1.7
January 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.9 | 1.7
February 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.9 | 1.7
| 5 | 2.0 | 1.7
March 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 2.0 | 1.7
| 5 | 1.9 | 1.7
April 2007 | 1.25 | 1.5 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.7 | 1.7
May 2007 | 1.25 | 1.6 | 1.7
| 2.5 | 1.8 | 1.8
| 5 | 1.8 | 1.7
June 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.8 | 1.7
| 5 | 1.9 | 1.7
July 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.9 | 1.7
| 5 | 1.9 | 1.8
August 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
September 2007 | 1.25 | 1.6 | 1.8
| 2.5 | 1.7 | 1.8
| 5 | 1.7 | 1.7
October 2007 | 1.25 | 1.6 | 1.8
| 2.5 | 1.9 | 1.7
| 5 | 1.8 | 1.8
November 2007 | 1.25 | 1.7 | 1.7
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
December 2007 | 1.25 | 1.6 | 1.9
| 2.5 | 1.8 | 1.7
| 5 | 1.9 | 1.7
January 2008 | 1.25 | 1.6 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.7
February 2008 | 1.25 | 1.5 | 1.8
| 2.5 | 1.7 | 1.8
| 5 | 1.8 | 1.8
March 2008 | 1.25 | 1.7 | 1.8
| 2.5 | 1.8 | 1.8
| 5 | 1.9 | 1.7
April 2008 | 1.25 | 1.5 | 1.8
| 2.5 | 1.7 | 1.7
| 5 | 1.8 | 1.7
May 2008 | 1.25 | 1.7 | 1.9
| 2.5 | 1.7 | 1.7
| 5 | 1.7 | 1.8
Range | 1.25 | 1.5–1.8 | 1.7–1.9
| 2.5 | 1.6–2.1 | 1.6–1.8
| 5 | 1.7–2.0 | 1.6–1.8

Figure L-1

X-ray Diffraction Pattern of Cobalt Metal

Figure L-2

Schematic of the Aerosol Generation and Delivery System in the Two-week Inhalation Studies of Cobalt Metal

Figure L-3

Schematic of the Aerosol Generation and Delivery System in the Three-month and Two-year Inhalation Studies of Cobalt Metal

Figure L-4

Schematic of the Linear Feed Generator in the Fill Position Used in the Three-month and Two-year Inhalation Studies of Cobalt Metal