# Appendix K Analysis of Kras, Egfr, and Tp53 Mutations in F344/NTac Rat and B6C3F1/N Mouse Alveolar/Bronchiolar Carcinomas Resulting from Chronic Inhalation Exposure to Cobalt Metal

## K.1 Introduction

Spontaneous incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in control B6C3F1/N mice range from 8.4% (female) to 26.2% (male) (all routes, all vehicles, NTP historical control database, May 2011), and the incidences of these lung neoplasms after exposure to certain chemicals can be considerably higher in 2-year NTP studies. The incidences of spontaneous alveolar/bronchiolar adenoma or carcinoma (combined) in control F344/N rats are considerably lower [2.3% females, 3.6% males (all routes, all vehicles, NTP historical control database, May 2011)] than in the B6C3F1/N mouse. In the concurrent 2-year cobalt metal studies, there were significantly increased incidences of alveolar/bronchiolar neoplasms in both B6C3F1/N mice and F344/NTac rats exposed by inhalation compared to those in the chamber controls. The rodent lung neoplasms that arise either spontaneously or from chronic exposure to chemicals morphologically resemble non-small cell lung cancer in humans.^264^

The carcinogenic process involves the alteration of four broad categories of cancer-associated genes: proto-oncogenes, tumor suppressor genes, apoptosis genes, and repair genes.^265^ At least 80 genetic alterations in cancer genes, a dozen of which are considered “driver” mutations, are involved in the cancer process. Proto-oncogene and tumor suppressor gene mutation analysis has revealed mechanistic insights in chemical carcinogenesis. Mutations may be due to direct interaction of the chemical or its metabolite with DNA, or indirectly via altering DNA replicative or repair (epigenetic) processes. A change in the frequency and spectrum of cancer gene mutations reveals chemical-specific pathways that either override or include promotion of endogenous events. Interpretation of these data is complicated because mutation profiles are dependent on species, strain, gender, tumor differentiation, dose of carcinogen, as well as dosing regimen. Our main objective was to assess whether mutation frequencies and spectra in alveolar/bronchiolar carcinomas in treated rats and mice differed from published literature on spontaneous rodent and human lung cancers.

Lung cancer is a complex disease with variable clinical presentations and behavior. Genome sequencing of lung cancers in humans has identified several “driver” mutations that may play an important role in lung carcinogenesis. These cancer genes include KRAS, EGFR, TP53, EML4-ALK, HER2 (or ERBB2), BRAF, PIK3CA, PTEN, STK11, FGFR1, DDR2, AKT1, MAP2K1, and MET.^266^ These genes encode proteins that are critical for cellular proliferation and survival, as well as cellular transformation and tumorigenesis. We performed extensive mutation analyses on the most commonly altered cancer genes in human lung cancer (KRAS, EGFR, and TP53) in alveolar/bronchiolar carcinomas from F344/NTac rats and B6C3F1/N mice exposed to various concentrations of cobalt metal by inhalation for 2 years.

In human non-small cell lung cancer, the incidence of KRAS mutations is approximately 26% (67/254).^267^ Of these, 86% of the mutations arise within codon 12, and 14% occur in codon 13. Point mutations in codons 12, 13, and 61 of KRAS are activating mutations that result in constitutive activation of the KRAS protein, making it refractory to the inhibitory GTPase activating proteins, which results in stimulus-independent, persistent activation of downstream effectors, in particular the RAF-MEK-ERK cascade. Constitutive activation of this kinase cascade results in promotion of cellular proliferation and transformation.^268,269^

The incidence of EGFR mutations in the non-small cell lung cancer subtype of adenocarcinoma in humans is about 9% (22/254) with the majority (70%) of the mutations located within codons 19 and 21.^267^ EGFR is a transmembrane receptor, which upon ligand binding, dimerizes and activates the cytosolic kinase domain of the receptor tyrosine kinase resulting in activation of signaling pathways that support cancer development and progression. These signaling pathways include the PI3K pathway, which when activated leads to AKT activation and apoptosis inhibition, and the GRB2 and SOS pathways, which lead to activation of P21RAS, resulting in cell cycle progression.^270^

The incidence of TP53 mutations in human non-small cell lung cancer is approximately 50%; the frequency of this mutation is relatively increased in smokers.^271^ TP53 is regarded as a master regulator gene that is frequently altered in a wide range of cancers, and as a tumor suppressor, its critical roles in cell cycle control, apoptosis, and DNA repair are compromised when the gene is mutated. Tobacco-associated lung cancer has a high frequency of transversions (e.g., purine to pyrimidine or pyrimidine to purine) in TP53, whereas lung cancers in humans who have never smoked are associated with transitions (e.g., pyrimidine to pyrimidine or purine to purine), especially in women.^272,273^ In contrast to KRAS and EGFR mutations, which are predominantly noted only in the non-small cell lung cancer subtype of adenocarcinoma, mutations in TP53 are observed equally in both squamous cell carcinoma and adenocarcinoma subtypes of non-small cell lung cancer.^274^

## K.2 Materials and Methods

### K.2.1 Animals and Tissue Sampling

Alveolar/bronchiolar carcinoma tissue with adjacent nontumor tissue was obtained from F344/NTac rats and B6C3F1/N mice exposed to cobalt metal by inhalation for 2 years; spontaneous alveolar/bronchiolar carcinomas were obtained from chamber control mice at terminal kill. There were no spontaneous alveolar/bronchiolar carcinomas in the F344/NTac rats in the concurrent cobalt metal study. Hence, the spontaneous alveolar/bronchiolar carcinomas (n=10) were sourced from F344 rat vehicle control groups in various NTP chronic bioassays. These studies include sodium azide (VM55), elmiron (VM17), ginseng (VM46), tert-butyl alcohol (VM10) (all gavage, water vehicle); probenecid (VF23), isoeugenol (VM3, VM33) (all gavage, corn oil vehicle); trimethylolpropane triacrylate (VM63) (topical application in acetone vehicle); lauric acid diethanolamine condensate (VF163) (topical application in ethanol vehicle); and ethylbenzene (VM460) (inhalation of filtered air). These spontaneous alveolar/bronchiolar carcinoma samples were sourced from eight male and two female F344 rats. The mouse tumors that were selected for mutation analysis were generally greater than 5 mm in diameter, whereas the rat tumors were smaller and scattered throughout the pulmonary parenchyma. Normal lungs without tumors from age-matched chamber control rats and mice were also collected for histologic evaluation and molecular analysis. After formalin fixation, the tissues were transferred to 70% ethanol and were routinely processed in graded alcohols, embedded in paraffin, sectioned, and stained with hematoxylin and eosin (H&E) for microscopic analysis. The formalin fixed paraffin embedded (FFPE) tissues were used for mutation analysis. The alveolar/bronchiolar carcinomas were selected for molecular biology analysis based on their overall size and viability (minimal to no necrosis/hemorrhage microscopically) in order to maximize the amount and quality of DNA obtained from FFPE sections. DNA quality was measured using a Nanodrop spectrophotometer (Thermo Scientific, Wilmington DE) to calculate the 260/280 nm absorbance ratio, and DNA samples with a purity range of 1.7 to 2.0 were used for analysis. Samples falling outside of this range were reisolated from FFPE sections until a suitable purity measure was obtained or discarded.

### K.2.2 DNA Extraction, Polymerase Chain Reaction, Autosequencing, and Mutation Analysis

Alveolar/bronchiolar carcinoma samples (48 from F344/NTac rats and 69 from B6C3F1/N mice) representing all cobalt metal exposed groups and spontaneous alveolar/bronchiolar carcinomas (10 each from chamber control rats and mice) were evaluated for hot spot mutations within specific codons or exons in Kras, Egfr, and Tp53 genes that are relevant in human lung cancer. FFPE sections at 10 µm thickness were collected on glass slides. The neoplasms (single or multiple from the same lung) were dissected with a sharp microtome blade and collected into screw top tubes. In some cases (especially in rats) where the alveolar/bronchiolar carcinomas had a miliary distribution and were scattered throughout the pulmonary parenchyma, the entire lung section was used for DNA isolation. DNA was isolated from these FFPE dissected neoplasm tissue sections with the DNeasy^®^ Tissue Kit (Qiagen, Valencia, CA). Amplification reactions were carried out by semi-nested polymerase chain reaction (PCR) using primer sets designed for Kras (exons 1 and 2), Tp53 (exons 5 through 8), and Egfr (exons 18 through 21) (Table K-1 and Table K-2). Controls lacking DNA were run with all sets of reactions. PCR products were purified using a QIAquick^®^ Gel Extraction Kit (Qiagen). The purified products were cycled with Terminal Ready Reaction Mix-Big Dye^®^ (Perkin-Elmer, Foster City, CA), and the extension products were purified with the DyeEx^®^ 2.0 SpinKit (Qiagen). The lyophilized PCR products were sequenced with an automatic sequencer (Perkin-Elmer ABI Model 3100). The resulting electropherograms were compared to identify mutations in alveolar/bronchiolar carcinomas that either arise spontaneously or due to exposure to cobalt metal.^275^

### K.2.3 Statistics

To test for significance of exposure concentration-related trends in the incidences of mutations, a one-sided Cochran-Armitage test was conducted. A Fisher exact test was conducted to test for significant differences in the number of mutations between the control and various exposure groups.

## K.3 Results

### K.3.1 Rats

The incidence of Kras mutations in lung alveolar/bronchiolar carcinomas from F344/NTac rats exposed to cobalt metal by inhalation for 2 years was 31% (15/48) (Table K-3, supplemented by Table K-4 and Table K-5). The majority of Kras mutations in the rat were within codon 12 [29% (14/48)], followed by codon 13 [2% (1/48)]. Surprisingly there were no mutations within codon 61. The most common codon 12 mutations in rat alveolar/bronchiolar carcinomas from all groups exposed to cobalt metal were G→T transversions [57% (8/14)] and G→A transitions [43% (6/14)]. The frequencies of Kras mutations were 14% (2/14), 35% (6/17), and 41% (7/17) in alveolar/bronchiolar carcinomas from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. Kras mutations were not detected in spontaneous alveolar/bronchiolar carcinomas from chamber control rats in this study.

The incidence of Egfr mutations in alveolar/bronchiolar carcinomas from F344/NTac rats exposed to cobalt metal by inhalation for 2 years was 17% (8/48) (Table K-3, supplemented by Table K-4 and Table K-5). The majority of Egfr mutations in alveolar/bronchiolar carcinomas from rats exposed to cobalt metal for 2 years were present in exon 20 (codons 768, 770, 771, 785, 790, 791, and 806) [13% (6/48)], followed by exon 21 (codons 845 and 875) [4% (2/48)] and exon 19 (codon 750) [2% (1/48)]. The frequencies of Egfr mutations in alveolar/bronchiolar carcinomas from rats exposed to cobalt metal were 14% (2/14), 18% (3/17), and 18% (3/17) from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. A majority of Egfr mutations in rat alveolar/bronchiolar carcinomas were transitions such as G→A [50% (5/10)] or C→T [30% (3/10)]. Egfr mutations were not detected in spontaneous alveolar/bronchiolar carcinomas from chamber control rats in this study.

The incidence of Tp53 mutations in alveolar/bronchiolar carcinomas from F344/NTac rats exposed to cobalt metal for 2 years was 23% (11/48) (Table K-7, supplemented by Table K-8 and Table K-9). The majority of Tp53 mutations in alveolar/bronchiolar carcinomas from exposed rats were present within exon 6 (codons 203, 212, 242, and 247) [10% (5/48)], followed by exon 7 (codons 266, 277, and 278) [6% (3/48)] and exon 8 (codons 314 and 321) [6% (3/48)]. The frequencies of Tp53 mutations were 21% (3/14), 35% (6/17), and 12% (2/17) in the alveolar/bronchiolar carcinomas from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. The majority of Tp53 mutations in rats were transitions [85% (11/13)] such as C→T [38% (5/13)] or G→A [31% (4/13)]. Tp53 mutations were not observed in spontaneous alveolar/bronchiolar carcinomas from chamber control rats in this study.

### K.3.2 Mice

The incidence of Kras mutations in lung alveolar/bronchiolar carcinomas from B6C3F1/N mice exposed to cobalt metal for 2 years was 67% (46/69) (Table K-10; supplemented by Table K-11 and Table K-12). The majority of Kras mutations were localized within codon 12 [43% (30/69)], followed by codons 61 [20% (14/69)] and 13 [6% (4/69)]. The most common codon 12 mutations in alveolar/bronchiolar carcinomas from all groups exposed to cobalt metal were G→T transversions (G[underlined: G]T→G[underlined: T]T or [underlined: T]GT) [80% (24/30)] and G→A transitions (G[underlined: G]T→G[underlined: A]T) [17% (5/30)]. The frequencies of Kras mutations were 69% (11/16), 48% (11/23), and 80% (24/30) in alveolar/bronchiolar carcinomas from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. Kras mutations were not detected in spontaneous alveolar/bronchiolar carcinomas in this study. However, according to historical control data, Kras mutation incidence in spontaneous alveolar/bronchiolar carcinomas is 27% (34/124), and these mutations are localized within codon 12 [16% (20/124)], followed by codons 61 [6% (8/124)] and 13 [5% (6/124)].^275^ The most common mutation in codon 12 is a G→A transition (G[underlined: G]T→G[underlined: A]T) [70% (14/20)].

The incidence of Egfr mutations in alveolar/bronchiolar carcinomas from B6C3F1/N mice exposed to cobalt metal by inhalation was relatively low. The incidence of Egfr mutations in mouse alveolar/bronchiolar carcinomas due to exposure to cobalt metal for 2 years was 17% (12/69) (Table K-13, supplemented by Table K-11 and Table K-12). All regions of DNA that were queried for mutations (exons 18 through 21) encode the tyrosine kinase domain. The majority of Egfr mutations within alveolar/bronchiolar carcinomas from groups exposed to cobalt metal were present within exon 20 (codons 780, 791, 801, 812, and 817) [9% (6/69)], followed by exons 21 (codons 846, 861, 870, and 873) [6% (4/69)], 18 (codon 721) and 19 (codon 735) [each 1% (1/69)]. The frequencies of Egfr mutations in mouse alveolar/bronchiolar carcinomas exposed to cobalt metal were 13% (2/16), 30% (7/23), and 10% (3/30) from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. A majority of Egfr mutations in mouse alveolar/bronchiolar carcinomas were transition mutations such as G→A [42% (5/12)] or C→T [17% (2/12)]. Egfr mutations were not detected in spontaneous alveolar/bronchiolar carcinomas from chamber control mice in this study.

The incidence of Tp53 mutations in alveolar/bronchiolar carcinomas from B6C3F1/N mice exposed to cobalt metal for 2 years was 19% (13/69) (Table K-14, supplemented by Table K-15 and Table K-16). The majority of Tp53 mutations in alveolar/bronchiolar carcinomas from mice exposed to cobalt metal was found within exon 5 (codons 155, 156, 158, and 179) [10% (7/69)], followed by exons 6 (codons 194 and 212) [4% (3/69)] and 7 (codons 230, 232, 239, and 257) [6% (4/69)]. The majority of mutations were transversions [60% (9/15)], most of which were G→C. The frequencies of Tp53 mutations were 19% (3/16), 13% (3/23), and 20% (6/30) in alveolar/bronchiolar carcinomas from the 1.25, 2.5, and 5 mg/m^3^ groups, respectively. Tp53 mutations were not detected in spontaneous alveolar/bronchiolar carcinomas from chamber control mice in this study.

According to the historical control database (all routes, all vehicles, NTP historical control database, May 2011), male B6C3F1 mice have a higher incidence (12.5%) of spontaneous alveolar/bronchiolar carcinomas than B6C3F1 female mice (3.7%). However, there were no significant differences in the number or type of mutations evaluated in Kras, Egfr, or Tp53 genes between male and female B6C3F1/N mice chronically exposed to cobalt metal by inhalation.

## K.4 Discussion

Kras mutations were more frequent than Egfr and Tp53 mutations within the lung alveolar/bronchiolar carcinomas from F344/NTac rats and B6C3F1/N mice exposed to cobalt metal for 2 years in the concurrent studies. It is interesting to note that in mice, Kras mutations were observed in both spontaneous alveolar/bronchiolar carcinomas [27% (34/124); Hong et al.^275^] as well as in alveolar/bronchiolar carcinomas from mice exposed to cobalt metal [67% (46/69)]. However, alveolar/bronchiolar carcinomas from mice exposed to cobalt metal had predominantly G→T transversions [80% (24/30)], whereas the spontaneous alveolar/bronchiolar carcinomas had G→A transitions [70% (14/20)] in codon 12. Not surprisingly, G→T transversions were also the most predominant [67% (6/9)] mutations in alveolar/bronchiolar carcinomas from mice exposed to cobalt sulfate heptahydrate aerosols for 2 years (Table K-17; NTP^122^). Incidentally, G→T transversions are one of the most common Kras mutations in human lung cancer.^260^ G→T Kras mutations appear to correlate with 8-hydroxydeoxyguanine adducts that result from oxidative stress. G→T transversions in codon 12 of Kras were also noted previously in several lung neoplasms in mice exposed to various other chemicals such as tobacco-specific nitrosamines, aflatoxin B1, vanadium pentoxide, ozone, cumene, ethylene oxide, and transplacental AZT exposure.^276-279^ In the current study, it is not surprising that these mutations were seen almost exclusively in alveolar/bronchiolar carcinomas from mice exposed to cobalt metal and not in spontaneous alveolar/bronchiolar carcinomas. It has been demonstrated that cobalt can induce hypoxia and upregulate HIF-1α signaling, thereby modulating inflammatory responses and inducing oxidative stress.^154^ Thus, the G→T transversions that were observed in mice, primarily within codon 12 of Kras, may be attributable to oxidative stress resulting from chronic cobalt metal exposure.

EGFR, together with KRAS, plays an important role in initiating and maintaining the MAPK signaling cascade and other signaling pathways that are relevant to cancer. Kras mutations in non-small cell lung cancer are observed more frequently in smokers, while Egfr mutations in lung cancers are most frequently observed in women and people who have never smoked.^267^ The incidence of Egfr mutations in alveolar/bronchiolar carcinomas from rats and mice exposed to cobalt metal was lower than the incidence of Kras mutations. In contrast to the Kras mutations which are predominantly transversions, Egfr mutations in both rat and mouse alveolar/bronchiolar carcinomas were G→A or C→T transitions. This is the first study in which Egfr mutations were examined in the context of chemically induced rodent lung neoplasms. Mutations within Egfr and Kras are mutually exclusive in human lung and colon cancers, and the treatment modalities depend on Egfr and Kras mutation status of the respective neoplasm. Surprisingly, in alveolar/bronchiolar carcinomas from rodents exposed to cobalt metal, 38% (3/8) of rats and 25% (3/12) of mice that harbored Egfr mutations also had Kras mutations.

Mutations in Tp53 in chemically induced rodent models are considered a late event, especially in neoplasms that are initiated by mutations in Kras.^256^ The incidences of Tp53 mutations resulting from exposure to cobalt metal for 2 years were similar in rats and mice, but the nature of the mutations was different; Tp53 mutations in rats were predominantly transitions, whereas in mice, they were predominantly transversions. Interestingly, in humans, Tp53 transversions are commonly observed in non-small cell lung cancer from smokers, while Tp53 transitions are often noted in non-small cell lung cancer from people who have never smoked. The significance of this differential mutation spectrum in rats and mice and its relationship to human lung cancer needs to be further explored.

In summary, there was a significantly higher incidence of Kras mutations, accompanied by a lower incidence of Egfr and Tp53 mutations, in alveolar/bronchiolar carcinomas from rats and mice exposed to cobalt metal for 2 years. Several of the observed mutations in Kras are comparable to mutations observed in other NTP studies in which a significant increase in the incidence of lung neoplasms in response to chronic chemical exposure was evident. In addition, these mutations arise within the hotspot regions of Kras, Egfr, and Tp53 genes, and are thus comparable to the mutations observed in human non-small cell lung cancer.

Table K-1 Primers Used to Amplify the Hot Spot Regions of Rat Kras, Tp53, and Egfr Genes

Exon | Codon | Primer | Strand | Sequence
1 | Kras-12-13 | RK12F25927 | Sense | 5´-ACTTGTGGTAGTTGGAGC-3´
| | RK12R26069 | Antisense | 5´-CTGCCACCCTTTACAAATTG-3´
| | RK12R26034 | Antisense | 5´-GCAGCATTTACCTCTATCGT-3´
2 | Kras-61 | RK61F14325 | Sense | 5´-ATCCAGACTGTGTTTCTACC-3´
| | RK61R13986 | Antisense | 5´-CAGGAATTCTACATACTTGACAC-3´
| | RK61R14035 | Antisense | 5´-TGCAGGCCTAACAACTAGC-3´
5 | Tp53-124-184 | Rp53Ex5OF1366 | Sense | 5´-CCTAGTTGGCTTGTCCG-3´
| | Rp53Ex5OR1671 | Antisense | 5´-AGCAAGAATAAGTCAGAGGC-3´
| | Rp53Ex5IF1382 | Sense | 5´-CGCTGACCTTTGATTCTTTCTCC-3´
| | Rp53Ex5IR1639 | Antisense | 5´-GACAACCAGTTCTAAACCCCACAG-3´
6 | Tp53-185-259 | Rp53Ex6OF1620 | Sense | 5´-TGGGGTTAGAACTGGTTG-3´
| | Rp53Ex6OR1963 | Antisense | 5´-GAACAAAAACAGGCCGAG-3´
| | Rp53Ex6IF1645 | Sense | 5´-TCTCCCGGCCTCTGACTTATTC-3´
| | Rp53Ex6IR1927 | Antisense | 5´-CAGCCCAACCTGGCACAC-3´
7 | Tp53-260-304 | Rp53Ex7OF2101 | Sense | 5´-AGCTCCAGATAGGACAAG-3´
| | Rp53Ex7OR2434 | Antisense | 5´-TGGGCAGTGCTATGGAAG-3´
| | Rp53Ex7IF2166 | Sense | 5´-AGCTTTCTTACTGCCTTGTG-3´
| | Rp53Ex7IR2402 | Antisense | 5´-TGACTTTGGGGTGAAGCTG-3´
8 | Tp53-305-329 | Rp53Ex8OF2333 | Sense | 5´-GGAGTGCAAAGAGAGGTG-3´
| | Rp53Ex8OR2602 | Antisense | 5´-TGCGCTCTGACGATAATG-3´
| | Rp53Ex8IF2386 | Sense | 5´-GCTTCACCCCAAAGTCAC-3´
| | Rp53Ex8IR2549 | Antisense | 5´-GCGTTTTGTGTCCTAGACTTAG-3´
18 | Egfr-689-729 | REgfr18F144544 | Sense | 5´-ACACATTGCTCCTTTGATCAC-3´
| | REgfr18R144922 | Antisense | 5´-AACACGAGTTCCTACATAAACC-3´
| | REgfr18R145009 | Antisense | 5´-CACTCCCAAGTTTATGCCTC-3´
19 | Egfr-730-762 | REgfr19F146377 | Sense | 5´-ACAAGGCAACATGCTGCTG-3´
| | REgfr19R146775 | Antisense | 5´-TGACTTTACTCTTCCCTCCCC-3´
| | REgfr19R146605 | Antisense | 5´-ACACAAACTAAGGAAGCAAGAC-3´
20 | Egfr-763-824 | REgfr20F150643 | Sense | 5´-ACATGTGTTGTCCTTACC-3´
| | REgfr20R150924 | Antisense | 5´-ATTCATCCTGCTTCTGAAACC-3´
| | REgfr20R150905 | Antisense | 5´-CCTGCTATTGGCTCTTTG-3´
21 | Egfr-825-876 | REgfr21F162620 | Sense | 5´-TCACTCCCTCACTGAAGC-3´
| | REgfr21R162881 | Antisense | 5´-CTACAGCTGACACATAGG-3´
| | REgfr21R162852 | Antisense | 5´-GGGCTGTCAGGAAAATGC-3´

Table K-2 Primers Used to Amplify the Hot Spot Regions of Mouse Kras, TP53, and Egfr Genes

Exon | Codon | Primer | Strand | Sequence
1 | Kras-12-13 | K12AOS | Sense | 5´-TTATTGTAAGGCCTGCTGAA-3´
| | K12AOA | Antisense | 5´-GCAGCGTTACCTCTATCGTA-3´
| | K12AIS | Sense | 5´-ATGACTGAGTATAAACTTGT-3´
| | K12AIA | Antisense | 5´-TCGTACTCATCCACAAAGTG-3´
2 | Kras-61 | K61OS | Sense | 5´-TTCTCAGGACTCCTACAGGA-3´
| | K61OA | Antisense | 5´-ACCCACCTATAATGGTGAAT-3´
| | APK61IS | Sense | 5´-TACAGGAAACAAGTAGTAATTGATGGAGAA-3´
| | APK61IA | Antisense | 5´-ATAATGGTGAATATCTTCAAATGATTTAGT-3´
5-6 | Tp53-123-221 | Mp53F1407 | Sense | 5´-TCCCCACCTTGACACCTG-3´
| | Mp53R1885 | Antisense | 5´-GTCTCTAAGACGCACAAACC-3´
| | Mp53F1453 | Sense | 5´-GTTCTCTCTCCTCTCTTCCAG-3´
7 | Tp53-222-258 | Mp7FO | Sense | 5´-GGTCACCTGTAGTGAGGTAG-3´
| | Mp7RO | Antisense | 5´-GGAACAGAAACAGGCAGAAG-3´
| | Mp7FI | Sense | 5´-TGTAGTGAGGTAGGGAGCGAC-3´
| | Mp7RI | Antisense | 5´-AAGCTGGGGAAGAAACAGGC-3´
8 | Tp53-259-303 | Mp8FO | Sense | 5´-GTTTACACACAGTCAGGATGG-3´
| | Mp8RO | Antisense | 5´-TGTGGAAGGAGAGAGCAAG-3´
| | Mp8FI | Sense | 5´-AGCTTTCTTACTGCCTTGTGC-3´
| | Mp8RI | Antisense | 5´-TGAAGCTCAACAGGCTCCTC-3´
18 | Egfr-688-728 | Egfr18F138824 | Sense | 5´-CCACTGCTCCTTTGAACAC-3´
| | Egfr18F138836 | Sense | 5´-TGAACACATTGCTCCTTTGAAC-3´
| | Egfr18R139212 | Antisense | 5´-TGGAGAGCACAGCAAACAC-3´
19 | Egfr-729-761 | Egfr19F140636 | Sense | 5´-GAGCTTGATAGCTAAGAACCTC-3´
| | Egfr19F140659 | Sense | 5´-GAAATATGAAGAGTCCCAGCAC-3´
| | Egfr19R141071 | Antisense | 5´-CCAGAATACTTCCAAACAGTCC-3´
20 | Egfr-762-823 | Egfr20F144483 | Sense | 5´-TCC TTTTAACATGCAACATCCC-3´
| | Egfr20F144598 | Sense | 5´-GGGGGGGCATTTCATTTTAC-3´
| | Egfr20R145114 | Antisense | 5´-CAGACACACACACCTATCATC-3´
21 | Egfr-824-875 | Egfr21F151895 | Sense | 5´-TGTCTTGTCATTCATGCCAG-3´
| | Egfr21F151978 | Sense | 5´-TGTTGAGCAGCCTAGAGATTC-3´
| | Egfr21R152444 | Antisense | 5´-TCCTCCTTACTACTCCCACC-3´

Table K-3 Kras Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal

Cobalt Metal Concentration | Mutation Frequency | Codon 12 (GGT) | | | | Codon 13 (GGC) | Codon 61 (CAA)
Cobalt Metal Concentration | Mutation Frequency | (GAT) | (TGT) | (GTT) | (TTT) | (CGC)
0 mg/m3# | 0/10 (0%)** | 0 | 0 | 0 | 0 | 0 | 0
1.25 mg/m3 | 2/14 (14%) | 1 | 0 | 1 | 0 | 0 | 0
2.5 mg/m3 | 6/17 (35%)* | 4 | 1 | 0 | 0 | 1 | 0
5 mg/m3 | 7/17 (41%)* | 1 | 2 | 3 | 1 | 0 | 0
All exposed groups combined | 15/48 (31%)* | 6 | 3 | 4 | 1 | 1 | 0

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** Significant trend (P ≤ 0.001) by the Cochran-Armitage trend test.

^#^ There were no spontaneous alveolar/bronchiolar carcinomas in the cobalt metal study. Hence, the spontaneous alveolar/bronchiolar carcinomas (n = 10) were sourced from vehicle or chamber control groups in various NTP chronic bioassays. These spontaneous alveolar/bronchiolar samples were sourced from eight male and two female F344/N rats.

Table K-4 Kras and Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Male F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Conc. (mg/m^3^) | Kras | | | Egfr
Sample/Animal # | Cobalt Conc. (mg/m^3^) | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/M55 | 0 | none | none | none | none | none | none | none
2/M46 | 0 | none | none | none | none | none | none | none
3/M17 | 0 | none | none | none | none | none | none | none
4/M10 | 0 | none | none | none | none | none | none | none
5/M03 | 0 | none | none | none | none | none | none | none
6/M33 | 0 | none | none | none | none | none | none | none
7/M63 | 0 | none | none | none | none | none | none | Codon 837 CGT→CGC (Arg→Arg)
8/M46 | 0 | none | none | none | none | none | none | Codon 863 CTT→CTA (Leu→Leu)
9/M215 | 1.25 | none | none | none | none | none | none | none
10/M230 | 1.25 | none | none | none | none | none | none | Codon 875 GGC→GGT (Gly→Gly)
11/M249 | 1.25 | none | none | none | none | none | none | none
12/M202 | 1.25 | none | none | none | none | none | none | none
13/M226 | 1.25 | none | none | none | none | none | none | none
14/M233 | 1.25 | none | none | none | none | none | none | none
15/M241 | 1.25 | none | none | none | none | none | none | none
16/M247 | 1.25 | none | none | none | none | none | none | none
17/M248 | 1.25 | none | none | none | none | none | none | Codon 845 CTG→CAG (Leu→Gln)
18/M406 | 2.5 | none | none | none | none | none | none | none
19/M408 | 2.5 | none | GGC→CGC (Gly→Arg) | none | none | none | Codon 791 ACA→ATA (Thr→Ile) Codon 806 CAT→TAT (His→Tyr) | none
20/M413 | 2.5 | none | none | none | none | none | none | none
21/M425 | 2.5 | none | none | none | none | none | none | none
22/M438 | 2.5 | none | none | none | none | none | none | none
23/M448 | 2.5 | GGT→TGT (Gly→Cys) | none | none | none | none | none | none
24/M417 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
25/M418 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
26/M411 | 5 | GGT→TGT (Gly→Cys) | none | none | none | none | none | none
27/M641 | 5 | none | none | none | none | none | none | none
28/M649 | 5 | none | none | none | none | none | none | none
29/M605 | 5 | none | none | none | none | none | none | none
30/M608 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
31/M611 | 5 | none | none | none | none | none | none | none
32/M615 | 5 | none | none | none | none | none | none | Codon 875 GGC→AGC (Gly→Ser)
33/M616 | 5 | none | none | none | none | none | none | none
34/M618 | 5 | none | none | none | none | none | none | none

Table K-5 Kras and Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Female F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal

Sample/ Animal # | Cobalt Conc. (mg/m^3^) | Kras | | | Egfr
Sample/ Animal # | Cobalt Conc. (mg/m^3^) | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/F224 | 0 | none | none | none | none | none | none | none
2/F163 | 0 | none | none | none | none | none | none | none
3/F314 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
4/F337 | 1.25 | none | none | none | none | none | none | none
5/F338 | 1.25 | none | none | none | none | none | none | none
6/F342 | 1.25 | none | none | none | none | none | Codon 790 ATT→ACT (Ile→Thr) | none
7/F348 | 1.25 | GGT→GAT (Gly→Asp) | none | none | none | none | none | Codon 844 GTA→GTG (Val→Val)
8/F504 | 2.5 | none | none | none | none | none | none | none
9/F505 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | Codon 838 GAC→GAT (Asp→Asp)
10/F513 | 2.5 | none | none | none | none | none | Codon 770 GTG→ATG (Val→Met) | none
11/F514 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
12/F519 | 2.5 | none | none | none | none | none | none | none
13/F520 | 2.5 | none | none | none | none | Codon 750 GAA→AAA (Glu→Lys) | Codon 771 GAC→AAC (Asp→Asn) | none
14/F539 | 2.5 | none | none | none | none | none | none | none
15/F543 | 2.5 | none | none | none | none | none | none | none
16/F548 | 2.5 | none | none | none | none | none | none | none
17/F707 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
18/F723 | 5 | GGT→GAT (Gly→Asp) | none | none | none | none | Codon 768 GCC→ACC (Ala→Thr) | none
19/F728 | 5 | none | none | none | none | none | none | none
20/F746 | 5 | none | none | none | none | none | none | none
22/F703 | 5 | GGT→TGT (Gly→Cys) | none | none | none | none | none | none
21/F701 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | Codon 785 TCC→TTC (Ser→Phe) | none
23/F711 | 5 | none | none | none | none | none | none | none
24/F717 | 5 | GGT→TTT (Gly→Phe) | none | none | none | none | none | none

Table K-6 Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal^a^

Cobalt Metal Concentration | Mutation Frequency | Exon 18 | Exon 19 | Exon 20 | Exon 21
0 mg/m^3#^ | 0/10 (0%) | 0 | 0 | 0 | 0
1.25 mg/m^3^ | 2/14 (14%) | 0 | 0 | 1 | 1
2.5 mg/m^3^ | 3/17 (18%) | 0 | 1^b^ | 3^b^ | 0
5 mg/m^3^ | 3/17 (18%) | 0 | 0 | 2 | 1
All exposed groups combined | 8/48 (17%) | 0 | 1^b^ | 6^b^ | 2

^#^ There were no spontaneous alveolar/bronchiolar carcinomas in the cobalt metal study. Hence, the spontaneous alveolar/bronchiolar carcinomas (n = 10) were sourced from vehicle or chamber control groups in various NTP chronic bioassays. These spontaneous alveolar/bronchiolar samples were sourced from eight male and two female F344/N rats.

^a^ Silent mutations are not included.

^b^ Same animal with multiple mutations.

Table K-7 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal^a^

Cobalt Metal Concentration | Mutation Frequency | Exon 5 | Exon 6 | Exon 7 | Exon 8
0 mg/m^3#^ | 0/10 (0%) | 0 | 0 | 0 | 0
1.25 mg/m^3^ | 3/14 (21%) | 1 | 1^b^ | 1^b^ | 1
2.5 mg/m^3^ | 6/17 (35%)* | 0 | 4^b^ | 1^b^ | 2
5 mg/m^3^ | 2/17 (12%) | 1 | 0 | 1 | 0
All exposed groups combined | 11/48 (23%) | 2 | 5^b^ | 3^b^ | 3

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

^#^ There were no spontaneous alveolar/bronchiolar carcinomas in the cobalt metal study. Hence, the spontaneous alveolar/bronchiolar carcinomas (n = 10) were sourced from vehicle or chamber control groups in various NTP chronic bioassays. These spontaneous alveolar/bronchiolar samples were sourced from eight male and two female F344/N rats.

^a^ Silent mutations are not included.

^b^ Same animal with double mutations.

Table K-8 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Male F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Metal Concentration (mg/m^3^) | Exon 5 | Exon 6 | Exon 7 | Exon 8
1/M55 | 0 | none | none | none | none
2/M46 | 0 | none | none | none | none
3/M17 | 0 | none | none | none | none
4/M10 | 0 | none | none | none | none
5/M03 | 0 | none | Codon 205 GAC→GAT (Asp→Asp) | none | none
6/M33 | 0 | none | none | none | none
7/M63 | 0 | none | none | none | none
8/M46 | 0 | none | none | none | none
9/M215 | 1.25 | Codon 134 CAG→TAG (Gln→Stop) | none | none | none
10/M230 | 1.25 | Codon 160 ATC→ATT (Ile→Ile) | none | none | none
11/M249 | 1.25 | none | none | none | none
12/M202 | 1.25 | none | none | none | none
13/M226 | 1.25 | none | none | none | none
14/M233 | 1.25 | none | none | none | none
15/M241 | 1.25 | none | none | none | none
16/M247 | 1.25 | none | none | none | none
17/M248 | 1.25 | none | none | none | none
18/M406 | 2.5 | none | Codon 247 CGG→CAG (Arg→Gln) | none | none
19/M408 | 2.5 | none | none | none | Codon 321 CTC→TTC (Leu→Phe)
20/M413 | 2.5 | none | Codon 206 (GAC→GAT (Asp→Asp) Codon 242 GGG→GAG (Gly→Gln) | none | none
21/M425 | 2.5 | none | none | none | none
22/M438 | 2.5 | none | none | none | none
23/M448 | 2.5 | none | none | none | none
24/M417 | 2.5 | none | none | none | none
25/M418 | 2.5 | none | none | none | none
26/M411 | 5 | none | none | none | none
27/M641 | 5 | none | none | none | none
28/M649 | 5 | none | Codon 258 TCC→TCT (Ser→Ser) | none | none
29/M605 | 5 | none | Codon 242 GGG→GGA (Gly→Gly) | Codon 277 GGG→GAG (Gly→Glu) | none
30/M608 | 5 | none | none | none | none
31/M611 | 5 | none | none | none | none
32/M615 | 5 | none | none | none | none
33/M616 | 5 | none | none | none | none
34/M618 | 5 | Codon 135 CTG→CGG (Leu→Arg) | none | none | none

Table K-9 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Female F344/NTac Rats in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Metal Concentration (mg/m^3^) | Exon 5 | Exon 6 | Exon 7 | Exon 8
1/F224 | 0 | none | none | none | none
2/F163 | 0 | none | none | none | none
3/F314 | 1.25 | none | Codon 203 TAT→CAT (Tyr→His) | Codon 278 AGA→GGA (Arg→Gly) | none
4/F337 | 1.25 | none | none | none | none
5/F338 | 1.25 | none | none | none | none
6/F342 | 1.25 | none | none | none | Codon 314 CCC→CTC (Pro→Leu)
7/F348 | 1.25 | none | none | none | none
8/F504 | 2.5 | none | Codon 242 GGG→AGG (Gly→Arg) | Codon 266 GAC→TAC (Asp→Tyr) | none
9/F505 | 2.5 | none | none | none | none
10/F513 | 2.5 | none | none | none | Codon 314 CCC→CTC (Pro→Leu)
11/F514 | 2.5 | none | Codon 212 CAC→TAC (His→Tyr) | none | none
12/F519 | 2.5 | none | none | none | none
13/F520 | 2.5 | none | none | none | none
14/F539 | 2.5 | none | none | none | none
15/F543 | 2.5 | none | none | none | none
16/F548 | 2.5 | none | none | none | none
17/F707 | 5 | none | none | none | none
18/F723 | 5 | none | none | none | none
19/F728 | 5 | none | none | none | none
20/F746 | 5 | none | none | none | none
21/F701 | 5 | none | none | none | none
22/F703 | 5 | none | none | none | none
23/F711 | 5 | none | none | none | none
24/F717 | 5 | none | none | none | none

Table K-10 Kras Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal

Cobalt Metal Concentration | Mutation Frequency | Codon 12 (GGT) | | | | Codon 13 (GGC) | Codon 61 (CAA)
Cobalt Metal Concentration | Mutation Frequency | (GAT) | (TGT) | (GTT) | (CGT) | (CGC) | (CGA) | (CAT) | (CAC)
Historical Control^a^ | 34/124 (27%) | 14 | 5 | 1 | 0 | 6 | 3 | 4 | 1
0 mg/m^3^ | 0/10 (0%)^###^ | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
1.25 mg/m^3^ | 11/16 (69%)*** | 1 | 0 | 7 | 0 | 0 | 1 | 2 | 0
2.5 mg/m^3^ | 11/23 (48%)** | 2 | 1 | 5 | 0 | 0 | 1 | 0 | 2
5 mg/m^3^ | 24/30 (80%)*** | 2 | 0 | 11^b^ | 1^b^ | 4 | 3^b^ | 2 | 3
All exposed groups combined | 46/69 (67%)*** | 5 | 1 | 23^b^ | 1^b^ | 4 | 5^b^ | 4 | 5

** Significantly different (P ≤ 0.01) from the chamber control group by the Fischer’s exact test.

*** P ≤ 0.001 by one-sided Fischer exact test for single or combined exposure groups or a one-sided Cochran-Armitage trend test for the chamber control group.

^###^ Significant trend (P ≤ 0.001) by the Cochran-Armitage trend test.

^a^ Spontaneous lung neoplasms from control B6C3F1 mice.^275^

^b^ Same animal with double mutations.

Table K-11 Kras and Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Male B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal

Sample/ Animal # | Cobalt Conc. (mg/m^3^) | Kras | | | Egfr
Sample/ Animal # | Cobalt Conc. (mg/m^3^) | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/M42 | 0 | none | none | none | none | none | none | none
2/M12 | 0 | none | none | none | none | none | none | none
3/M30 | 0 | none | none | none | none | none | none | none
4/M36 | 0 | none | none | none | none | none | none | none
5/M21 | 0 | none | none | none | none | none | none | none
6/M24 | 0 | none | none | none | none | none | none | none
7/M201 | 1.25 | none | none | none | none | none | Codon 807 CAC→CAT (His→His) | none
8/M203 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
9/M209 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
10/M211 | 1.25 | none | none | none | none | none | none | none
11/M216 | 1.25 | none | none | none | Codon 721 GGT→AGT (Gly→Ser) | none | none | none
12/M219 | 1.25 | GGT→GAT (Gly→Asp) | none | none | none | none | none | Codon 846 CTG→CAG (Leu→Gln)
13/M204 | 1.25 | none | none | CAA→CAT (Gln→His) | none | none | none | none
14/M217 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
15/M218 | 1.25 | none | none | CAA→CGA (Gln→Arg) | none | none | none | none
16/M401 | 2.5 | none | none | none | none | none | none | Codon 870 GAA→AAA (Glu→Lys)
17/M403 | 2.5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
18/M405 | 2.5 | none | none | none | none | Codon 735 CCA→CTA (Pro→Leu) | none | none
19/M407 | 2.5 | none | none | none | none | none | Codon 812 GGC→GAC (Gly→Asp) | none
20/M409 | 2.5 | none | none | none | none | none | none | none
21/M404 | 2.5 | none | none | none | none | none | none | none
22/M411 | 2.5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
23/M413 | 2.5 | GGT→GTT (Gly→Val) | none | CAA→CGA (Gln→Arg) | none | none | none | none
24/M417 | 2.5 | GGT→TGT (Gly→Cys) | none | none | none | none | none | none
25/M418 | 2.5 | none | none | none | none | none | none | none
26/M618 | 5 | none | none | CAA→CAT (Gln→His) | none | none | none | none
27/M627 | 5 | none | none | CAA→CAT (Gln→His) | none | none | none | none
28/M629 | 5 | none | none | CAACAC (Gln→His)
29/M606 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
30/M648 | 5 | none | GGC→CGC (Gly→Arg) | none | none | none | none | none
31/M632 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
32/M601 | 5 | none | none | none | none | none | none | none
33/M602 | 5 | none | none | none | none | none | none | Codon 861 GCC→ACC (Ala→Thr)
34/M605 | 5 | GGT→GTT (Gly→Val) | none | CAA→CGA (Gln→Arg) | none | none | Codon 791 ATT→GTT (Ile→Val) | none
35/M609 | 5 | none | GGC→CGC (Gly→Arg) | none | none | none | Codon 804 GTC→GTA (Val→Val) | none
36/M611 | 5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
37/M604 | 5 | none | none | none | none | none | none | none
38/M607 | 5 | none | none | CAA→CAC (Gln→His) | none | none | none | none
39/M608-12a | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
40/M608-13a | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none

^a^ Same animal with different blocks.

Table K-12 Kras and Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Female B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Conc. (mg/m^3^) | Kras | | | Egfr
Sample/Animal # | Cobalt Conc. (mg/m^3^) | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/F145 | 0 | none | none | none | none | none | none | none
2/F125 | 0 | none | none | none | none | none | none | none
3/F106 | 0 | none | none | none | none | none | none | none
4/F131 | 0 | none | none | none | none | none | none | Codon 832 GAT→GAC (Asp→Asp) Codon 859 GGG→GGA (Gly→Gly)
5/F308 | 1.25 | none | none | none | none | none | none | none
6/F318 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
7/F322 | 1.25 | none | none | none | none | none | none | none
8/F306 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
9/F307 | 1.25 | none | none | CAA→CAT (Gln→His) | none | none | none | none
10/F321 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
11/F326 | 1.25 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
12/F502 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
13/F506 | 2.5 | none | none | none | none | none | Codon 780 CTG→CAG (Leu→Gln) | none
14/F508 | 2.5 | none | none | none | none | none | Codon 817 CTC→TTC (Leu→Phe) | none
15/F509 | 2.5 | none | none | none | none | none | none | none
16/F511 | 2.5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
17/F512 | 2.5 | none | none | none | none | none | Codon 801 CTG→CAG (Leu→Gln) | none
18/F517 | 2.5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | Codon 873 GCC→ACC (Ala→Thr)
19/F504 | 2.5 | none | none | none | none | none | none | none
20/F505 | 2.5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
21/F507 | 2.5 | none | none | CAA→CAC (Gln→His) | none | none | none | none
22/F514 | 2.5 | none | none | none | none | none | none | none
23/F515 | 2.5 | none | none | CAA→CAC (Gln→His) | none | none | none | none
24/F517 | 2.5 | none | none | none | none | none | none | none
25/F746 | 5 | none | GGC→CGC (Gly→Arg) | none | none | none | none | none
26/F717 | 5 | none | GGC→CGC (Gly→Arg) | none | none | none | none | none
27/F720 | 5 | none | none | none | none | none | none | none
28/F732 | 5 | none | none | CAA→CAC (Gln→His) | none | none | none | none
29/F718 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
30/F714 | 5 | GGT→GAT (Gly→Asp) | none | none | none | none | none | none
31/F723 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
32/F710 | 5 | GGT→CGT (Gly→Arg) | none | CAA→CGA (Gln→Arg) | none | none | none | none
33/F729 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
34/F747 | 5 | none | none | none | none | none | none | none
35/F711 | 5 | none | none | none | none | none | Codon 780 CTG→CAG (Leu→Gln) | none
36/F712 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
37/F713 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
38/F715 | 5 | GGT→GTT (Gly→Val) | none | none | none | none | none | none
39/F710 | 5 | none | none | CAA→CGA (Gln→Arg) | none | none | none | none

Table K-13 Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal^a^

Cobalt Metal Concentration | Mutation Frequency | Exon 18 | Exon 19 | Exon 20 | Exon 21
0 mg/m^3^ | 0/10 (0%) | 0 | 0 | 0 | 0
1.25 mg/m^3^ | 2/16 (13%) | 1 | 0 | 0 | 1
2.5 mg/m^3^ | 7/23 (30%) | 0 | 1 | 4 | 2
5 mg/m^3^ | 3/30 (10%) | 0 | 0 | 2 | 1
All exposed groups combined | 12/69 (17%) | 1 | 1 | 6 | 4

^a^ Silent mutations are not included.

Table K-14 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Male and Female B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal^a^

Cobalt Metal Concentration | Mutation Frequency | Exon 5 | Exon 6 | Exon 7
0 mg/m^3^ | 0/10 (0%) | 0 | 0 | 0
1.25 mg/m^3^ | 3/16 (19%) | 1 | 0 | 2
2.5 mg/m^3^ | 3/23 (13%) | 2^b^ | 1 | 1^b^
5 mg/m^3^ | 6/30 (20%) | 4 | 2 | 1
All exposed groups combined | 13/69 (19%) | 7^b^ | 3 | 4^b^

^a^ Silent mutations are not included. No mutations were detected in exon 8.

^b^ Same animal with double mutations.

Table K-15 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Male B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Metal Concentration (mg/m^3^) | Exon 5 | Exon 6 | Exon 7 | Exon 8
1/M42 | 0 | none | none | none | none
2/M12 | 0 | none | none | none | none
3/M30 | 0 | none | none | none | none
4/M36 | 0 | none | none | none | none
5/M21 | 0 | none | none | none | none
6/M24 | 0 | none | none | none | none
7/M201 | 1.25 | none | Codon 203 CTG→CTA (Leu→Leu) | none | none
8/M203 | 1.25 | none | none | none | none
9/M209 | 1.25 | none | none | Codon 230 CAC→TAC (His→Tyr) | none
10/M211 | 1.25 | none | none | none | none
11/M216 | 1.25 | Codon 156 GCC→CCC (Ala→Pro) | none | none | none
12/M219 | 1.25 | none | none | none | none
13/M204 | 1.25 | none | none | none | none
14/M217 | 1.25 | none | none | none | none
15/M218 | 1.25 | none | none | none | none
16/M401 | 2.5 | none | none | none | none
17/M403 | 2.5 | none | none | none | none
18/M405 | 2.5 | Codon 179 TGC→TAC (Cys→Tyr) | none | none | none
19/M407 | 2.5 | none | none | none | none
20/M409 | 2.5 | none | Codon 194 GTG→GAG (Val→Glu) | none | none
21/M404 | 2.5 | none | none | none | none
22/M411 | 2.5 | none | none | none | none
23/M413 | 2.5 | Codon 156 GCC→CCC (Ala→Pro) | none | Codon 232 AAG→ACG (Lys→Thr) | none
24/M417 | 2.5 | none | none | none | none
25/M418 | 2.5 | none | none | Codon 231 TAC→TAT (Tyr→Tyr) | none
26/M618 | 5 | none | none | none | none
27/M627 | 5 | none | none | none | none
28/M629 | 5 | none | Codon 212 AGC→GGC (Ser→Gly) | none | none
29/M606 | 5 | none | none | none | none
30/M648 | 5 | none | none | none | none
31/M632 | 5 | none | none | none | none
32/M601 | 5 | none | Codon 192 ATC→ATT (Ile→Ile) | none | none
33/M602 | 5 | none | none | none | none
34/M605 | 5 | Codon 155 CGC→CCC (Arg→Pro) | none | none | none
35/M609 | 5 | Codon 155 CGC→CCC (Arg→Pro) | none | none | none
36/M611 | 5 | none | none | none | none
37/M604 | 5 | none | none | none | none
38/M607 | 5 | none | none | none | none
39/M608-12a | 5 | none | none | none | none
40/M608-13a | 5 | none | none | none | none

^a^ Same animal with different blocks.

Table K-16 Tp53 Mutations in Alveolar/Bronchiolar Carcinomas from Female B6C3F1/N Mice in the Two-year Inhalation Study of Cobalt Metal

Sample/Animal # | Cobalt Metal Concentration (mg/m^3^) | Exon 5 | Exon 6 | Exon 7 | Exon 8
1/F145 | 0 | none | none | none | none
2/F125 | 0 | none | none | none | none
3/F106 | 0 | none | none | none | none
4/F131 | 0 | none | none | none | none
5/F308 | 1.25 | none | none | Codon 257 TCC→TTC (Ser→Phe) | none
6/F318 | 1.25 | none | none | none | none
7/F322 | 1.25 | none | none | none | none
8/F306 | 1.25 | none | none | none | none
9/F307 | 1.25 | none | none | none | none
10/F321 | 1.25 | none | none | none | none
11/F326 | 1.25 | none | none | none | none
12/F502 | 2.5 | none | none | none | none
13/F506 | 2.5 | none | none | none | none
14/F508 | 2.5 | none | none | none | none
15/F509 | 2.5 | none | none | none | none
16/F511 | 2.5 | none | none | none | none
17/F512 | 2.5 | none | none | none | none
18/F517 | 2.5 | none | none | none | none
19/F504 | 2.5 | none | none | none | none
20/F505 | 2.5 | none | none | none | none
21/F507 | 2.5 | none | none | none | none
22/F514 | 2.5 | none | none | none | none
23/F515 | 2.5 | none | none | none | none
24/F517 | 2.5 | none | none | none | none
25/F746 | 5 | none | none | none | none
26/F717 | 5 | none | none | none | none
27/F720 | 5 | none | none | none | none
28/F732 | 5 | none | Codon 212 AGC→GGC (Ser→Gly) | none | none
29/F718 | 5 | none | none | none | none
30/F714 | 5 | none | none | none | none
31/F723 | 5 | none | none | none | none
32/F710 | 5 | none | none | none | none
33/F729 | 5 | none | none | none | none
34/F747 | 5 | none | none | none | none
35/F711 | 5 | Codon 161 AAG→AAA (Lys→Lys) Codon 179 TGC→TTC (Cys→Gly) | none | none | none
36/F712 | 5 | Codon 158 GCC→ACC (Ala→Thr) Codon 179 TGC→GGC (Cys→Gly) | none | none | none
37/F713 | 5 | none | none | none | none
38/F715 | 5 | none | none | Codon 239 TGC→TGG (Cys→Trp) | none
39/F710 | 5 | none | none | none | none

Table K-17 Summary of Kras Mutations in Alveolar/Bronchiolar Neoplasms from Male and Female B6C3F1/N Mice in Selected Two-year NTP Studies

Chemical (Study Type) | Mutations | Codon 12 GGT | | | | | | Codon 13 GGC | | | | | | Codon 61 CAA
Chemical (Study Type) | Mutations | GAT | TGT | GTT | CGT | Other | | CGC | GAC | CGA | CAT | Other | | CAC | CTA | CGA | CAT | CAC
Historical controls
| 34/124 (27%) | 14 | 5 | 1 | 0 | – | | 6 | 0 | 0 | 0 | – | | 0 | 0 | 3 | 4 | 1
Concurrent chamber controls (inhalation)
| 0/10 (0%) | 0 | 0 | 0 | 0 | – | | 0 | 0 | 0 | 0 | – | | 0 | 0 | 0 | 0 | 0
Cobalt metal (inhalation)^a^
| 46/69 (67%) | 5 | 1 | 23 | 1 | – | | 4 | 0 | 0 | 0 | – | | 0 | 0 | 5 | 4 | 5
Cobalt sulfate heptahydrate (inhalation)
| 9/26 (35%) | 2 | 1 | 5 | 0 | – | | 1 | 0 | 0 | 0 | – | | 0 | 0 | 0 | 0 | 0
Ozone (inhalation)
| 19/26 (73%) | 3 | 2 | 5 | 0 | – | | 0 | 1 | 0 | 0 | – | | 0 | 8 | 0 | 0 | 0
1,3,Butadiene (inhalation)
| 20/24 (83%) | 1 | 2 | 0 | 0 | – | | 8 | 0 | 0 | 0 | – | | 0 | 6 | 3 | 0 | 0
Methylene chloride (inhalation)
| 11/54 (20%) | 1 | 1 | 1 | 0 | – | | 1 | 0 | 0 | 0 | – | | 4 | 1 | 1 | 1 | 0
Ethylene oxide (inhalation)^a^
| 23/23 (100%) | 2 | 0 | 21 | 0 | – | | 0 | 0 | 0 | 0 | AGC | | 0 | 0 | 1 | 0 | 0
Cumene (inhalation)
| 45/52 (87%) | 6 | 5 | 11 | 3 | – | | 4 | 0 | 13 | 0 | – | | 2 | 1 | 0 | 0 | 0
2,2-Bis(bromomethyl-1,3-propanediol (feed)
| 29/51 (57%) | 20 | 1 | 7 | 0 | – | | 1 | 0 | 0 | 0 | – | | 0 | 0 | 0 | 0 | 0
Tetranitromethane (inhalation)^a^
| 14/26 (54%) | 13 | 0 | 0 | 0 | – | | 2 | 0 | 0 | 0 | – | | 0 | 0 | 0 | 0 | 0
Isoprene (inhalation)
| 11/11 (100%) | 0 | 0 | 0 | 0 | – | | 1 | 0 | 0 | 0 | – | | 0 | 10 | 0 | 0 | 0
Chloroprene (inhalation)
| 37/46 (80%) | 5 | 0 | 2 | 1 | ATT CTT | | 2 | 0 | 0 | 0 | – | | 0 | 22 | 3 | 0 | 0

^a^ If the same neoplasm had two point mutations, it was counted as one.