# Appendix J Liver Cytochrome P450 Data

Table J-1 Liver Cytochrome P450 Data for Female Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 3 | 3 | 3 | 3 | 3
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 26 | 0.571 ± 0.022 | 0.707 ± 0.022 | 0.730 ± 0.042* | 0.615 ± 0.039 | 0.635 ± 0.009
Day 40 | 0.615 ± 0.035 | 0.703 ± 0.048 | 0.650 ± 0.050 | 0.592 ± 0.047 | 0.637 ± 0.027
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 26 | 44.185 ± 2.751 | 41.774 ± 1.129 | 36.922 ± 1.376* | 36.933 ± 0.636* | 36.119 ± 2.635*
Day 40 | 34.291 ± 1.548 | 37.698 ± 4.281 | 36.055 ± 2.482 | 32.852 ± 2.045 | 38.460 ± 3.395
7-Pentoxyresorufin-O-deethylase (PROD) (pmol/minute per mg microsomal protein)
Day 26 | 4.766 ± 0.122 | 4.918 ± 0.094 | 4.489 ± 0.214 | 4.089 ± 0.161* | 3.899 ± 0.247*
Day 40 | 3.905 ± 0.154 | 4.334 ± 0.311 | 4.283 ± 0.071 | 3.721 ± 0.230 | 3.747 ± 0.241

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

^a^ Data are presented as mean ± standard error.

Table J-2 Liver Cytochrome P450 Data for Special Study Female Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
n | 3 | 3 | 3 | 3 | 3 | 3
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 26 | 0.515 ± 0.018 | 0.434 ± 0.017 | 0.521 ± 0.043 | 0.525 ± 0.016 | 0.752 ± 0.081 | 0.659 ± 0.014
Day 40 | 0.483 ± 0.031 | 0.557 ± 0.041 | 0.515 ± 0.025 | 0.526 ± 0.052 | 0.656 ± 0.044** | 0.736 ± 0.070**
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 26 | 52.375 ± 4.334 | 53.046 ± 0.746 | 63.475 ± 6.343 | 58.552 ± 3.113 | 65.036 ± 0.191* | 70.237 ± 4.834*
Day 40 | 52.914 ± 3.989 | 53.358 ± 0.936 | 60.768 ± 2.310 | 58.398 ± 1.156 | 67.890 ± 2.157** | 73.859 ± 7.616*
7-Pentoxyresorufin-O-deethylase (PROD) (pmol/minute per mg microsomal protein)
Day 26 | 9.992 ± 0.740 | 10.329 ± 0.517 | 10.349 ± 0.676 | 9.577 ± 0.800 | 11.013 ± 0.651 | 9.737 ± 0.337
Day 40 | 10.212 ± 0.388 | 10.150 ± 0.404 | 11.274 ± 0.558 | 10.234 ± 0.252 | 10.539 ± 0.492 | 9.148 ± 0.503

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error.