# Appendix I Tissue Burden Results

## I.1 Lung Deposition and Clearance Equations Used in the Two-week Inhalation Studies of Cobalt Metal

Lung clearance rates were calculated using postexposure data and Equation (1):

Equation (1): A_(t)_ = A_0_(e^−kt^)

where A_(t)_ is the lung burden (µg cobalt) at time t (t = 21 days postexposure), A_0_ is the lung burden at t = 0 days postexposure, and k is the lung clearance rate constant (fraction cleared per day).

Lung clearance half-lives in days (t_½_) were calculated from Equation (2), where ln2 is the Napierian logarithm of 2:

Equation (2): t_1/2_ = ln2/k

Deposition rates were calculated from lung cobalt burdens using Equation (3). The lung cobalt burden and time at terminal kill and the calculated lung clearance rate constant were used to solve for the deposition rate α (µg/day).

Equation (3): A_(t)_ = (α/k)(1−e^−kt^)

In Equation (3), A_(t)_ is the lung burden (µg cobalt) at time t [t = 16 (rats) or 17 (mice) days on study]; α is the amount of cobalt deposited (µg/day); and k is the first-order clearance rate constant derived from Equation (1). Steady-state or equilibrium lung burdens (A_e_, µg cobalt) were calculated according to Equation (4):

Equation (4): A_e_ = α/k

Blood elimination rates and half-lives were calculated as described for lung cobalt burden, except blood cobalt concentration data were used.

## I.2 Lung Deposition and Clearance Equations Used in the Three-month and Two-year Inhalation Studies of Cobalt Metal

Lung burdens during the recovery period initially decreased rapidly, followed by a slower clearance phase. The pattern of decrease fit a two-compartment, biexponential clearance model of the form shown in Equation (5):

Equation (5): L_(t)_ = Ae^−at^ + Be^−bt^

where L_(t)_ is the retained lung burden (µg cobalt/lung) at any recovery time point t (days); A and B are the lung burdens (µg cobalt/lung) at t = 0 days after exposure was terminated postexposure in the rapid and slow clearance compartments, respectively; and a and b are the lung clearance rate constants (in days^−1^) in the rapid and slow clearance compartments, respectively. This model was fitted to lung cobalt burdens normalized to exposure concentrations at 7, 14, 28, and 42 days after termination of exposures in the animals sampled. An exposure concentration term was included in Equation (5) to account for this normalization, and model output parameters A and B were subsequently converted to appropriate values by multiplying by exposure concentration.

Half-lives for the rapid and slow clearance phases were calculated using Equation (6):

Equation (6):t_½ (rapid phase)_ = ln2/a or t_½ (slow phase)_ = ln2/b

where t_½_ is the rapid or slow phase lung clearance half-life (in days), ln2 is the Napierian logarithm of 2, and a and b are the rapid phase and slow phase clearance rate constants, respectively, defined in Equation (5).

Given the nature of lung clearance observed with the recovery data, it was expected that a reasonable model for lung cobalt burden during exposure would incorporate a constant deposition rate and a two-compartment, biexponential clearance rate. Attempts were made to fit such a model to lung burden data collected during exposure. However, attempts to fit this model to the data were unsuccessful. The model fit to the data was poor, and standard errors for the parameter estimates were excessively large.

The inability of the two-compartment model to fit these data was possibly due to the fact that the data were inadequate to fully define the lung cobalt burden versus time curve, especially during the early part of the study. The rapid lung clearance half-lives calculated from the recovery period were on the order of 1 to 3 days. In examining plots of lung burden versus time during exposure, it was clear that lung burdens rapidly approached steady state. Within the first 5 days of exposure, lung burdens increased rapidly and were already approaching steady-state values. This was consistent with the rapid clearance half-life observed during the recovery period. Generally, after the first 5 to 40 days of exposure, lung burden values continued to increase slowly for the remainder of the exposure period as they asymptotically approached steady state over time. However, given that no data were collected until 5 days of exposure, there were insufficient data to define the early part of the lung burden versus the time curve during this period when lung burdens were rapidly changing. Thus, a possible explanation for the inability to fit the two-compartment model to lung burden data during exposure was the lack of data during the very early part of the study (<5 days).

However, a model that assumes a constant cobalt deposition rate and a one-compartment, monoexponential clearance rate provided a reasonable fit to the data collected during exposure. This model is defined by Equations (7), (8), and (9):

Equation (7): L_(t)_ = (D/k)(1–e^−kt^)

Equation (8): t_½_ = ln2/k

Equation (9): L_ss_ = D/k

where L_(t)_ is the retained lung burden (µg cobalt/lung) at any time t (days) during exposure; D is the deposition rate of cobalt in the lungs (µg cobalt/lung per day); k is the lung clearance rate constant (days^−1^); t_½_ is the clearance half-life in days; ln2 is the Napierian logarithm of 2; and L_ss_ is the predicted steady-state lung burden (µg cobalt/lung).

This one-compartment model does not adequately define the two-phase lung clearance process that was seen during the recovery period. This model predicts only one clearance half-life, and it is expected that this half-life would be intermediate between the true rapid and slow clearance half-lives. However, it was found that this model did generally fit the data adequately to provide a reasonably precise estimate for the cobalt deposition rate, which is important in predicting the dose of cobalt to the lungs arising from the inhalation process. While this model does not adequately describe the true clearance process, it provides reasonable predictive power for determining the lung dose. The two-compartment model provides an adequate description of the lung clearance process during the recovery period. Thus, between the two models used for data collected during and after exposure, reasonable estimates of both deposition and clearance parameters were obtained.

Because the 3-month study postexposure lung cobalt burden data fit the model described by Equation (5) reasonably well, the model chosen for the 2-year studies also included both rapid and slow lung clearance phases. However, lung burden data collected during the 2-year studies were all collected during the in-life parts of the studies because there was not a recovery period. Accordingly, the model used for the 2-year studies had to account for deposition rates as well as clearance rates, because both deposition and clearance were occurring during the in-life part of the study.

The model used for the 2-year studies assumed zero-order (constant) deposition and first-order (with respect to lung burden) clearance rates and included rapid and slow clearance phases. This model is described by Equation (10):

Equation (10): L_(t)_ = A/k_a_(1–e^−k^_a_^t^) + B/k_b_(1–e^−k^_b_^t^)

Equation (10) is essentially the sum of two processes that incorporate zero-order deposition and first-order clearance. A and B represent the deposition rates (µg cobalt/day) in the rapid and slow phases, respectively, and k_a_ and k_b_ represent the lung clearance rate constants (days^−1^) in the rapid and slow clearance phases, respectively.

This model was fit to the lung cobalt burden data collected during the in-life parts of the 3-month and 2-year studies using data collected in both studies from the 1.25, 2.5, and 5 mg/m^3^ exposure groups. The model was fit to the data from each exposure group using SAS PROC NLIN (SAS Institute Inc., Cary, NC). This fit provided direct estimates of A, k_a_, B, and k_b_ along with their asymptotic standard errors. These values were used to calculate the following quantities along with their approximate standard errors using propagation of error techniques:

• Fraction of deposition in the slow clearance phase: F_B_ = B/(A + B)

• Half-life of the rapid clearance phase: t_½a_ = ln2/k_a_ (days)

• Half-life of the slow clearance phase: t_½b_ = ln2/k_b_ (days)

• Theoretical steady-state lung burden for the rapid phase: L_SSa_ = A/k_a_ (µg cobalt/lung)

• Theoretical steady-state lung burden for the slow phase: L_SSb_ = B/k_b_ (µg cobalt/lung)

Due to the potential for more uncertainty with relatively higher lung cobalt burdens, several weighting schemes were investigated, including unweighted, 1/mean, and 1/variance. Review of the results suggested that 1/mean was the best choice, so all results presented are from model fits using 1/mean weighting.

Table I-1 Tissue Weights, Cobalt Concentrations, and Cobalt Burdens for Rats in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^
Male
n | 5 | 5 | 5 | 5 | 0^b^
Blood
µg Co/g blood
Day 16 | 0 | 0.14 ± 0.01 | 0.27 ± 0.02 | 0.45 ± 0.02 | –
Serum
µg Co/g serum
Day 16 | 0 | 0.28 ± 0.01 | 0.48 ± 0.02 | 0.72 ± 0.04 | –
Right femur
Absolute right femur wt (g)
Day 16 | 0.142 ± 0.008 | 0.143 ± 0.004 | 0.135 ± 0.003 | 0.116 ± 0.005* | –
µg Co/g right femur
Day 16 | 0 | 0.58 ± 0.04 | 1.08 ± 0.09 | 2.24 ± 0.13 | –
µg Co/right femur
Day 16 | 0 | 0.082 ± 0.006 | 0.146 ± 0.014 | 0.253 ± 0.009 | –
µg Co/right femur per mg Co/m^3^
Day 16 | NA | 0.033 ± 0.002 | 0.029 ± 0.003 | 0.025 ± 0.001 | –
Heart
Absolute heart wt (g)
Day 16 | 0.551 ± 0.013 | 0.540 ± 0.007 | 0.527 ± 0.014 | 0.468 ± 0.014** | –
µg Co/g heart
Day 16 | 0 | 0.48 ± 0.03 | 0.73 ± 0.06 | 1.07 ± 0.06 | –
µg Co/heart
Day 16 | 0 | 0.258 ± 0.014 | 0.384 ± 0.034 | 0.498 ± 0.024 | –
µg Co/heart per mg Co/m^3^
Day 16 | NA | 0.103 ± 0.006 | 0.077 ± 0.007 | 0.050 ± 0.002 | –
Right kidney
Absolute right kidney wt (g)
Day 16 | 0.586 ± 0.017 | 0.579 ± 0.008 | 0.566 ± 0.016 | 0.519 ± 0.018 | –
µg Co/g right kidney
Day 16 | 0 | 2.04 ± 0.02 | 3.26 ± 0.18 | 5.90 ± 0.38 | –
µg Co/right kidney
Day 16 | 0 | 1.177 ± 0.018 | 1.838 ± 0.116 | 3.031 ± 0.146 | –
µg Co/right kidney per mg Co/m^3^
Day 16 | NA | 0.471 ± 0.007 | 0.368 ± 0.023 | 0.303 ± 0.015 | –
Liver
Absolute liver wt (g)
Day 16 | 5.834 ± 0.164 | 5.102 ± 0.094* | 5.081 ± 0.156* | 4.292 ± 0.238** | –
µg Co/g liver
Day 16 | 0 | 2.69 ± 0.09 | 5.14 ± 0.46 | 14.00 ± 1.58 | –
µg Co/liver
Day 16 | 0 | 13.638 ± 0.335 | 25.956 ± 2.189 | 58.632 ± 4.098 | –
µg Co/liver per mg Co/m^3^
Day 16 | NA | 5.455 ± 0.134 | 5.191 ± 0.438 | 5.863 ± 0.410 | –
Total lung^c^
Absolute total lung wt (g)
Day 16 | 1.140 ± 0.096 | 1.167 ± 0.085 | 1.186 ± 0.043 | 1.285 ± 0.116 | –
µg Co/total lung
Day 16 | 0 | 10.806 ± 0.619 | 20.077 ± 0.675 | 23.518 ± 1.647 | –
µg Co/total lung per mg Co/m^3^
Day 16 | NA | 4.322 ± 0.247 | 4.015 ± 0.135 | 2.352 ± 0.165 | –
Right lung^d^
Absolute right lung wt (g)
Day 16 | 0.573 ± 0.047 | 0.570 ± 0.055 | 0.578 ± 0.020 | 0.636 ± 0.063 | –
µg Co/g right lung
Day 16 | 0 | 9.53 ± 1.07 | 16.95 ± 0.38 | 18.44 ± 0.70 | –
Right testis
Absolute right testis wt (g)
Day 16 | 0.850 ± 0.040 | 0.870 ± 0.016 | 0.831 ± 0.033 | 0.563 ± 0.089 | –
µg Co/g right testis
Day 16 | 0 | 0.09 ± 0.00 | 0.20 ± 0.02 | 0.48 ± 0.06 | –
µg Co/right testis
Day 16 | 0 | 0.086 ± 0.003 | 0.170 ± 0.014 | 0.245 ± 0.011 | –
µg Co/right testis per mg Co/m^3^
Day 16 | NA | 0.034 ± 0.001 | 0.034 ± 0.003 | 0.024 ± 0.001 | –
Female
n
Day 16 | 5 | 5 | 5 | 5 | 2
Week 3 PE | 3 | 3 | 3 | 3 | 1^e^
Blood
µg Co/g blood
Day 16 | 0^f^ | 0.13 ± 0.01^f^ | 0.25 ± 0.02^f^ | 0.48 ± 0.02^f^ | 1.06 ± 0.17^g^
Week 3 PE | 0 | 0.02 ± 0.00 | 0.06 ± 0.01 | 0.12 ± 0.01 | 0.22
Serum
µg Co/g serum
Day 16 | 0^f^ | 0.25 ± 0.01^f^ | 0.44 ± 0.04^f^ | 0.76 ± 0.04^f^ | 1.88 ± 0.21^g^
Week 3 PE | 0 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01
Right femur
Absolute right femur wt (g)
Day 16 | 0.105 ± 0.006 | 0.115 ± 0.004 | 0.108 ± 0.003 | 0.100 ± 0.006 | 0.070 ± 0.005
µg Co/g right femur
Day 16 | 0 | 0.69 ± 0.06 | 1.30 ± 0.11 | 2.40 ± 0.24 | 6.09 ± 0.72
µg Co/right femur
Day 16 | 0 | 0.080 ± 0.005 | 0.139 ± 0.007 | 0.235 ± 0.012 | 0.418 ± 0.018
µg Co/right femur per mg Co/m^3^
Day 16 | NA | 0.032 ± 0.002 | 0.028 ± 0.001 | 0.023 ± 0.001 | 0.021 ± 0.001
Heart
Absolute heart wt (g)
Day 16 | 0.420 ± 0.013 | 0.469 ± 0.013 | 0.445 ± 0.013 | 0.416 ± 0.006 | 0.341 ± 0.004
µg Co/g heart
Day 16 | 0 | 0.44 ± 0.03 | 0.76 ± 0.04 | 1.03 ± 0.03 | 1.81 ± 0.19
µg Co/heart
Day 16 | 0 | 0.206 ± 0.008 | 0.339 ± 0.015 | 0.427 ± 0.014 | 0.613 ± 0.068
µg Co/heart per mg Co/m^3^
Day 16 | NA | 0.083 ± 0.003 | 0.068 ± 0.003 | 0.043 ± 0.001 | 0.031 ± 0.003
Right kidney
Absolute right kidney wt (g)
Day 16 | 0.499 ± 0.017 | 0.477 ± 0.008 | 0.465 ± 0.017 | 0.448 ± 0.008* | 0.356 ± 0.003**
µg Co/g right kidney
Day 16 | 0 | 1.78 ± 0.07 | 3.01 ± 0.21 | 5.74 ± 0.23 | 13.87 ± 0.51
µg Co/right kidney
Day 16 | 0 | 0.844 ± 0.025 | 1.382 ± 0.059 | 2.556 ± 0.111 | 4.896 ± 0.145
µg Co/right kidney per mg Co/m^3^
Day 16 | NA | 0.338 ± 0.010 | 0.276 ± 0.012 | 0.256 ± 0.011 | 0.245 ± 0.007
Liver
Absolute liver wt (g)
Day 16 | 4.073 ± 0.163 | 3.768 ± 0.046 | 3.613 ± 0.125* | 3.440 ± 0.049** | 2.567 ± 0.061**
µg Co/g liver
Day 16 | 0 | 2.15 ± 0.13 | 4.81 ± 0.43 | 15.93 ± 1.59 | 59.02 ± 9.05
µg Co/liver
Day 16 | 0 | 8.064 ± 0.403 | 17.223 ± 1.292 | 54.542 ± 5.203 | 150.785 ± 19.614
µg Co/liver per mg Co/m^3^
Day 16 | NA | 3.226 ± 0.161 | 3.445 ± 0.258 | 5.454 ± 0.520 | 7.539 ± 0.981
Total lung^c^
Absolute total lung wt (g)
Day 16 | 0.850 ± 0.032^f^ | 0.891 ± 0.051^f^ | 0.943 ± 0.034^f^ | 1.004 ± 0.042*^f^ | 0.996 ± 0.026*^g^
Week 3 PE | 0.90 ± 0.02 | 0.96 ± 0.07 | 1.24 ± 0.10* | 1.17 ± 0.04* | 1.41
µg Co/total lung
Day 16 | 0^f^ | 9.713 ± 0.431^f^ | 17.289 ± 0.805^f^ | 20.710 ± 1.070^f^ | 49.842 ± 11.212^g^
Week 3 PE | 0 | 0.605 ± 0.011 | 1.288 ± 0.113 | 1.278 ± 0.112 | 1.514
µg Co/total lung per mg Co/m^3^
Day 16 | NA^f^ | 3.885 ± 0.173^f^ | 3.458 ± 0.161^f^ | 2.071 ± 0.107^f^ | 2.492 ± 0.561^g^
Week 3 PE | NA | 0.242 ± 0.004 | 0.258 ± 0.023 | 0.128 ± 0.011 | 0.076
Left lung^h^
Absolute left lung wt (g)
Day 16 | 0.237 ± 0.048^i^ | 0.333 ± 0.061^i^ | 0.299 ± 0.009^i^ | 0.275 ± 0.003^i^ | 0.299^e^
Week 3 PE | 0.24 ± 0.01 | 0.28 ± 0.02 | 0.38 ± 0.04** | 0.35 ± 0.00** | 0.40
µg Co/g left lung
Day 16 | 0^i^ | 9.89 ± 2.35^i^ | 19.04 ± 0.32^i^ | 21.87 ± 2.07^i^ | 35.68^e^
Week 3 PE | 0 | 0.62 ± 0.01 | 0.93 ± 0.17 | 1.09 ± 0.10 | 0.96
µg Co/left lung
Day 16 | 0^i^ | 3.150 ± 0.178^i^ | 5.698 ± 0.267^i^ | 6.000 ± 0.514^i^ | 10.669^e^
Week 3 PE | 0 | 0.171 ± 0.011 | 0.335 ± 0.027 | 0.377 ± 0.032 | 0.386
µg Co/left lung per mg Co/m^3^
Day 16 | NA^i^ | 1.260 ± 0.071^i^ | 1.140 ± 0.053^i^ | 0.600 ± 0.051^i^ | 0.533^e^
Week 3 PE | NA | 0.069 ± 0.004 | 0.067 ± 0.005 | 0.038 ± 0.003 | 0.019
Right lung^d^
Absolute right lung wt (g)
Day 16 | 0.404 ± 0.018^f^ | 0.446 ± 0.036^f^ | 0.471 ± 0.025^f^ | 0.519 ± 0.022**^f^ | 0.539 ± 0.018**^g^
Week 3 PE | 0.44 ± 0.01 | 0.48 ± 0.03 | 0.63 ± 0.05** | 0.60 ± 0.01** | 0.77
µg Co/g right lung
Day 16 | 0^f^ | 11.06 ± 0.66^f^ | 18.43 ± 0.92^f^ | 20.82 ± 1.31^f^ | 49.55 ± 9.81^f^
Week 3 PE | 0 | 0.64 ± 0.04 | 1.06 ± 0.16 | 1.09 ± 0.10 | 1.07
µg Co/right lung
Day 16 | 0^i^ | 5.501 ± 0.323^i^ | 10.283 ± 0.593^i^ | 11.304 ± 1.402^i^ | 17.765^e^
Week 3 PE | 0 | 0.302 ± 0.006 | 0.652 ± 0.057 | 0.661 ± 0.059 | 0.823
µg Co/right lung per mg Co/m^3^
Day 16 | NA^i^ | 2.200 ± 0.129^i^ | 2.057 ± 0.119^i^ | 1.130 ± 0.140^i^ | 0.888^e^
Week 3 PE | NA | 0.121 ± 0.002 | 0.130 ± 0.011 | 0.066 ± 0.006 | 0.041

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. All values except absolute tissue weights are control corrected. Statistical tests were performed only on absolute tissue weight data. All 40 mg/m^3^ rats died before the end of the study. NA = not applicable; PE = postexposure.

^b^ All 20 mg/m^3^ male rats died before the end of the study; no data are available for this group.

^c^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

^d^ Right lung cobalt burden was calculated using the right lung weight and the concentration of cobalt measured in the right lung.

^e^ n = 1; No standard error was calculated; less than two measurements were available.

^f^ n = 7.

^g^ n = 3.

^h^ Left lung cobalt burden was calculated using the left lung weight and the concentration of cobalt measured in the left lung.

^i^ n = 2.

Table I-2 Deposition and Clearance Parameter Estimates for Female Rats in the Two-week Inhalation Study of Cobalt Metal^a^

Tissue | Exposure Concentration (mg/m^3^) | k (days^−1^) | t_1/2_(days) | α (µg Co/day) | A_e_ (µg Co)
Blood | 2.5 | 0.07 | 9.45 | NA | NA
Blood | 5 | 0.06 | 11.09 | NA | NA
Blood | 10 | 0.07 | 10.35 | NA | NA
Blood | 20 | 0.08 | 9.15 | NA | NA
Serum | 2.5 | –^b^ | NA | NA | NA
Serum | 5 | – | NA | NA | NA
Serum | 10 | 0.21 | 3.35 | NA | NA
Serum | 20 | 0.25 | 2.77 | NA | NA
Lung^c^ | 2.5 | 0.13 | 5.24 | 1.46 | 11.06
Lung^c^ | 5 | 0.12 | 5.61 | 2.48 | 20.07
Lung^c^ | 10 | 0.13 | 5.23 | 3.12 | 23.54
Lung^c^ | 20 | 0.17 | 4.17 | 8.91 | 53.59

^a^ Statistical analyses of these data were not performed due to the limited number of time points and data points within some time points. k = first-order clearance rate constant; t_½_ = clearance half-life; α=lung deposition rate; A_e_ = steady-state lung burden; NA = not applicable.

^b^ Parameters not calculated when average concentration for a time point is zero.

^c^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

Table I-3 Urine Volume, Creatinine and Cobalt Concentrations, and Cobalt Burdens for Rats on Day 12 in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^
Male
n | 5 | 5 | 5 | 5 | 1^b^
Volume (mL/16 hours) | 19.54 ± 2.70 | 17.88 ± 1.06 | 17.42 ± 0.43 | 5.88 ± 1.47** | 0.40
Creatinine (mg/dL) | 13.0 ± 1.8 | 13.0 ± 0.8 | 13.4 ± 1.0 | 23.4 ± 2.0** | 46.1
µg Co/mL (control corrected) | NA | 3.23 ± 0.33 | 5.98 ± 0.21 | 19.61 ± 2.97 | 71.27
µg Co/mg creatinine | 0.2 ± 0.1 | 25.0 ± 1.8** | 45.4 ± 3.0** | 81.8 ± 6.6** | 154.6
µg Co/16 hours (control corrected) | NA | 56.87 ± 4.24 | 104.13 ± 4.58 | 100.18 ± 8.95 | 28.51
µg Co/16 hours per mg Co/m^3^ (control corrected) | NA | 22.721 ± 1.691 | 20.817 ± 0.918 | 9.990 ± 0.897 | 1.407
Female
n | 5 | 5 | 5 | 5 | 2
Volume (mL/16 hours) | 15.74 ± 3.09 | 17.90 ± 2.68 | 10.98 ± 1.89 | 5.62 ± 2.23 | 0.25 ± 0.05*
Creatinine (mg/dL) | 12.9 ± 2.1 | 11.4 ± 1.3 | 16.8 ± 2.7 | 25.0 ± 4.3 | 50.4 ± 24.2*
µg Co/mL (control corrected) | NA | 2.51 ± 0.22 | 6.76 ± 1.10 | 20.21 ± 4.72 | 70.27 ± 22.35
µg Co/mg creatinine | 0.4 ± 0.1 | 22.7 ± 1.1** | 40.8 ± 2.5** | 76.9 ± 6.6** | 153.6 ± 29.4**
µg Co/16 hours (control corrected) | NA | 42.71 ± 1.86 | 66.22 ± 3.06 | 77.85 ± 5.27 | 18.68 ± 9.10
µg Co/16 hours per mg Co/m^3^ (control corrected) | NA | 17.111 ± 0.785 | 13.213 ± 0.621 | 7.749 ± 0.536 | 0.906 ± 0.455

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed only on data that were not control corrected. All 40 mg/m^3^ rats died before day 12; no data are available for this group. NA = not applicable.

^b^ No standard error was calculated for data in this exposed group; less than two measurements were available.

Table I-4 Tissue Weights, Cobalt Concentrations, and Cobalt Burdens for Female Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 3 | 3 | 3 | 3 | 3
Blood
µg Co/g blood
Day 5 | 0.004 ± 0.000 | 0.066 ± 0.006* | 0.109 ± 0.021** | 0.344 ± 0.071** | 0.745 ± 0.116**
Day 12 | 0.004 ± 0.000 | 0.065 ± 0.006* | 0.109 ± 0.014** | 0.235 ± 0.035** | 0.512 ± 0.009**
Day 26 | 0.004 ± 0.000 | 0.060 ± 0.002* | 0.096 ± 0.011** | 0.230 ± 0.003** | 0.520 ± 0.036**
Day 40 | 0.004 ± 0.000 | 0.053 ± 0.014* | 0.115 ± 0.020** | 0.199 ± 0.026** | 0.479 ± 0.046**
Day 61 | 0.004 ± 0.000 | 0.047 ± 0.011* | 0.116 ± 0.010** | 0.213 ± 0.013** | 0.440 ± 0.027**
Day 89 | 0.004 ± 0.000 | 0.037 ± 0.012* | 0.097 ± 0.013** | 0.164 ± 0.024** | 0.401 ± 0.012**
PE day 7 | 0.004 ± 0.000 | 0.025 ± 0.000* | 0.025 ± 0.000* | 0.048 ± 0.012** | 0.142 ± 0.013**
PE day 14 | 0.004 ± 0.000 | 0.018 ± 0.007 | 0.025 ± 0.000* | 0.038 ± 0.013** | 0.119 ± 0.010**
PE day 28 | 0.004 ± 0.000 | 0.011 ± 0.007 | 0.025 ± 0.000* | 0.025 ± 0.000* | 0.067 ± 0.003**
PE day 42 | 0.004 ± 0.000 | 0.004 ± 0.000 | 0.018 ± 0.007 | 0.025 ± 0.000* | 0.025 ± 0.000*
µg Co/g blood per mg Co/m^3^
Day 5 | – | 0.106 ± 0.009 | 0.087 ± 0.017 | 0.138 ± 0.029 | 0.149 ± 0.023
Day 12 | – | 0.104 ± 0.010 | 0.087 ± 0.011 | 0.094 ± 0.014 | 0.102 ± 0.002
Day 26 | – | 0.095 ± 0.004 | 0.077 ± 0.009 | 0.092 ± 0.001 | 0.104 ± 0.007
Day 40 | – | 0.085 ± 0.022 | 0.092 ± 0.016 | 0.079 ± 0.011 | 0.096 ± 0.009
Day 61 | – | 0.076 ± 0.018 | 0.093 ± 0.008 | 0.085 ± 0.005 | 0.088 ± 0.005
Day 89 | – | 0.059 ± 0.019 | 0.078 ± 0.010 | 0.066 ± 0.009 | 0.080 ± 0.002
PE day 7 | – | 0.040 ± 0.000 | 0.020 ± 0.000 | 0.019 ± 0.005 | 0.028 ± 0.003
PE day 14 | – | 0.029 ± 0.011 | 0.020 ± 0.000 | 0.015 ± 0.005 | 0.024 ± 0.002
PE day 28 | – | 0.017 ± 0.011 | 0.020 ± 0.000 | 0.010 ± 0.000 | 0.013 ± 0.001
PE day 42 | – | 0.006 ± 0.000 | 0.014 ± 0.006 | 0.010 ± 0.000 | 0.005 ± 0.000
Liver
Absolute liver wt (g)
Day 26 | 5.601 ± 0.170 | 4.917 ± 0.119 | 5.342 ± 0.163 | 5.324 ± 0.111 | 4.188 ± 0.281*
Day 40 | 5.810 ± 0.134 | 5.261 ± 0.039 | 5.689 ± 0.388 | 5.843 ± 0.320 | 5.194 ± 0.358
µg Co/g liver
Day 26 | 0.025 ± 0.000 | 0.801 ± 0.069* | 1.360 ± 0.146** | 2.975 ± 0.103** | 6.762 ± 0.100**
Day 40 | 0.025 ± 0.000 | 0.666 ± 0.128* | 1.322 ± 0.268* | 2.070 ± 0.084** | 4.893 ± 0.462**
µg Co/liver
Day 26 | 0.140 ± 0.004 | 3.937 ± 0.333* | 7.279 ± 0.886** | 15.833 ± 0.551** | 28.273 ± 1.584**
Day 40 | 0.145 ± 0.003 | 3.503 ± 0.671* | 7.324 ± 1.093** | 12.139 ± 1.079** | 25.095 ± 0.995**
µg Co per liver Co/m^3^
Day 26 | – | 6.299 ± 0.533 | 5.823 ± 0.709 | 6.333 ± 0.220 | 5.655 ± 0.317
Day 40 | – | 5.605 ± 1.074 | 5.859 ± 0.874 | 4.856 ± 0.432 | 5.019 ± 0.199
Total lung^b^
Absolute total lung wt (g)
Day 5 | 0.957 ± 0.072 | 0.626 ± 0.057* | 0.768 ± 0.029 | 0.711 ± 0.097 | 0.809 ± 0.094
Day 12 | 0.826 ± 0.030 | 0.944 ± 0.170 | 0.723 ± 0.052 | 0.763 ± 0.031 | 0.953 ± 0.020
Day 26 | 1.028 ± 0.134 | 0.741 ± 0.019 | 0.862 ± 0.058 | 0.965 ± 0.021 | 0.957 ± 0.077
Day 40 | 0.841 ± 0.012 | 0.817 ± 0.014 | 0.959 ± 0.075 | 1.111 ± 0.064 | 1.206 ± 0.075*
Day 61 | 0.849 ± 0.027 | 1.046 ± 0.019* | 1.093 ± 0.038* | 1.129 ± 0.056* | 1.291 ± 0.078**
Day 89 | 0.816 ± 0.034 | 1.233 ± 0.014 | 1.224 ± 0.095 | 1.322 ± 0.040** | 1.318 ± 0.006**
PE day 7 | 0.755 ± 0.059 | 1.176 ± 0.034 | 1.295 ± 0.022** | 1.247 ± 0.031 | 1.206 ± 0.065
PE day 14 | 0.961 ± 0.101 | 1.369 ± 0.152 | 1.312 ± 0.093 | 1.165 ± 0.131 | 1.565 ± 0.292
PE day 28 | 0.904 ± 0.069 | 1.010 ± 0.057 | 1.065 ± 0.047 | 1.203 ± 0.109* | 1.181 ± 0.076*
PE day 42 | 0.842 ± 0.062 | 1.151 ± 0.074* | 0.993 ± 0.030 | 0.948 ± 0.030 | 1.451 ± 0.344
µg Co/g total lung
Day 5 | 0.040 ± 0.000 | 2.407 ± 0.107* | 3.829 ± 0.349** | 7.433 ± 0.773** | 12.976 ± 1.766**
Day 12 | 0.040 ± 0.000 | 2.407 ± 0.377* | 6.435 ± 0.725** | 12.663 ± 1.047** | 16.101 ± 0.689**
Day 26 | 0.040 ± 0.000 | 3.235 ± 0.034* | 6.456 ± 0.314** | 11.423 ± 0.814** | 21.581 ± 0.734**^c^
Day 40 | 0.040 ± 0.000 | 3.135 ± 0.117* | 6.114 ± 0.245** | 12.214 ± 0.180** | 21.263 ± 0.520**
Day 61 | 0.040 ± 0.000 | 2.682 ± 0.152* | 5.978 ± 0.303** | 11.146 ± 0.301** | 22.517 ± 1.509**
Day 89 | 0.040 ± 0.000 | 2.741 ± 0.131* | 6.018 ± 0.184** | 12.108 ± 0.417** | 21.882 ± 0.806**
PE day 7 | 0.040 ± 0.000 | 0.601 ± 0.011* | 1.216 ± 0.018** | 2.496 ± 0.015** | 6.067 ± 0.065**
PE day 14 | 0.040 ± 0.000 | 0.339 ± 0.035* | 0.769 ± 0.061** | 1.613 ± 0.121** | 2.705 ± 0.344**
PE day 28 | 0.040 ± 0.000 | 0.277 ± 0.010* | 0.499 ± 0.020** | 0.852 ± 0.080** | 1.603 ± 0.227**
PE day 42 | 0.040 ± 0.000 | 0.100 ± 0.000* | 0.372 ± 0.004** | 0.670 ± 0.023** | 0.959 ± 0.195**
µg Co/total lung
Day 5 | 0.038 ± 0.003 | 1.497 ± 0.082* | 2.923 ± 0.173** | 5.132 ± 0.107** | 10.304 ± 1.063**
Day 12 | 0.033 ± 0.001 | 2.144 ± 0.024* | 4.591 ± 0.334** | 9.607 ± 0.454** | 15.337 ± 0.723**
Day 26 | 0.041 ± 0.005 | 2.397 ± 0.086* | 5.530 ± 0.125** | 10.993 ± 0.592** | 20.545 ± 3.555**^c^
Day 40 | 0.034 ± 0.000 | 2.559 ± 0.051* | 5.888 ± 0.648** | 13.543 ± 0.593** | 25.710 ± 2.135**
Day 61 | 0.034 ± 0.001 | 2.809 ± 0.194* | 6.512 ± 0.146** | 12.603 ± 0.859** | 28.860 ± 0.770**
Day 89 | 0.033 ± 0.001 | 3.379 ± 0.162* | 7.345 ± 0.453** | 15.996 ± 0.544** | 28.857 ± 1.184**
PE day 7 | 0.030 ± 0.002 | 0.706 ± 0.014* | 1.576 ± 0.045** | 3.114 ± 0.095** | 7.325 ± 0.471**
PE day 14 | 0.038 ± 0.004 | 0.453 ± 0.011* | 0.999 ± 0.022** | 1.856 ± 0.135** | 4.042 ± 0.227**
PE day 28 | 0.036 ± 0.003 | 0.279 ± 0.012* | 0.531 ± 0.026** | 1.007 ± 0.013** | 1.864 ± 0.164**
PE day 42 | 0.034 ± 0.002 | 0.115 ± 0.007* | 0.370 ± 0.015** | 0.634 ± 0.021** | 1.261 ± 0.019**
µg Co/total lung per mg Co/m^3^)
Day 5 | – | 2.395 ± 0.132 | 2.338 ± 0.139 | 2.053 ± 0.043 | 2.061 ± 0.213
Day 12 | – | 3.430 ± 0.038 | 3.673 ± 0.267 | 3.843 ± 0.182 | 3.067 ± 0.145
Day 26 | – | 3.835 ± 0.138 | 4.424 ± 0.100 | 4.397 ± 0.237 | 4.109 ± 0.711^c^
Day 40 | – | 4.094 ± 0.082 | 4.710 ± 0.519 | 5.417 ± 0.237 | 5.142 ± 0.427
Day 61 | – | 4.494 ± 0.310 | 5.210 ± 0.116 | 5.041 ± 0.343 | 5.772 ± 0.154
Day 89 | – | 5.406 ± 0.259 | 5.876 ± 0.363 | 6.399 ± 0.218 | 5.771 ± 0.237
PE day 7 | – | 1.130 ± 0.022 | 1.260 ± 0.036 | 1.246 ± 0.038 | 1.465 ± 0.094
PE day 14 | – | 0.726 ± 0.017 | 0.799 ± 0.017 | 0.742 ± 0.054 | 0.808 ± 0.045
PE day 28 | – | 0.446 ± 0.019 | 0.425 ± 0.021 | 0.403 ± 0.005 | 0.373 ± 0.033
PE day 42 | – | 0.184 ± 0.012 | 0.296 ± 0.012 | 0.254 ± 0.009 | 0.252 ± 0.004

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Values below the limit of detection (LOD) or below the experimental limit of quantitation (ELOQ) were replaced with ½ the LOD or ELOQ value. Statistical tests were performed only on data that were not normalized. PE = postexposure.

^b^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

^c^ n = 2.

Table I-5 Lung Deposition and Clearance Parameter Estimates for Female Rats During the Recovery Period in the Three-month Inhalation Study of Cobalt Metal (Two-Compartment Model)^a^

Parameter | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
A (µg Co/total lung) | 2.69 ± 0.15 | 5.78 ± 0.39 | 13.0 ± 0.69 | 23.4 ± 2.03
A (days^−1^) | 0.39 ± 0.04 | 0.37 ± 0.04 | 0.38 ± 0.03 | 0.27 ± 0.03
t_½ (rapid)_ (days) | 1.78 ± 0.02 | 1.90 ± 0.02 | 1.81 ± 0.01 | 2.59 ± 0.04
B (µg Co/total lung) | 0.65 ± 0.05 | 1.45 ± 0.15 | 2.86 ± 0.23 | 4.95 ± 0.95
b (days^−1^) | 0.030 ± 0.003 | 0.034 ± 0.003 | 0.036 ± 0.003 | 0.033 ± 0.006
t_½ (slow)_ (days) | 23.5 ± 0.2 | 20.6 ± 0.2 | 19.1 ± 0.1 | 20.7 ± 0.6

^a^ Data are presented as mean ± standard error. A = lung burden in the rapid clearance compartment at t = 0 days postexposure; a = rapid phase lung clearance rate constant; t_½(rapid)_ = rapid phase lung clearance rate constant; B = lung burden in the slow clearance compartment at t = 0 days postexposure; b = slow phase lung clearance rate constant; t_½(slow)_ = slow phase lung clearance rate constant.

Table I-6 Lung Deposition and Clearance Parameter Estimates for Female Rats During the Exposure Period in the Three-month Inhalation Study of Cobalt Metal (One-Compartment Model)^a^

Parameter | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
D (µg Co/total lung per day) | 0.40 ± 0.04 | 0.72 ± 0.07 | 1.28 ± 0.10 | 2.06 ± 0.20
k (days^−1^) | 0.15 ± 0.02 | 0.12 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.01
t_½_ (days) | 4.65 ± 0.07 | 5.94 ± 0.08 | 7.23 ± 0.07 | 8.99 ± 0.16
L_ss_ (µg Co/total lung) | 2.7 ± 0.1 | 6.2 ± 0.2 | 13.3 ± 0.5 | 26.8 ± 1.5

^a^ Data are presented as mean ± standard error. D = deposition rate; k = lung clearance rate constant; t_½_ = lung clearance half-life; L_ss_ = steady-state lung burden.

Table I-7 Lung Weights, Cobalt Concentrations, and Cobalt Burdens for Female Rats in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute total lung wt (g)^b^
Day 1 | 0.509 ± 0.023 | 0.632 ± 0.070 | 0.497 ± 0.027 | 0.465 ± 0.012
Day 2 | 0.552 ± 0.037 | 0.523 ± 0.021 | 0.488 ± 0.017 | 0.539 ± 0.016
Day 3 | 0.539 ± 0.035 | 0.567 ± 0.018 | 0.616 ± 0.074 | 0.647 ± 0.027
Day 4 | 0.786 ± 0.091 | 0.877 ± 0.041 | 0.688 ± 0.025 | 0.693 ± 0.018
Day 184 | 1.125 ± 0.237 | 1.468 ± 0.064 | 1.682 ± 0.075* | 1.693 ± 0.030*
Day 366 | 1.039 ± 0.025 | 1.801 ± 0.064** | 2.103 ± 0.066** | 2.333 ± 0.070**
Day 548 | 1.279 ± 0.039 | 2.678 ± 0.187** | 2.691 ± 0.145*^c^ | 3.815 ± 0.323**
µg Co/g total lung
Day 1 | 0.040 ± 0.000 | 2.797 ± 0.393** | 6.028 ± 0.400** | 16.152 ± 0.466**
Day 2 | 0.040 ± 0.000 | 4.603 ± 0.219** | 8.987 ± 0.045** | 12.662 ± 0.865**
Day 3 | 0.040 ± 0.000 | 5.474 ± 0.237** | 8.177 ± 0.735** | 13.511 ± 0.853**
Day 4 | 0.040 ± 0.000 | 3.804 ± 0.232** | 7.338 ± 0.393** | 18.406 ± 1.266**
Day 184 | 0.040 ± 0.000 | 5.685 ± 0.126** | 11.238 ± 0.592** | 21.670 ± 0.606**
Day 366 | 0.040 ± 0.000 | 5.251 ± 0.058** | 10.748 ± 0.351** | 18.491 ± 0.401**
Day 548 | 0.052 ± 0.012 | 5.113 ± 0.400** | 10.108 ± 0.532**^c^ | 13.248 ± 0.567**
µg Co/total lung
Day 1 | 0.020 ± 0.001 | 1.663 ± 0.081** | 2.962 ± 0.114** | 7.505 ± 0.253**
Day 2 | 0.022 ± 0.001 | 2.404 ± 0.136** | 4.382 ± 0.154** | 6.792 ± 0.379**
Day 3 | 0.022 ± 0.001 | 3.103 ± 0.165** | 4.829 ± 0.147** | 8.705 ± 0.522**
Day 4 | 0.031 ± 0.004 | 3.306 ± 0.137** | 5.018 ± 0.124** | 12.780 ± 1.038**
Day 184 | 0.045 ± 0.009 | 8.327 ± 0.279** | 18.758 ± 0.484** | 36.678 ± 1.061**
Day 366 | 0.042 ± 0.001 | 9.454 ± 0.309** | 22.578 ± 0.923** | 43.068 ± 0.985**
Day 548 | 0.067 ± 0.016 | 13.419 ± 0.454** | 26.998 ± 0.677**^c^ | 49.954 ± 2.876**
µg Co/total lung per mg Co/m^3^)
Day 1 | – | 1.330 ± 0.065 | 1.185 ± 0.046 | 1.501 ± 0.051
Day 2 | – | 1.923 ± 0.109 | 1.753 ± 0.062 | 1.358 ± 0.076
Day 3 | – | 2.482 ± 0.132 | 1.932 ± 0.059 | 1.741 ± 0.104
Day 4 | – | 2.645 ± 0.110 | 2.007 ± 0.050 | 2.556 ± 0.208
Day 184 | – | 6.662 ± 0.223 | 7.503 ± 0.194 | 7.336 ± 0.212
Day 366 | – | 7.563 ± 0.247 | 9.031 ± 0.369 | 8.614 ± 0.197
Day 548 | – | 10.735 ± 0.363 | 10.799 ± 0.271^c^ | 9.991 ± 0.575

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Values below the limit of detection (LOD) or below the experimental limit of quantitation (ELOQ) were replaced with ½ the LOD or ELOQ value. Statistical tests were performed only on data that were not normalized.

^b^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

^c^ n = 4.

Table I-8 Lung Deposition and Clearance Parameter Estimates for Female Rats During the Exposure Periods in the Three-month and Two-year Inhalation Studies of Cobalt Metal (Two-Compartment Model)^a^

Parameter | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
A (µg Co/day) | 1.449 ± 0.112 | 2.128 ± 0.158 | 5.555 ± 0.832
k_a_ (days^−1^) | 0.293 ± 0.035 | 0.236 ± 0.032 | 0.453 ± 0.114
B (µg Co/day) | 0.0179 ± 0.0043 | 0.0778 ± 0.0156 | 0.2885 ± 0.0530
k_b_ (days^−1^) | 0.00088 ± 0.00097 | 0.00414 ± 0.00110 | 0.00837 ± 0.00156
F_B_ | 0.012 ± 0.003 | 0.035 ± 0.007 | 0.049 ± 0.008
t_½a_ (days) | 2.37 ± 0.28 | 2.94 ± 0.39 | 1.53 ± 0.38
L_SSa_ (µg Co/total lung) | 4.95 ± 0.30 | 9.02 ± 0.75 | 12.25 ± 1.55
t_½b_ (days) | 789 ± 874 | 167 ± 45 | 83 ± 15
L_SSb_ (µg Co/total lung) | 20.4 ± 18.0 | 18.8 ± 1.8 | 34.5 ± 2.1

^a^ Data are presented as mean ± standard error. A = deposition rate in the rapid phase; k_a_ = rapid phase clearance rate constant; B = deposition rate in the slow phase; k_b_ = slow phase clearance rate constant; F_B_ = fraction of deposition in the slow clearance phase; t_½a_ = half-life of the rapid clearance phase; L_SSa_ = theoretical steady-state lung burden for the rapid phase; t_½b_ = half-life of the slow clearance phase; L_SSb_ = theoretical steady-state lung burden for the slow phase.

Table I-9 Tissue Weights, Cobalt Concentrations, and Cobalt Burdens for Mice in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
Male
n | 5 | 5 | 5 | 5 | 5 | 2
Blood
µg Co/g blood
Day 17 | 0^b^ | 0.40 ± 0.04 | 0.74 ± 0.06 | 0.65 ± 0.03 | 1.44 ± 0.22 | 2.53 ± 0.13
Serum
µg Co/g serum
Day 17 | 0 | 0.63 ± 0.06 | 1.38 ± 0.12 | 1.31 ± 0.04 | 2.72 ± 0.38 | 4.94 ± 0.03
Right femur
Absolute right femur wt (g)
Day 17 | 0.025 ± 0.001 | 0.026 ± 0.001 | 0.025 ± 0.001 | 0.025 ± 0.001 | 0.024 ± 0.001 | 0.021 ± 0.001
µg Co/g right femur
Day 17 | 0 | 0.42 ± 0.10 | 0.56 ± 0.06 | 1.13 ± 0.15 | 1.65 ± 0.23 | 2.78 ± 0.24
µg Co/right femur
Day 17 | 0 | 0.011 ± 0.002 | 0.014 ± 0.001 | 0.029 ± 0.003 | 0.039 ± 0.005 | 0.057 ± 0.007
µg Co/right femur per mg Co/m^3^
Day 17 | NA | 0.004 ± 0.001 | 0.003 ± 0.000 | 0.003 ± 0.000 | 0.002 ± 0.000 | 0.001 ± 0.000
Heart
Absolute heart wt (g)
Day 17 | 0.125 ± 0.005 | 0.127 ± 0.003 | 0.124 ± 0.003 | 0.120 ± 0.004 | 0.110 ± 0.003* | 0.106 ± 0.007*
µg Co/g heart
Day 17 | 0 | 0.39 ± 0.09 | 0.98 ± 0.20 | 0.95 ± 0.13 | 1.65 ± 0.21 | 6.45 ± 2.77
µg Co/heart
Day 17 | 0 | 0.050 ± 0.011 | 0.123 ± 0.028 | 0.112 ± 0.014 | 0.178 ± 0.018 | 0.700 ± 0.340
µg Co/heart per mg Co/m^3^
Day 17 | NA | 0.020 ± 0.004 | 0.025 ± 0.006 | 0.011 ± 0.001 | 0.009 ± 0.001 | 0.017 ± 0.008
Right kidney
Absolute right kidney wt (g)
Day 17 | 0.223 ± 0.009 | 0.216 ± 0.011 | 0.197 ± 0.005 | 0.199 ± 0.007 | 0.171 ± 0.003** | 0.150 ± 0.003**
µg Co/g right kidney
Day 17 | 0 | 0.91 ± 0.06 | 1.86 ± 0.12 | 2.02 ± 0.06 | 3.82 ± 0.35 | 4.97 ± 1.76
µg Co/right kidney
Day 17 | 0 | 0.197 ± 0.019 | 0.360 ± 0.019 | 0.396 ± 0.018 | 0.642 ± 0.058 | 0.737 ± 0.279
µg Co/right kidney per mg Co/m^3^
Day 17 | NA | 0.079 ± 0.007 | 0.072 ± 0.004 | 0.040 ± 0.002 | 0.032 ± 0.003 | 0.018 ± 0.007
Liver
Absolute liver wt (g)
Day 17 | 1.127 ± 0.037 | 0.978 ± 0.035* | 0.976 ± 0.037* | 0.993 ± 0.018* | 0.888 ± 0.019** | 0.830 ± 0.013**
µg Co/g liver
Day 17 | 0 | 1.72 ± 0.13 | 4.79 ± 0.70 | 4.55 ± 0.41 | 12.84 ± 2.07 | 33.73 ± 2.79
µg Co/liver
Day 17 | 0 | 1.669 ± 0.138 | 4.566 ± 0.512 | 4.516 ± 0.437 | 11.370 ± 1.836 | 28.007 ± 2.751
µg Co/liver per mg Co/m^3^
Day 17 | NA | 0.668 ± 0.055 | 0.913 ± 0.102 | 0.452 ± 0.044 | 0.568 ± 0.092 | 0.700 ± 0.069
Total lung^c^
Absolute total lung wt (g)
Day 17 | 0.182 ± 0.007 | 0.210 ± 0.009* | 0.225 ± 0.009** | 0.244 ± 0.014** | 0.295 ± 0.007** | 0.360 ± 0.050**
µg Co/total lung
Day 17 | 0 | 5.587 ± 0.473 | 10.451 ± 0.448 | 16.403 ± 0.980 | 20.356 ± 0.666 | 28.931 ± 11.814
µg Co/total lung per mg Co/m^3^
Day 17 | NA | 2.235 ± 0.189 | 2.090 ± 0.090 | 1.640 ± 0.098 | 1.018 ± 0.033 | 0.723 ± 0.295
Right lung^d^
Absolute right lung wt (g)
Day 17 | 0.078 ± 0.006 | 0.097 ± 0.002 | 0.110 ± 0.003 | 0.117 ± 0.004 | 0.152 ± 0.005 | 0.199 ± 0.031**
µg Co/g right lung
Day 17 | 0 | 26.49 ± 1.37 | 46.36 ± 67.26 | 67.26 ± 1.13 | 69.14 ± 2.93 | 86.50 ± 44.86
µg Co/right lung
Day 17 | – | 0.942 ± 0.048 | 0.988 ± 0.048 | 0.730 ± 0.151 | 0.442 | –^e^
µg Co/right lung per mg Co/m^3^
Day 17 | NA | 0.523 ± 0.012 | 0.590 ± 0.006 | 0.455 ± 0.002 | 0.309 | –
Right testis
Absolute right testis wt (g)
Day 17 | 0.098 ± 0.004 | 0.100 ± 0.002 | 0.098 ± 0.002 | 0.097 ± 0.002 | 0.088 ± 0.002* | 0.076 ± 0.005*
µg Co/g right testis
Day 17 | 0 | 0.06 ± 0.01 | 0.15 ± 0.01 | 0.34 ± 0.08 | 0.58 ± 0.06 | 1.20 ± 0.03
µg Co/right testis
Day 17 | 0 | 0.005 ± 0.001 | 0.014 ± 0.001 | 0.033 ± 0.009 | 0.051 ± 0.005 | 0.090 ± 0.008
µg Co/right testis per mg Co/m^3^
Day 17 | NA | 0.002 ± 0.000 | 0.003 ± 0.000 | 0.003 ± 0.001 | 0.003 ± 0.000 | 0.002 ± 0.000
Female
n
Day 17 | 5 | 5 | 5 | 5 | 5 | 2
Week 3 PE | 3 | 3 | 3 | 3 | 3 | 1^b^
Blood
µg Co/g blood
Day 17 | 0^g^ | 0.47 ± 0.06^f^ | 0.78 ± 0.08^f^ | 0.97 ± 0.10^f^ | 2.01 ± 0.13^g^ | 2.52 ± 0.88
Week 3 PE | 0 | 0.06 ± 0.02 | 0.07 ± 0.05 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.13
Serum
µg Co/g serum
Day 17 | 0^g^ | 0.99 ± 0.13^f^ | 1.52 ± 0.18^f^ | 1.83 ± 0.20^f^ | 3.92 ± 0.28^g^ | 5.10 ± 1.57
Week 3 PE | 0 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.03 ± 0.01 | 0.07
Right femur
Absolute right femur wt (g)
Day 17 | 0.024 ± 0.001 | 0.025 ± 0.000 | 0.025 ± 0.001 | 0.023 ± 0.001 | 0.020 ± 0.001* | 0.018 ± 0.001*
µg Co/g right femur
Day 17 | 0 | 0.71 ± 0.05 | 1.24 ± 0.10 | 1.80 ± 0.14 | 3.03 ± 0.29 | 3.92 ± 1.07
µg Co/right femur
Day 17 | 0 | 0.019 ± 0.001 | 0.030 ± 0.002 | 0.041 ± 0.003 | 0.058 ± 0.009 | 0.065 ± 0.016
µg Co/right femur per mg Co/m^3^
Day 17 | NA | 0.007 ± 0.001 | 0.006 ± 0.000 | 0.004 ± 0.000 | 0.003 ± 0.000 | 0.002 ± 0.000
Heart
Absolute heart wt (g)
Day 17 | 0.111 ± 0.002 | 0.110 ± 0.003 | 0.112 ± 0.001 | 0.100 ± 0.002 | 0.097 ± 0.005 | 0.099 ± 0.004
µg Co/g heart
Day 17 | 0 | 0.70 ± 0.12 | 0.99 ± 0.08 | 1.33 ± 0.12 | 2.53 ± 0.13 | 3.26 ± 1.11
µg Co/heart
Day 17 | 0 | 0.076 ± 0.012 | 0.111 ± 0.009 | 0.131 ± 0.009 | 0.243 ± 0.012 | 0.316 ± 0.097
µg Co/heart per mg Co/m^3^
Day 17 | NA | 0.030 ± 0.005 | 0.02 ± 0.002 | 0.013 ± 0.001 | 0.012 ± 0.001 | 0.008 ± 0.002
Right kidney
Absolute right kidney wt (g)
Day 17 | 0.151 ± 0.002 | 0.147 ± 0.004 | 0.142 ± 0.005 | 0.132 ± 0.004** | 0.113 ± 0.003** | 0.098 ± 0.006**
µg Co/g right kidney
Day 17 | 0 | 1.44 ± 0.15 | 2.08 ± 0.17 | 2.76 ± 0.16 | 5.45 ± 0.32 | 8.63 ± 0.69
µg Co/right kidney
Day 17 | 0 | 0.213 ± 0.028 | 0.291 ± 0.017 | 0.355 ± 0.015 | 0.600 ± 0.028 | 0.826 ± 0.117
µg Co/right kidney per mg Co/m^3^
Day 17 | NA | 0.085 ± 0.011 | 0.058 ± 0.003 | 0.035 ± 0.001 | 0.030 ± 0.001 | 0.021 ± 0.003
Liver
Absolute liver wt (g)
Day 17 | 0.928 ± 0.026 | 0.814 ± 0.021* | 0.799 ± 0.029* | 0.748 ± 0.030** | 0.692 ± 0.026** | 0.605 ± 0.057**
µg Co/g liver
Day 17 | 0 | 2.74 ± 0.28 | 4.94 ± 0.63 | 7.21 ± 0.74 | 21.98 ± 1.62 | 35.83 ± 5.10
µg Co/liver
Day 17 | 0 | 2.213 ± 0.229 | 3.884 ± 0.426 | 5.329 ± 0.474 | 15.155 ± 1.123 | 21.941 ± 5.131
µg Co/liver per mg Co/m^3^
Day 17 | NA | 0.885 ± 0.092 | 0.777 ± 0.085 | 0.533 ± 0.047 | 0.758 ± 0.056 | 0.549 ± 0.128
Total lung^c^
Absolute total lung wt (g)
Day 17 | 0.189 ± 0.007^e^ | 0.194 ± 0.004^e^ | 0.223 ± 0.006**^f^ | 0.234 ± 0.006**^f^ | 0.290 ± 0.010**^g^ | 0.329 ± 0.020**
Week 3 PE | 0.18 ± 0.01 | 0.16 ± 0.01 | 0.19 ± 0.02 | 0.18 ± 0.01 | 0.24 ± 0.03 | 0.20
µg Co/total lung
Day 17 | 0^f^ | 4.511 ± 0.159^f^ | 9.630 ± 0.327^f^ | 14.495 ± 0.855^f^ | 16.303 ± 0.843^g^ | 8.205 ± 4.106
Week 3 PE | 0 | 0.483 ± 0.029 | 0.947 ± 0.112 | 1.484 ± 0.187 | 1.123 ± 0.144 | 1.927
µg Co/total lung per mg Co/m^3^
Day 17 | 0^f^ | 1.804 ± 0.064^f^ | 1.926 ± 0.065^f^ | 1.450 ± 0.085^f^ | 0.815 ± 0.042^g^ | 0.205 ± 0.103
Week 3 PE | 0 | 0.193 ± 0.012 | 0.189 ± 0.022 | 0.148 ± 0.019 | 0.056 ± 0.007 | 0.048
Left lung^g^
Absolute left lung wt (g)
Day 17 | 0.103 ± 0.006^i^ | 0.088 ± 0.004^i^ | 0.091 ± 0.006^i^ | 0.099 ± 0.002^i^ | 0.113^b^ | –
Week 3 PE | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.00 | 0.07 ± 0.01* | 0.06
µg Co/g left lung
Day 17 | NA^h^ | 14.88 ± 0.34^i^ | 32.72 ± 2.34^i^ | 45.98 ± 1.16^i^ | 54.72^b^ | –
Week 3 PE | NA | 3.05 ± 0.06 | 5.66 ± 0.49 | 8.00 ± 0.20 | 5.75 ± 1.06 | 9.71
µg Co/left lung
Day 17 | NA^h^ | 1.308 ± 0.030^i^ | 2.949 ± 0.032^i^ | 4.550 ± 0.024^i^ | 6.183^b^ | –
Week 3 PE | NA | 0.123 ± 0.004 | 0.246 ± 0.030 | 0.360 ± 0.017 | 0.365 ± 0.028 | 0.566
µg Co/left lung per mg Co/m^3^
Day 17 | NA^h^ | 0.523 ± 0.012^i^ | 0.590 ± 0.006^i^ | 0.455 ± 0.002^i^ | 0.309^b^ | –
Week 3 PE | NA | 0.049 ± 0.002 | 0.049 ± 0.006 | 0.036 ± 0.002 | 0.018 ± 0.001 | 0.014
Right lung^d^
Absolute right lung wt (g)
Day 17 | 0.090 ± 0.005^f^ | 0.098 ± 0.002^f^ | 0.112± 0.003**^f^ | 0.120 ± 0.004**^f^ | 0.159 ± 002**^g^ | 0.186 ± 0.006
Week 3 PE | 0.09 ± 0.00 | 0.08 ± 0.00 | 0.09 ± 0.00 | 0.09 ± 0.00 | 0.12 ± 0.01* | 0.11
µg Co/g right lung
Day 17 | NA^f^ | 23.28 ± 0.86^f^ | 43.24 ± 1.18^f^ | 61.99 ± 3.66^f^ | 56.24 ± 2.78^g^ | 24.28 ± 11.05
Week 3 PE | NA | 3.10 ± 0.03 | 5.04 ± 0.15 | 8.06 ± 0.48 | 4.99 ± 1.14 | 9.68
µg Co/right lung
Day 17 | NA^h^ | 2.356 ± 0.120i | 4.939 ± 0.241^i^ | 7.303 ± 1.512^i^ | 8.848^b^ | NA
Week 3 PE | NA | 0.253 ± 0.014 | 0.473 ± 0.036 | 0.751 ± 0.053 | 0.553 ± 0.086 | 1.017
µg Co/right lung per mg Co/m^3^
Day 17 | NA^i^ | 0.942 ± 0.048^i^ | 0.988 ± 0.048^i^ | 0.730 ± 0.151^h^ | 0.442^b^ | NA
Week 3 PE | NA | 0.101 ± 0.005 | 0.095 ± 0.007 | 0.075 ± 0.005 | 0.028 ± 0.004 | 0.025

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. All values except absolute tissue weights are control corrected. Statistical tests were performed only on absolute tissue weight data. NA = not applicable; PE = postexposure.

^b^ n = 1; No standard error was calculated; less than two measurements were available.

^c^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

^d^ Right lung cobalt burden was calculated using the right lung weight and the concentration of cobalt measured in the right lung.

^e^ No data are available.

^f^ n = 7.

^g^ n =6.

^h^ Left lung cobalt burden was calculated using the left lung weight and the concentration of cobalt measured in the left lung.

^i^ n = 2.

Table I-10 Deposition and Clearance Parameter Estimates for Female Mice in the Two-week Inhalation Study of Cobalt Metal^a^

Tissue | Exposure Concentration (mg/m^3^) | k (days^−1^) | t_½_ (days) | α (µg Co/day) | A_e_ (µg Co)
Blood | 2.5 | 0.10 | 7.26 | NA | NA
Blood | 5 | 0.11 | 6.19 | NA | NA
Blood | 10 | 0.14 | 4.81 | NA | NA
Blood | 20 | 0.17 | 4.11 | NA | NA
Serum | 2.5 | 0.19 | 3.71 | NA | NA
Serum | 5 | 0.24 | 2.89 | NA | NA
Serum | 10 | 0.22 | 3.22 | NA | NA
Serum | 20 | 0.22 | 3.17 | NA | NA
Lung^b^ | 2.5 | 0.11 | 6.57 | 0.57 | 5.44
Lung^b^ | 5 | 0.11 | 6.30 | 1.25 | 11.41
Lung^b^ | 10 | 0.11 | 6.40 | 1.87 | 17.26
Lung^b^ | 20 | 0.13 | 5.46 | 2.34 | 18.45

^a^ Statistical analyses of these data were not performed due to the limited number of time points and data points within some time points. k = first order clearance rate constant; t_1/2_ = clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden; NA = not applicable.

^b^ Total lung cobalt burden was calculated using the weight of total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

Table I-11 Tissue Weights, Cobalt Concentrations, and Cobalt Burdens for Female Mice in the Three-month Inhalation Study of Cobalt Metal^a^

Parameter | Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
n | 3 | 3 | 3 | 3 | 3 | 3
Blood
µg Co/g blood
Day 5 | 0.009 ± 0.000 | 0.056 ± 0.015* | 0.154 ± 0.030** | 0.412 ± 0.087** | 0.857 ± 0.114** | 1.073 ± 0.029**
Day 12 | 0.009 ± 0.000 | 0.134 ± 0.012* | 0.250 ± 0.045** | 0.352 ± 0.025** | 0.949 ± 0.078** | 1.540 ± 0.097**
Day 26 | 0.009 ± 0.000 | 0.077 ± 0.010* | 0.154 ± 0.011** | 0.421 ± 0.023** | 0.874 ± 0.113** | 1.634 ± 0.169**
Day 40 | 0.009 ± 0.000 | 0.155 ± 0.014* | 0.263 ± 0.036** | 0.520 ± 0.026** | 0.941 ± 0.119** | 1.619 ± 0.053**
Day 61 | 0.009 ± 0.000 | 0.111 ± 0.028* | 0.188 ± 0.008** | 0.359 ± 0.046** | 0.916 ± 0.071** | 2.576 ± 0.944**
Day 89 | 0.009 ± 0.000 | 0.093 ± 0.013* | 0.155 ± 0.007** | 0.308 ± 0.008** | 0.660 ± 0.035** | 1.257 ± 0.088**
PE day 7 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.014 ± 0.005 | 0.025 ± 0.000* | 0.063 ± 0.004** | 0.115 ± 0.002**
PE day 14 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.025 ± 0.000** | 0.069 ± 0.008**
PE day 28 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.025 ± 0.000**
PE day 42 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000 | 0.009 ± 0.000
µg Co/g blood per mg Co/m^3^
Day 5 | – | 0.089 ± 0.025 | 0.123 ± 0.024 | 0.165 ± 0.035 | 0.171 ± 0.023 | 0.107 ± 0.003
Day 12 | – | 0.214 ± 0.019 | 0.200 ± 0.036 | 0.141 ± 0.010 | 0.190 ± 0.016 | 0.154 ± 0.010
Day 26 | – | 0.123 ± 0.016 | 0.123 ± 0.009 | 0.168 ± 0.009 | 0.175 ± 0.023 | 0.163 ± 0.017
Day 40 | – | 0.248 ± 0.023 | 0.211 ± 0.029 | 0.208 ± 0.010 | 0.188 ± 0.024 | 0.162 ± 0.005
Day 61 | – | 0.178 ± 0.045 | 0.151 ± 0.006 | 0.144 ± 0.019 | 0.183 ± 0.014 | 0.258 ± 0.094
Day 89 | – | 0.149 ± 0.020 | 0.124 ± 0.006 | 0.123 ± 0.003 | 0.132 ± 0.007 | 0.126 ± 0.009
PE day 7 | – | 0.014 ± 0.000 | 0.011 ± 0.004 | 0.010 ± 0.000 | 0.013 ± 0.001 | 0.011 ± 0.000
PE day 14 | – | 0.014 ± 0.000 | 0.007 ± 0.000 | 0.004 ± 0.000 | 0.005 ± 0.000 | 0.007 ± 0.001
PE day 28 | – | 0.014 ± 0.000 | 0.007 ± 0.000 | 0.004 ± 0.000 | 0.002 ± 0.000 | 0.003 ± 0.000
PE day 42 | – | 0.014 ± 0.000 | 0.007 ± 0.000 | 0.004 ± 0.000 | 0.002 ± 0.000 | 0.001 ± 0.000
Liver
Absolute liver wt (g)
Day 26 | 0.969 ± 0.055` | 0.970 ± 0.024 | 0.902 ± 0.019 | 0.873 ± 0.056 | 0.813 ± 0.031* | 0.754 ± 0.022*
Day 40 | 1.011 ± 0.011 | 1.046 ± 0.021 | 1.082 ± 0.008 | 0.989 ± 0.032 | 0.880 ± 0.052 | 0.802 ± 0.019
µg Co/g liver
Day 26 | 0.220 ± 0.000 | 0.500 ± 0.000* | 0.956 ± 0.240** | 2.494 ± 0.247** | 5.768 ± 0.593** | 12.002 ± 1.095**
Day 40 | 0.220 ± 0.000^b^ | 0.722 ± 0.222 | 1.808 ± 0.289* | 3.307 ± 0.101** | 6.676 ± 1.189** | 11.583 ± 0.434**
µg Co/liver
Day 26 | 0.213 ± 0.012 | 0.485 ± 0.012* | 0.866 ± 0.220* | 2.157 ± 0.149** | 4.699 ± 0.538** | 9.065 ± 0.943**
Day 40 | 0.222 ± 0.004^b^ | 0.747 ± 0.214 | 1.952 ± 0.297* | 3.263 ± 0.022** | 5.963 ± 1.311** | 9.310 ± 0.560**
µg Co/liver per mg Co/m^3^
Day 26 | – | 0.776 ± 0.019 | 0.693 ± 0.176 | 0.863 ± 0.060 | 0.940 ± 0.108 | 0.906 ± 0.094
Day 40 | – | 1.195 ± 0.343 | 1.561 ± 0.237 | 1.305 ± 0.009 | 1.193 ± 0.262 | 0.931 ± 0.056
Total lung^c^
Absolute total lung wt (g)
Day 5 | 0.144 ± 0.006 | 0.138 ± 0.012 | 0.151 ± 0.007 | 0.158 ± 0.007 | 0.167 ± 0.011 | 0.178 ± 0.023
Day 12 | 0.144 ± 0.005 | 0.158 ± 0.010 | 0.168 ± 0.015 | 0.177 ± 0.012* | 0.200 ± 0.006** | 0.238 ± 0.023**
Day 26 | 0.145 ± 0.006 | 0.157 ± 0.002 | 0.163 ± 0.009 | 0.169 ± 0.008 | 0.203 ± 0.014** | 0.251 ± 0.015**
Day 40 | 0.168 ± 0.008 | 0.165 ± 0.007 | 0.183 ± 0.006 | 0.191 ± 0.002* | 0.247 ± 0.015** | 0.259 ± 0.006**
Day 61 | 0.188 ± 0.023 | 0.170 ± 0.002 | 0.227 ± 0.025 | 0.189 ± 0.003 | 0.255 ± 0.005* | 0.279 ± 0.015*
Day 89 | 0.189 ± 0.022 | 0.187 ± 0.006 | 0.197 ± 0.002 | 0.206 ± 0.003 | 0.260 ± 0.010* | 0.300 ± 0.014**
PE day 7 | 0.174 ± 0.015 | 0.178 ± 0.013 | 0.203 ± 0.019 | 0.201 ± 0.019 | 0.237 ± 0.014* | 0.289 ± 0.014**
PE day 14 | 0.176 ± 0.011 | 0.186 ± 0.009 | 0.190 ± 0.006 | 0.183 ± 0.004 | 0.209 ± 0.009* | 0.249 ± 0.016**
PE day 28 | 0.174 ± 0.008 | 0.192 ± 0.013 | 0.168 ± 0.006 | 0.184 ± 0.010 | 0.184 ± 0.007 | 0.209 ± 0.006
PE day 42 | 0.169 ± 0.002 | 0.169 ± 0.005 | 0.181 ± 0.007 | 0.178 ± 0.002* | 0.196 ± 0.005** | 0.213 ± 0.014**
µg Co/g total lung
Day 5 | 0.200 ± 0.000 | 5.920 ± 0.456* | 10.292 ± 0.874** | 20.877 ± 1.371** | 28.959 ± 2.874** | 15.697 ± 2.720**
Day 12 | 0.200 ± 0.000 | 6.770 ± 0.817* | 12.310 ± 1.396** | 22.624 ± 1.973** | 46.133 ± 3.142** | 47.334 ± 19.444**
Day 26 | 0.200 ± 0.000^b^ | 5.505 ± 0.313 | 12.957 ± 1.029* | 27.070 ± 0.926** | 72.553 ± 3.071** | 109.153 ± 3.027**
Day 40 | 0.200 ± 0.000 | 7.038 ± 0.531* | 16.986 ± 0.344** | 28.659 ± 1.896** | 85.895 ± 5.226** | 141.694 ± 2.904**
Day 61 | 0.200 ± 0.000 | 6.517 ± 0.412* | 12.891 ± 1.662** | 32.787 ± 2.120** | 77.234 ± 6.030** | 143.304 ± 6.747**
Day 89 | 0.200 ± 0.000 | 6.944 ± 0.431* | 18.504 ± 1.996** | 39.129 ± 0.956** | 108.420 ± 3.413** | 141.003 ± 5.456**
PE day 7 | 0.200 ± 0.000 | 2.342 ± 0.041* | 6.392 ± 0.619** | 17.275 ± 2.533** | 44.664 ± 1.910** | 65.663 ± 3.483**
PE day 14 | 0.200 ± 0.000 | 1.565 ± 0.160* | 5.147 ± 0.114** | 15.226 ± 0.822** | 42.632 ± 3.321** | 48.445 ± 4.201**
PE day 28 | 0.200 ± 0.000 | 0.670 ± 0.170* | 3.548 ± 0.174** | 9.758 ± 0.484** | 30.466 ± 0.878** | 42.285 ± 1.482**
PE day 42 | 0.200 ± 0.000 | 0.500 ± 0.000* | 2.762 ± 0.027** | 7.583 ± 0.446** | 24.409 ± 1.234** | 31.551 ± 2.958**
µg Co/total lung
Day 5 | 0.029 ± 0.001 | 0.809 ± 0.050* | 1.539 ± 0.072** | 3.273 ± 0.100** | 4.791 ± 0.286** | 2.671 ± 0.206**
Day 12 | 0.029 ± 0.001 | 1.051 ± 0.054* | 2.031 ± 0.080** | 3.996 ± 0.460** | 9.219 ± 0.537** | 10.431 ± 3.867**
Day 26 | 0.030 ± 0.001^b^ | 0.864 ± 0.044 | 2.094 ± 0.060* | 4.561 ± 0.054** | 14.723 ± 1.257** | 27.397 ± 1.454**
Day 40 | 0.034 ± 0.002 | 1.154 ± 0.071* | 3.110 ± 0.141** | 5.479 ± 0.334** | 21.033 ± 0.324** | 36.623 ± 0.529**
Day 61 | 0.038 ± 0.005 | 1.104 ± 0.060* | 2.849 ± 0.109** | 6.193 ± 0.388** | 19.777 ± 1.877** | 39.990 ± 2.606**
Day 89 | 0.038 ± 0.004 | 1.293 ± 0.067* | 3.644 ± 0.413** | 8.070 ± 0.150** | 28.293 ± 1.946** | 42.263 ± 1.680**
PE day 7 | 0.035 ± 0.003 | 0.417 ± 0.033* | 1.274 ± 0.012** | 3.384 ± 0.327** | 10.517 ± 0.251** | 18.903 ± 0.681**
PE day 14 | 0.035 ± 0.002 | 0.290 ± 0.030* | 0.977 ± 0.051** | 2.798 ± 0.207** | 8.857 ± 0.430** | 11.943 ± 0.455**
PE day 28 | 0.035 ± 0.002 | 0.126 ± 0.026* | 0.598 ± 0.050** | 1.801 ± 0.150** | 5.594 ± 0.064** | 8.864 ± 0.515**
PE day 42 | 0.034 ± 0.000 | 0.085 ± 0.003* | 0.499 ± 0.015** | 1.347 ± 0.079** | 4.765 ± 0.137** | 6.678 ± 0.517**
µg Co/total lung per mg Co/m^3^
Day 5 | – | 1.294 ± 0.080 | 1.231 ± 0.058 | 1.309 ± 0.040 | 0.958 ± 0.057 | 0.267 ± 0.021
Day 12 | – | 1.682 ± 0.086 | 1.625 ± 0.064 | 1.599 ± 0.184 | 1.844 ± 0.107 | 1.043 ± 0.387
Day 26 | – | 1.382 ± 0.070 | 1.675 ± 0.048 | 1.824 ± 0.022 | 2.945 ± 0.251 | 2.740 ± 0.145
Day 40 | – | 1.847 ± 0.114 | 2.488 ± 0.112 | 2.191 ± 0.134 | 4.207 ± 0.065 | 3.662 ± 0.053
Day 61 | – | 1.767 ± 0.096 | 2.279 ± 0.087 | 2.477 ± 0.155 | 3.955 ± 0.375 | 3.999 ± 0.261
Day 89 | – | 2.069 ± 0.106 | 2.915 ± 0.330 | 3.228 ± 0.060 | 5.659 ± 0.389 | 4.226 ± 0.168
PE day 7 | – | 0.667 ± 0.052 | 1.019 ± 0.010 | 1.354 ± 0.131 | 2.103 ± 0.050 | 1.890 ± 0.068
PE day 14 | – | 0.464 ± 0.048 | 0.782 ± 0.041 | 1.119 ± 0.083 | 1.771 ± 0.086 | 1.194 ± 0.046
PE day 28 | – | 0.201 ± 0.042 | 0.478 ± 0.040 | 0.721 ± 0.060 | 1.119 ± 0.013 | 0.886 ± 0.051
PE day 42 | – | 0.135 ± 0.004 | 0.399 ± 0.012 | 0.539 ± 0.032 | 0.953 ± 0.027 | 0.668 ± 0.052

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Values below the limit of detection (LOD) or below the experimental limit of quantitation (ELOQ) were replaced with ½ the LOD or ELOQ value. Statistical tests were performed only on data that were not normalized. PE = postexposure.

^b^ n = 2.

^c^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

Table I-12 Lung Deposition and Clearance Parameter Estimates for Female Mice During the Recovery Period in the Three-month Inhalation Study of Cobalt Metal (Two-Compartment Model)^a^

Parameter | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
A (µg Co/total lung) | 0.947 ± 0.124 | 2.302 ± 0.341 | 4.283 ± 0.736 | 16.746 ± 1.876 | 28.342 ± 3.014
A (days^−1^) | 0.271 ± 0.060 | 0.268 ± 0.073 | 0.509 ± 0.454 | 0.381 ± 0.119 | 0.215 ± 0.042
t_½ (rapid)_ (days) | 2.556 ± 0.127 | 2.592 ± 0.194 | 1.361 ± 1.080 | 1.818 ± 0.177 | 3.225 ± 0.123
B (µg Co/total lung) | 0.324 ± 0.070 | 1.103 ± 0.222 | 3.776 ± 0.458 | 10.933 ± 1.141 | 13.811 ± 2.331
b (days^−1^) | 0.022 ± 0.006 | 0.020 ± 0.006 | 0.026 ± 0.004 | 0.021 ± 0.003 | 0.018 ± 0.005
t_½ (slow)_ (days) | 30.88 ± 2.56 | 34.66 ± 3.11 | 27.08 ± 0.64 | 33.01 ± 0.82 | 39.33 ± 2.80

^a^ Data are presented as mean ± standard error. A = lung burden in the rapid clearance compartment at t = 0 days postexposure; a = rapid phase lung clearance rate constant; t_½(rapid)_ = rapid phase lung clearance rate constant; B = lung burden in the slow clearance compartment at t = 0 days postexposure; b = slow phase lung clearance rate constant; t_½(slow)_ = slow phase lung clearance rate constant.

Table I-13 Lung Deposition and Clearance Parameter Estimates for Female Mice During the Exposure Period in the Three-month Inhalation Study of Cobalt Metal (One-Compartment Model)^a^

Parameter | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
D (µg Co/total lung per day) | 0.301 ± 0.062 | 0.381 ± 0.061 | 0.737 ± 0.129 | 0.971 ± 0.076 | 0.710 ± 0.094
k (days^−1^) | 0.287 ± 0.065 | 0.141 ± 0.027 | 0.132 ± 0.028 | 0.041 ± 0.006 | 0.006 ± 0.005
t_½_ (days) | 2.412 ± 0.122 | 4.903 ± 0.183 | 5.249 ± 0.235 | 16.996 ± 0.321 | 121.975 ± 104.527
L_ss_ (µg Co/total lung) | 1.048 ± 0.045 | 2.691 ± 0.162 | 5.578 ± 0.375 | 23.810 ± 1.853 | 124.948 ± 103.207

^a^ Data are presented as mean ± standard error. D = deposition rate; k = lung clearance rate constant; t_½_ = lung clearance half-life; L_ss_ = steady-state lung burden.

Table I-14 Lung Weights, Cobalt Concentrations, and Cobalt Burdens for Female Mice in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute total lung wt (g)^b^
Day 1 | 0.130 ± 0.005 | 0.134 ± 0.002 | 0.133 ± 0.004 | 0.130 ± 0.002
Day 2 | 0.139 ± 0.003 | 0.130 ± 0.004 | 0.139 ± 0.004 | 0.139 ± 0.003
Day 3 | 0.132 ± 0.006 | 0.140 ± 0.002 | 0.136 ± 0.005 | 0.146 ± 0.006
Day 4 | 0.130 ± 0.004 | 0.138 ± 0.007 | 0.156 ± 0.002** | 0.163 ± 0.007**
Day 184 | 0.180 ± 0.015 | 0.175 ± 0.005 | 0.208 ± 0.006* | 0.283 ± 0.005**
Day 366 | 0.170 ± 0.003 | 0.218 ± 0.004** | 0.249 ± 0.004** | 0.418 ± 0.005**
Day 548 | 0.208 ± 0.015 | 0.279 ± 0.024^c^ | 0.380 ± 0.077** | 0.508 ± 0.029**
µg Co/g total lung
Day 1 | 0.200 ± 0.000^c^ | 5.527 ± 0.184*^c^ | 11.246 ± 0.403** | 21.869 ± 0.910**
Day 2 | 0.200 ± 0.000 | 7.797 ± 0.396** | 14.953 ± 0.393** | 19.443 ± 1.488**
Day 3 | 0.200 ± 0.000 | 9.994 ± 0.340** | 18.467 ± 0.502** | 25.041 ± 0.392**
Day 4 | 0.200 ± 0.000 | 11.009 ± 0.391** | 20.554 ± 0.638** | 26.425 ± 0.767**
Day 184 | 0.200 ± 0.000 | 32.370 ± 2.691** | 58.677 ± 2.508** | 120.993 ± 6.170**
Day 366 | 0.200 ± 0.000 | 44.922 ± 2.798** | 82.778 ± 8.031** | 126.628 ± 4.668**
Day 548 | 0.200 ± 0.000 | 38.918 ± 0.471**^c^ | 53.982 ± 9.362** | 93.214 ± 3.957**
µg Co/total lung
Day 1 | 0.026 ± 0.001^c^ | 0.743 ± 0.017*^c^ | 1.499 ± 0.084** | 2.839 ± 0.085**
Day 2 | 0.028 ± 0.001 | 1.020 ± 0.072** | 2.075 ± 0.081** | 2.698 ± 0.191**
Day 3 | 0.026 ± 0.001 | 1.399 ± 0.057** | 2.512 ± 0.157** | 3.654 ± 0.144**
Day 4 | 0.026 ± 0.001 | 1.524 ± 0.118** | 3.191 ± 0.056** | 4.303 ± 0.143**
Day 184 | 0.036 ± 0.003 | 5.663 ± 0.475** | 12.134 ± 0.285** | 34.246 ± 1.933**
Day 366 | 0.034 ± 0.001 | 9.834 ± 0.698** | 20.538 ± 1.833** | 52.896 ± 1.698**
Day 548 | 0.042 ± 0.003 | 10.883 ± 0.995*^c^ | 17.680 ± 1.790** | 47.218 ± 2.652**
µg Co/total lung per mg Co/m^3^
Day 1 | – | 0.595 ± 0.014^c^ | 0.600 ± 0.033 | 0.568 ± 0.017
Day 2 | – | 0.816 ± 0.058 | 0.830 ± 0.032 | 0.540 ± 0.038
Day 3 | – | 1.119 ± 0.046 | 1.005 ± 0.063 | 0.731 ± 0.029
Day 4 | – | 1.220 ± 0.095 | 1.276 ± 0.022 | 0.861 ± 0.029
Day 184 | – | 4.530 ± 0.380 | 4.854 ± 0.114 | 6.849 ± 0.387
Day 366 | – | 7.867 ± 0.559 | 8.215 ± 0.733 | 10.579 ± 0.340
Day 548 | – | 8.706 ± 0.796^c^ | 7.072 ± 0.716 | 9.444 ± 0.530

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Values below the limit of detection (LOD) or below the experimental limit of quantitation (ELOQ) were replaced with ½ the LOD or ELOQ value. Statistical tests were performed only on data that were not normalized.

^b^ Total lung cobalt burden was calculated using the weight of the total lung with mainstem bronchi at collection and cobalt concentration measured in the right lung.

^c^ n = 4.

Table I-15 Lung Deposition and Clearance Parameter Estimates for Female Mice During the Exposure Periods in the Three-month and Two-year Inhalation Studies of Cobalt Metal (Two-Compartment Model)^a^

Parameter | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
A (µg Co/day) | 0.870 ± 0.161 | 1.842 ± 0.431 | 1.175 ± 0.147
k_a_ (days^−1^) | 0.559 ± 0.146 | 0.652 ± 0.214 | 0.132 ± 0.040
B (µg Co/day) | 0.0274 ± 0.0034 | 0.0750 ± 0.0103 | 0.2516 ± 0.0499
k_b_ (days^−1^) | 0.00169 ± 0.00060 | 0.00404 ± 0.00083 | 0.00586 ± 0.00119
F_B_ | 0.031 ± 0.005 | 0.039 ± 0.008 | 0.176 ± 0.033
t_½a_ (days) | 1.24 ± 0.32 | 1.06 ± 0.35 | 5.24 ± 1.57
L_SSa_ (µg Co/total lung) | 1.56 ± 0.16 | 2.82 ± 0.37 | 8.89 ± 2.20
t_½b_ (days) | 409 ± 145 | 172 ± 35 | 118 ± 24
L_SSb_ (µg Co/total lung) | 16.2 ± 3.9 | 18.6 ± 1.7 | 42.9 ± 2.5

^a^ Data are presented as mean ± standard error. A = deposition rate in the rapid phase; k_a_ = rapid phase clearance rate constant; B = deposition rate in the slow phase; k_b_ = slow phase clearance rate constant; F_B_ = fraction of deposition in the slow clearance phase; t_½a_ = half-life of the rapid clearance phase; L_SSa_ = theoretical steady-state lung burden for the rapid phase; t_½b_ = half-life of the slow clearance phase; L_SSb_ = theoretical steady-state lung burden for the slow phase.

Figure I-1

Lung Cobalt Burdens in 1.25 (top), 2.5 (middle), and 5 (bottom) mg/m^3^ Female Rats in the Three-month and Two-year Inhalation Studies of Cobalt Metal

The lines represent the fit of the lung deposition and clearance model to the data.

Figure I-2

Lung Cobalt Burdens in 1.25 (top), 2.5 (middle), and 5 (bottom) mg/m^3^ Female Mice in the Three-month and Two-year Inhalation Studies of Cobalt Metal

The lines represent the fit of the lung deposition and clearance model to the data.