# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 319 ± 5 | 327 ± 7 | 326 ± 6 | 297 ± 5*
L. Cauda epididymis | 0.1741 ± 0.0054 | 0.1775 ± 0.0043 | 0.1853 ± 0.0075 | 0.1688 ± 0.0038
L. Epididymis | 0.4850 ± 0.0095 | 0.4999 ± 0.0117 | 0.4926 ± 0.0146 | 0.4846 ± 0.0116
L. Testis | 1.3700 ± 0.0179 | 1.3680 ± 0.0147 | 1.3778 ± 0.0205 | 1.3947 ± 0.0124
Spermatid measurements
Spermatid heads (10^6^/testis) | 174.00 ± 10.16 | 180.00 ± 10.06 | 176.50 ± 5.81 | 172.50 ± 5.94
Spermatid heads (10^6^/g testis) | 141.3 ± 8.7 | 146.5 ± 8.2 | 142.5 ± 3.7 | 139.9 ± 4.8
Epididymal spermatozoal measurements
Sperm motility (%) | 88.8 ± 0.8 | 86.0 ± 1.1* | 83.8 ± 1.3** | 81.9 ± 1.3**
Sperm (10^6^/cauda epididymis) | 104.52 ± 3.78 | 98.40 ± 3.13 | 102.27 ± 3.04 | 94.15 ± 3.18
Sperm (10^6^/g cauda epididymis) | 602.3 ± 21.6 | 556.4 ± 19.3 | 564.1 ± 37.0 | 559.4 ± 19.6

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test (body weight) or Shirley’s test (sperm motility).

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid, sperm/cauda epididymis, and sperm/g cauda epididymis).

Table H-2 Estrous Cycle Characterization for Female Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 201 ± 3 | 198 ± 4 | 199 ± 4 | 187 ± 3*
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 5.0 ± 0.0 | 5.0 ± 0.0 | 5.0 ± 0.0 | 5.1 ± 0.05
Estrous stages (% of cycle)
Diestrus | 50.0 | 52.5 | 45.0 | 60.8
Proestrus | 19.2 | 19.2 | 19.2 | 15.8
Estrus | 22.5 | 21.7 | 20.8 | 23.3
Metestrus | 8.3 | 6.7 | 15.0 | 0.0

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated a significantly higher probability of extended diestrus in the 5 mg/m^3^ group compared to the chamber control group.

^b^ Number of females with a regular cycle/number of females cycling.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Exposed to Cobalt Metal by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.01
Overall Tests | 1.25 mg/m^3^ vs. chamber controls | 0.944 | –
Overall Tests | 2.5 mg/m^3^ vs. chamber controls | 0.163 | N
Overall Tests | 5 mg/m^3^ vs. chamber controls | 0.001 | –
Extended Estrus | Overall | 0.407
Extended Estrus | 1.25 mg/m^3^ vs. chamber controls | 0.601 | N
Extended Estrus | 2.5 mg/m^3^ vs. chamber controls | 0.601 | N
Extended Estrus | 5 mg/m^3^ vs. chamber controls | 0.128 | –
Extended Diestrus | Overall | 0.06
Extended Diestrus | 1.25 mg/m^3^ vs. chamber controls | 0.785 | –
Extended Diestrus | 2.5 mg/m^3^ vs. chamber controls | 0.267 | N
Extended Diestrus | 5 mg/m^3^ vs. chamber controls | 0.011 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 1.25 mg/m^3^ vs. chamber controls | 1 | –
Extended Metestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Extended Metestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 1.25 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 1.25 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 1.25 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Summary of Significant Groups
Overall Tests | 5 mg/m^3^ vs. chamber controls | 0.001 | –
Extended Diestrus | 5 mg/m^3^ vs. Chamber Controls | 0.011 | –

^a^ N means that the exposed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 37.7 ± 0.8 | 37.0 ± 0.5 | 37.0 ± 0.9 | 32.5 ± 0.5**
L. Cauda epididymis | 0.0217 ± 0.0014 | 0.0210 ± 0.0008 | 0.0231 ± 0.0018 | 0.0168 ± 0.0006*
L. Epididymis | 0.0603 ± 0.0022 | 0.0578 ± 0.0019 | 0.0614 ± 0.0035 | 0.0429 ± 0.0021**
L. Testis | 0.1185 ± 0.0017 | 0.1132 ± 0.0023 | 0.1027 ± 0.0036** | 0.0316 ± 0.0014**
Spermatid measurements
Spermatid heads (10^6^/testis) | 22.34 ± 0.84 | 22.22 ± 0.65 | 18.90 ± 1.20* | 0.53 ± 0.10**
Spermatid heads (10^6^/g testis) | 210.84 ± 6.85 | 227.74 ± 7.16 | 205.67 ± 7.43 | 24.27 ± 4.78**
Epididymal spermatozoal measurements
Sperm motility (%) | 86.0 ± 1.1 | 82.0 ± 0.8* | 82.2 ± 1.1* | 2.6 ± 1.2**
Sperm (10^6^/cauda epididymis) | 11.55 ± 0.39 | 10.53 ± 0.43 | 9.62 ± 0.49** | 0.71 ± 0.06**
Sperm (10^6^/g cauda epididymis) | 551.1 ± 37.9 | 505.9 ± 23.3 | 439.9 ± 40.3* | 43.4 ± 3.7**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test (cauda epididymis weight) or Shirley’s test (spermatid and epididymal spermatozoal measurements).

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body and tissue weights) or Shirley’s test (spermatid and epididymal spermatozoal measurements).

^a^ Data are presented as mean ± standard error.

Table H-5 Estrous Cycle Characterization for Female Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Number weighed at necropsy | 10 | 9 | 10 | 10
Necropsy body wt (g) | 30.9 ± 1.0 | 30.1 ± 0.7 | 29.0 ± 1.1 | 26.8 ± 1.0**
Proportion of regular cycling females^b^ | 9/10 | 9/9 | 9/10 | 6/10
Estrous cycle length (days) | 4.1 ± 0.05 | 4.0 ± 0.00 | 4.1 ± 0.13 | 4.9 ± 0.36*
Estrous stages (% of cycle)
Diestrus | 28.3 | 25.9 | 29.2 | 30.0
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 47.5 | 50.0 | 48.3 | 49.2
Metestrus | 24.2 | 24.1 | 22.5 | 20.8

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated no significant differences in estrous cyclicity of the exposed and chamber control groups.

^b^ Number of females with a regular cycle/number of females cycling.

Table H-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Exposed to Cobalt Metal by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 2.5 mg/m^3^ vs. chamber controls | 0.627 | N
Overall Tests | 5 mg/m^3^ vs. chamber controls | 0.107 | –
Overall Tests | 10 mg/m^3^ vs. chamber controls | <0.001 | –
Extended Estrus | Overall | 0.932
Extended Estrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Extended Estrus | 5 mg/m^3^ vs. chamber controls | 0.596 | –
Extended Estrus | 10 mg/m^3^ vs. chamber controls | 0.663 | –
Extended Diestrus | Overall | 0.812
Extended Diestrus | 2.5 mg/m^3^ vs. chamber controls | 0.627 | N
Extended Diestrus | 5 mg/m^3^ vs. chamber controls | 1 | N
Extended Diestrus | 10 mg/m^3^ vs. chamber controls | 0.361 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Extended Metestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Extended Metestrus | 10 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Extended Proestrus | 10 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Estrus | 10 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 2.5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | 5 mg/m^3^ vs. chamber controls | 1 | –
Skipped Diestrus | 10 mg/m^3^ vs. chamber controls | 1 | –
Summary of Significant Groups
Overall Tests | 10 mg/m^3^ vs. Chamber Controls | <0.001

^a^ N means that the exposed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Figure H-1

Vaginal Cytology Plots for Female Rats in the Three-month Inhalation Study of Cobalt Metal

D = diestrus, P = proestrus, E = estrus, M = metestrus.

Figure H-2

Vaginal Cytology Plots for Female Mice in the Three-month Inhalation Study of Cobalt Metal

D = diestrus, E = estrus, M = metestrus.