# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
Male
N | 5 | 5 | 5 | 5 | 0 | 0
Necropsy body wt | 144 ± 3 | 144 ± 2 | 140 ± 4 | 115 ± 6** | – | –
Heart
Absolute | 0.55 ± 0.01 | 0.54 ± 0.01 | 0.53 ± 0.01 | 0.47 ± 0.01** | – | –
Relative | 3.84 ± 0.07 | 3.73 ± 0.02 | 3.79 ± 0.14 | 4.11 ± 0.17 | – | –
L. Kidney
Absolute | 0.61 ± 0.02 | 0.61 ± 0.01 | 0.58 ± 0.01 | 0.52 ± 0.02** | – | –
Relative | 4.25 ± 0.06 | 4.26 ± 0.08 | 4.12 ± 0.09 | 4.57 ± 0.10* | – | –
Liver
Absolute | 5.84 ± 0.16 | 5.10 ± 0.09** | 5.08 ± 0.15** | 4.29 ± 0.24** | – | –
Relative | 40.61 ± 0.46 | 35.40 ± 0.28** | 36.35 ± 0.63** | 37.43 ± 0.86** | – | –
Lung
Absolute | 1.14 ± 0.10 | 1.16 ± 0.08 | 1.19 ± 0.04 | 1.28 ± 0.12 | – | –
Relative | 7.91 ± 0.61 | 8.07 ± 0.55 | 8.49 ± 0.30 | 11.13 ± 0.50** | – | –
L. Testis
Absolute | 0.886 ± 0.040 | 0.928 ± 0.017 | 0.852 ± 0.035 | 0.590 ± 0.088** | – | –
Relative | 6.165 ± 0.246 | 6.446 ± 0.155 | 6.103 ± 0.248 | 5.053 ± 0.502 | – | –
Thymus
Absolute | 0.374 ± 0.013 | 0.358 ± 0.025 | 0.358 ± 0.007 | 0.284 ± 0.008** | – | –
Relative | 2.605 ± 0.054 | 2.485 ± 0.161 | 2.560 ± 0.023 | 2.498 ± 0.112 | – | –
Thyroid gland
Absolute | 0.017 ± 0.002 | 0.019 ± 0.002 | 0.016 ± 0.001 | 0.015 ± 0.001 | – | –
Relative | 0.115 ± 0.014 | 0.131 ± 0.011 | 0.115 ± 0.010 | 0.130 ± 0.008 | – | –
Female
n | 5 | 5 | 5 | 5 | 2 | 0
Necropsy body wt | 112 ± 4 | 112 ± 2 | 107 ± 3 | 98 ± 4** | 61 ± 5** | –
Heart
Absolute | 0.42 ± 0.01 | 0.47 ± 0.01* | 0.44 ± 0.01 | 0.42 ± 0.01 | 0.34 ± 0.00** | –
Relative | 3.75 ± 0.06 | 4.17 ± 0.07** | 4.15 ± 0.06** | 4.25 ± 0.10** | 5.59 ± 0.41** | –
L. Kidney
Absolute | 0.52 ± 0.02 | 0.50 ± 0.01 | 0.50 ± 0.02 | 0.46 ± 0.01* | 0.35 ± 0.00** | –
Relative | 4.66 ± 0.11 | 4.46 ± 0.05 | 4.63 ± 0.08 | 4.74 ± 0.12 | 5.75 ± 0.42** | –
Liver
Absolute | 4.07 ± 0.16 | 3.77 ± 0.05 | 3.61 ± 0.13** | 3.44 ± 0.05** | 2.57 ± 0.06** | –
Relative | 36.37 ± 0.49 | 33.59 ± 0.16 | 33.78 ± 1.08 | 35.17 ± 1.00 | 42.15 ± 2.12** | –
Lung
Absolute | 0.86 ± 0.04 | 0.83 ± 0.01 | 0.91 ± 0.04 | 1.03 ± 0.06* | 1.01 ± 0.04* | –
Relative | 7.71 ± 0.36 | 7.44 ± 0.07 | 8.49 ± 0.34 | 10.54 ± 0.69** | 16.54 ± 0.56** | –
Thymus
Absolute | 0.317 ± 0.016 | 0.324 ± 0.011 | 0.352 ± 0.022 | 0.289 ± 0.011 | 0.064 ± 0.016** | –
Relative | 2.842 ± 0.167 | 2.895 ± 0.126 | 3.289 ± 0.201 | 2.948 ± 0.092 | 1.024 ± 0.178** | –
Thyroid gland
Absolute | 0.011 ± 0.002 | 0.017 ± 0.002 | 0.019 ± 0.003 | 0.014 ± 0.003 | 0.017 ± 0.005 | –
Relative | 0.099 ± 0.012 | 0.151 ± 0.018 | 0.174 ± 0.024 | 0.140 ± 0.026 | 0.266 ± 0.054** | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). No data available for 20 mg/m^3^ males or 40 mg/m^3^ males or females due to 100% mortality.

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
n | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 319 ± 5 | 336 ± 6 | 327 ± 7 | 326 ± 6 | 297 ± 5*
Heart
Absolute | 0.86 ± 0.02 | 0.89 ± 0.02 | 0.86 ± 0.02 | 0.86 ± 0.02 | 0.81 ± 0.01*
Relative | 2.707 ± 0.036 | 2.650 ± 0.035 | 2.624 ± 0.040 | 2.636 ± 0.020 | 2.717 ± 0.038
R. Kidney
Absolute | 0.95 ± 0.01 | 1.00 ± 0.02 | 0.98 ± 0.02 | 0.99 ± 0.02 | 0.91 ± 0.02
Relative | 2.988 ± 0.037 | 2.970 ± 0.036 | 3.014 ± 0.021 | 3.044 ± 0.041 | 3.074 ± 0.036
Liver
Absolute | 9.97 ± 0.19 | 10.89 ± 0.33 | 10.08 ± 0.31 | 10.22 ± 0.20 | 9.07 ± 0.18*
Relative | 31.232 ± 0.479 | 32.362 ± 0.443 | 30.808 ± 0.467 | 31.374 ± 0.401 | 30.596 ± 0.389
Lung
Absolute | 1.63 ± 0.03 | 1.99 ± 0.05** | 2.14 ± 0.08** | 2.04 ± 0.06** | 2.05 ± 0.05**
Relative | 5.129 ± 0.111 | 5.932 ± 0.146** | 6.549 ± 0.174** | 6.259 ± 0.115** | 6.915 ± 0.138**
R. Testis
Absolute | 1.292 ± 0.014 | 1.325 ± 0.023 | 1.311 ± 0.015 | 1.314 ± 0.016 | 1.319 ± 0.020
Relative | 4.052 ± 0.051 | 3.949 ± 0.065 | 4.025 ± 0.061 | 4.039 ± 0.060 | 4.462 ± 0.117**
Thymus
Absolute | 0.322 ± 0.024 | 0.335 ± 0.018 | 0.328 ± 0.016 | 0.294 ± 0.019 | 0.277 ± 0.013
Relative | 1.004 ± 0.063 | 0.995 ± 0.045 | 1.008 ± 0.053 | 0.905 ± 0.064 | 0.935 ± 0.041
Thyroid gland
Absolute | 0.019 ± 0.001 | 0.019 ± 0.002 | 0.020 ± 0.002 | 0.024 ± 0.002 | 0.021 ± 0.001
Relative | 0.060 ± 0.002 | 0.057 ± 0.005 | 0.060 ± 0.006 | 0.072 ± 0.006 | 0.070 ± 0.004
Female
Necropsy body wt | 201 ± 3 | 205 ± 4 | 198 ± 4 | 199 ± 4 | 187 ± 3*
Heart
Absolute | 0.64 ± 0.01 | 0.62 ± 0.01 | 0.61 ± 0.01 | 0.63 ± 0.01 | 0.60 ± 0.01
Relative | 3.198 ± 0.071 | 3.049 ± 0.030 | 3.090 ± 0.052 | 3.156 ± 0.042 | 3.197 ± 0.033
R. Kidney
Absolute | 0.64 ± 0.01 | 0.63 ± 0.02 | 0.66 ± 0.02 | 0.67 ± 0.02 | 0.67 ± 0.01
Relative | 3.184 ± 0.036 | 3.068 ± 0.082 | 3.343 ± 0.052 | 3.349 ± 0.047 | 3.589 ± 0.055**
Liver
Absolute | 6.06 ± 0.09 | 6.37 ± 0.18 | 6.03 ± 0.21 | 6.06 ± 0.19 | 5.80 ± 0.12
Relative | 30.171 ± 0.262 | 31.073 ± 0.519 | 30.400 ± 0.557 | 30.444 ± 0.511 | 31.012 ± 0.288
Lung
Absolute | 1.05 ± 0.02 | 1.31 ± 0.02** | 1.33 ± 0.05** | 1.32 ± 0.03** | 1.36 ± 0.02**
Relative | 5.237 ± 0.087 | 6.388 ± 0.107** | 6.687 ± 0.149** | 6.650 ± 0.131** | 7.298 ± 0.111**
Thymus
Absolute | 0.347 ± 0.013 | 0.363 ± 0.011 | 0.337 ± 0.009 | 0.354 ± 0.014 | 0.318 ± 0.009
Relative | 1.725 ± 0.053 | 1.775 ± 0.059 | 1.715 ± 0.071 | 1.785 ± 0.069 | 1.704 ± 0.045
Thyroid gland
Absolute | 0.021 ± 0.001 | 0.018 ± 0.002 | 0.019 ± 0.001 | 0.019 ± 0.001 | 0.021 ± 0.001
Relative | 0.103 ± 0.007 | 0.090 ± 0.008 | 0.097 ± 0.006 | 0.096 ± 0.007 | 0.109 ± 0.005

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Cobalt Metal^a^

| Chamber Control | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^ | 20 mg/m^3^ | 40 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 2
Male
Necropsy body wt | 25.7 ± 0.5 | 25.0 ± 0.5 | 25.9 ± 0.3 | 25.3 ± 0.5 | 23.4 ± 0.4** | 18.9 ± 1.1**
Heart
Absolute | 0.12 ± 0.01 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.01*
Relative | 4.83 ± 0.16 | 5.14 ± 0.21 | 4.79 ± 0.12 | 4.68 ± 0.20 | 4.79 ± 0.11 | 5.57 ± 0.05
L. Kidney
Absolute | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.02 | 0.16 ± 0.01** | 0.13 ± 0.00**
Relative | 8.02 ± 0.20 | 8.24 ± 0.45 | 7.64 ± 0.23 | 7.02 ± 0.52 | 7.02 ± 0.25 | 6.92 ± 0.39
Liver
Absolute | 1.13 ± 0.04 | 0.98 ± 0.04** | 0.98 ± 0.04** | 0.99 ± 0.02** | 0.89 ± 0.02** | 0.83 ± 0.01**
Relative | 43.88 ± 0.80 | 39.18 ± 1.35* | 37.67 ± 1.09** | 39.32 ± 0.91* | 37.93 ± 0.51** | 44.20 ± 2.99
Lung
Absolute | 0.18 ± 0.01 | 0.21 ± 0.01 | 0.23 ± 0.01* | 0.24 ± 0.01** | 0.29 ± 0.01** | 0.36 ± 0.05**
Relative | 7.08 ± 0.15 | 8.33 ± 0.32 | 8.73 ± 0.33 | 9.61 ± 0.62* | 12.62 ± 0.51** | 19.31 ± 3.73**
L. Testis
Absolute | 0.098 ± 0.002 | 0.104 ± 0.001 | 0.099 ± 0.004 | 0.084 ± 0.009 | 0.089 ± 0.003 | 0.070 ± 0.002**
Relative | 3.834 ± 0.074 | 4.180 ± 0.114 | 3.812 ± 0.149 | 3.322 ± 0.311 | 3.807 ± 0.088 | 3.731 ± 0.314
Thymus
Absolute | 0.049 ± 0.004 | 0.053 ± 0.003 | 0.046 ± 0.008 | 0.046 ± 0.004 | 0.045 ± 0.002 | 0.025 ± 0.014*
Relative | 1.906 ± 0.148 | 2.137 ± 0.136 | 1.789 ± 0.300 | 1.851 ± 0.210 | 1.910 ± 0.074 | 1.264 ± 0.646
Thyroid gland
Absolute | 0.004 ± 0.000 | 0.004 ± 0.001 | 0.003 ± 0.000 | 0.003 ± 0.000 | 0.003 ± 0.001 | 0.003 ± 0.001
Relative | 0.141 ± 0.011 | 0.146 ± 0.023 | 0.131 ± 0.015 | 0.118 ± 0.017 | 0.144 ± 0.020 | 0.132 ± 0.019
Female
Necropsy body wt | 20.8 ± 0.1 | 20.3 ± 0.5 | 20.1 ± 0.5 | 20.0 ± 0.6 | 17.4 ± 0.4** | 13.0 ± 1.6**
Heart
Absolute | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.10 ± 0.00* | 0.10 ± 0.01** | 0.10 ± 0.01*
Relative | 5.39 ± 0.09 | 5.32 ± 0.10 | 5.48 ± 0.15 | 5.02 ± 0.16 | 5.51 ± 0.23 | 7.49 ± 1.28**
L. Kidney
Absolute | 0.14 ± 0.00 | 0.14 ± 0.01 | 0.14 ± 0.01 | 0.12 ± 0.00 | 0.11 ± 0.01** | 0.10 ± 0.01**
Relative | 6.74 ± 0.16 | 6.69 ± 0.23 | 6.86 ± 0.29 | 6.23 ± 0.23 | 6.31 ± 0.27 | 7.74 ± 0.15
Liver
Absolute | 0.93 ± 0.03 | 0.81 ± 0.02** | 0.80 ± 0.03** | 0.75 ± 0.03** | 0.69 ± 0.03** | 0.61 ± 0.06**
Relative | 44.56 ± 1.13 | 40.09 ± 0.31** | 39.75 ± 0.82** | 37.40 ± 1.12** | 39.73 ± 0.70** | 46.88 ± 1.36
Lung
Absolute | 0.19 ± 0.01 | 0.19 ± 0.00 | 0.22 ± 0.01* | 0.23 ± 0.01** | 0.29 ± 0.01** | 0.33 ± 0.02**
Relative | 9.34 ± 0.38 | 9.49 ± 0.37 | 11.14 ± 0.24* | 11.77 ± 0.59** | 16.80 ± 0.58** | 25.67 ± 1.53**
Thymus
Absolute | 0.078 ± 0.000 | 0.075 ± 0.003 | 0.074 ± 0.003 | 0.073 ± 0.004 | 0.059 ± 0.006** | 0.016 ± 0.008**
Relative | 3.735 ± 0.024 | 3.699 ± 0.199 | 3.658 ± 0.118 | 3.668 ± 0.182 | 3.361 ± 0.353 | 1.144 ± 0.442**
Thyroid gland
Absolute | 0.003 ± 0.001 | 0.004 ± 0.001 | 0.003 ± 0.000 | 0.004 ± 0.000 | 0.003 ± 0.001 | 0.002 ± 0.001
Relative | 0.126 ± 0.025 | 0.208 ± 0.037 | 0.168 ± 0.017 | 0.202 ± 0.025 | 0.162 ± 0.036 | 0.147 ± 0.060

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 37.7 ± 0.8 | 38.2 ± 0.6 | 37.9 ± 0.8 | 37.0 ± 0.5 | 37.0 ± 0.9 | 32.5 ± 0.5**
Heart
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.01 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00**
Relative | 4.233 ± 0.095 | 4.219 ± 0.067 | 4.224 ± 0.056 | 4.187 ± 0.063 | 4.029 ± 0.053 | 4.385 ± 0.157
R. Kidney
Absolute | 0.31 ± 0.01 | 0.32 ± 0.01 | 0.32 ± 0.01 | 0.32 ± 0.00 | 0.29 ± 0.01** | 0.23 ± 0.01**
Relative | 8.360 ± 0.192 | 8.441 ± 0.122 | 8.333 ± 0.237 | 8.507 ± 0.047 | 7.714 ± 0.145** | 7.176 ± 0.131**
Liver
Absolute | 1.48 ± 0.04 | 1.53 ± 0.04 | 1.51 ± 0.07 | 1.49 ± 0.04 | 1.42 ± 0.05 | 1.15 ± 0.03**
Relative | 39.217 ± 0.586 | 40.049 ± 0.671 | 39.753 ± 1.032 | 40.301 ± 0.698 | 38.159 ± 0.723 | 35.457 ± 0.668**
Lung
Absolute | 0.20 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.23 ± 0.01* | 0.27 ± 0.01** | 0.30 ± 0.01**
Relative | 5.416 ± 0.116 | 6.051 ± 0.235 | 5.737 ± 0.147 | 6.234 ± 0.088** | 7.436 ± 0.262** | 9.142 ± 0.177**
R. Testis
Absolute | 0.118 ± 0.002 | 0.119 ± 0.002 | 0.114 ± 0.002 | 0.114 ± 0.002 | 0.104 ± 0.003** | 0.033 ± 0.001**
Relative | 3.136 ± 0.058 | 3.131 ± 0.037 | 3.019 ± 0.078 | 3.073 ± 0.056 | 2.825 ± 0.082** | 1.004 ± 0.025**
Thymus
Absolute | 0.043 ± 0.002 | 0.046 ± 0.003 | 0.051 ± 0.003 | 0.048 ± 0.002 | 0.048 ± 0.003 | 0.049 ± 0.002
Relative | 1.136 ± 0.054 | 1.190 ± 0.078 | 1.348 ± 0.060 | 1.290 ± 0.057 | 1.298 ± 0.081 | 1.507 ± 0.048**
Female
n | 10 | 10 | 10 | 9 | 10 | 10
Necropsy body wt | 30.9 ± 1.0 | 31.6 ± 1.1 | 31.4 ± 0.9 | 30.1 ± 0.7 | 29.0 ± 1.1 | 26.8 ± 1.0**
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00* | 0.13 ± 0.00**
Relative | 4.561 ± 0.124 | 4.549 ± 0.092 | 4.472 ± 0.101 | 4.477 ± 0.082 | 4.475 ± 0.133 | 4.753 ± 0.195
R. Kidney
Absolute | 0.21 ± 0.01 | 0.22 ± 0.00 | 0.21 ± 0.01 | 0.20 ± 0.00 | 0.17 ± 0.00** | 0.16 ± 0.00**
Relative | 6.887 ± 0.184 | 6.849 ± 0.155 | 6.661 ± 0.126 | 6.689 ± 0.254 | 6.031 ± 0.132** | 6.142 ± 0.185**
Liver
Absolute | 1.46 ± 0.06 | 1.51 ± 0.07 | 1.46 ± 0.05 | 1.30 ± 0.03* | 1.16 ± 0.04** | 1.01 ± 0.03**
Relative | 47.051 ± 0.808 | 47.552 ± 0.952 | 46.455 ± 1.046 | 43.092 ± 0.773** | 39.831 ± 0.459** | 38.045 ± 1.246**
Lung
Absolute | 0.21 ± 0.01 | 0.22 ± 0.00 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.28 ± 0.01** | 0.33 ± 0.01**
Relative | 6.904 ± 0.227 | 6.884 ± 0.176 | 7.300 ± 0.274 | 7.555 ± 0.184 | 9.787 ± 0.241** | 12.602 ± 0.487**
Thymus
Absolute | 0.060 ± 0.004 | 0.064 ± 0.004 | 0.068 ± 0.005 | 0.062 ± 0.003 | 0.066 ± 0.004 | 0.064 ± 0.003
Relative | 1.960 ± 0.106 | 2.029 ± 0.100 | 2.163 ± 0.113 | 2.084 ± 0.105 | 2.257 ± 0.110 | 2.431 ± 0.155**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).