# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Male
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 9 | 10
Week 14 | 10 | 10 | 10 | 10 | 10
Hematocrit (spun) (%)
Day 3 | 46.5 ± 0.2 | 46.4 ± 0.2 | 47.4 ± 0.2* | 47.7 ± 0.3** | 51.2 ± 0.4**
Day 23 | 47.9 ± 0.4 | 48.5 ± 0.4 | 49.9 ± 0.5** | 51.1 ± 0.2** | 53.3 ± 0.4**
Week 14 | 49.6 ± 0.4 | 51.6 ± 0.4** | 59.2 ± 0.4** | 61.8 ± 0.2** | 63.9 ± 0.3**
Packed cell volume (mL/dL)
Day 3 | 45.1 ± 0.2 | 44.5 ± 0.3 | 45.7 ± 0.3 | 46.1 ± 0.4* | 49.7 ± 0.4**
Day 23 | 46.8 ± 0.4 | 47.3 ± 0.4 | 49.0 ± 0.6** | 49.7 ± 0.2** | 51.5 ± 0.5**
Week 14 | 49.6 ± 0.5 | 51.7 ± 0.4** | 58.3 ± 0.4** | 60.7 ± 0.1** | 62.9 ± 0.3**
Hemoglobin (g/dL)
Day 3 | 13.7 ± 0.1 | 13.8 ± 0.1 | 14.1 ± 0.1** | 14.2 ± 0.1** | 15.5 ± 0.1**
Day 23 | 15.0 ± 0.1 | 14.9 ± 0.1 | 15.4 ± 0.2 | 15.8 ± 0.1** | 16.1 ± 0.2**
Week 14 | 15.6 ± 0.1 | 16.3 ± 0.1** | 18.7 ± 0.1** | 19.7 ± 0.1** | 20.3 ± 0.1**
Erythrocytes (10^6^/µL)
Day 3 | 7.30 ± 0.06 | 7.27 ± 0.09 | 7.46 ± 0.05 | 7.57 ± 0.08* | 8.22 ± 0.08**
Day 23 | 7.97 ± 0.09 | 8.05 ± 0.09 | 8.36 ± 0.11* | 8.44 ± 0.06** | 9.27 ± 0.14**
Week 14 | 9.19 ± 0.10 | 9.67 ± 0.09** | 11.20 ± 0.06** | 11.80 ± 0.06** | 11.90 ± 0.08**
Reticulocytes (10^3^/µL)
Day 3 | 612.0 ± 42.3 | 562.3 ± 24.5^b^ | 613.0 ± 30.8 | 622.1 ± 25.6 | 873.8 ± 53.4**
Day 23 | 262.9 ± 13.9 | 261.3 ± 17.8 | 280.9 ± 14.3 | 291.6 ± 18.6 | 339.6 ± 25.1*
Week 14 | 219.8 ± 16.0 | 191.7 ± 19.9 | 189.3 ± 13.1 | 272.7 ± 18.7 | 360.0 ± 35.9*
Nucleated erythrocytes/100 leukocytes
Day 3 | 2.0 ± 0.3 | 1.6 ± 0.3 | 2.6 ± 0.6 | 2.4 ± 0.5 | 1.0 ± 0.3
Day 23 | 0.6 ± 0.2 | 0.3 ± 0.2 | 0.6 ± 0.2 | 0.3 ± 0.2 | 0.4 ± 0.2
Week 14 | 0.3 ± 0.2 | 0.3 ± 0.2 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.4 ± 0.2
Total nucleated cells (10^3^/µL)
Day 3 | 8.4 ± 0.4 | 9.5 ± 0.3 | 8.9 ± 0.4 | 8.8 ± 0.7 | 8.2 ± 0.3
Day 23 | 7.0 ± 0.6 | 6.8 ± 0.3 | 7.4 ± 0.6 | 7.7 ± 0.6 | 6.5 ± 0.4
Week 14 | 7.3 ± 0.3 | 7.0 ± 0.4 | 7.2 ± 0.5 | 7.0 ± 0.4 | 7.3 ± 0.2
Mean cell volume (fL)
Day 3 | 61.8 ± 0.3 | 61.2 ± 0.5 | 61.3 ± 0.2 | 61.0 ± 0.4 | 60.5 ± 0.4*
Day 23 | 58.8 ± 0.2 | 58.7 ± 0.2 | 58.7 ± 0.4 | 58.9 ± 0.3 | 55.7 ± 0.7**
Week 14 | 54.0 ± 0.3 | 53.5 ± 0.2 | 52.1 ± 0.2** | 51.4 ± 0.2** | 52.9 ± 0.2**
Mean cell hemoglobin (pg)
Day 3 | 18.8 ± 0.1 | 19.0 ± 0.1 | 18.9 ± 0.1 | 18.8 ± 0.1 | 18.9 ± 0.1
Day 23 | 18.8 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1 | 18.7 ± 0.1 | 17.4 ± 0.2**
Week 14 | 17.0 ± 0.1 | 16.9 ± 0.0 | 16.7 ± 0.0** | 16.7 ± 0.1* | 17.1 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 30.4 ± 0.1 | 31.1 ± 0.2** | 30.9 ± 0.2** | 30.9 ± 0.2* | 31.2 ± 0.1**
Day 23 | 31.9 ± 0.1 | 31.5 ± 0.1 | 31.5 ± 0.2 | 31.7 ± 0.1 | 31.3 ± 0.1**
Week 14 | 31.6 ± 0.1 | 31.6 ± 0.1 | 32.1 ± 0.1** | 32.5 ± 0.2** | 32.3 ± 0.1**
Platelets (10^3^/µL)
Day 3 | 899.7 ± 14.0 | 883.5 ± 23.9 | 939.4 ± 14.4 | 903.8 ± 22.8 | 1,123.7 ± 34.2**
Day 23 | 740.8 ± 16.2 | 712.0 ± 16.3 | 732.1 ± 22.7 | 682.0 ± 44.5 | 796.7 ± 12.8
Week 14 | 682.5 ± 27.7 | 646.8 ± 8.7 | 611.2 ± 13.8* | 548.2 ± 22.3** | 573.2 ± 15.3**
Leukocytes (10^3^/µL)
Day 3 | 8.22 ± 0.34 | 9.38 ± 0.28 | 8.63 ± 0.37 | 8.57 ± 0.64 | 8.10 ± 0.32
Day 23 | 6.93 ± 0.58 | 6.77 ± 0.32 | 7.31 ± 0.58 | 7.66 ± 0.57 | 6.44 ± 0.44
Week 14 | 7.25 ± 0.34 | 6.98 ± 0.42 | 7.19 ± 0.48 | 6.96 ± 0.39 | 7.27 ± 0.24
Segmented neutrophils (10^3^/µL)
Day 3 | 0.86 ± 0.03 | 1.02 ± 0.06 | 1.01 ± 0.04 | 0.98 ± 0.05 | 0.98 ± 0.09
Day 23 | 0.83 ± 0.04 | 0.96 ± 0.03* | 1.02 ± 0.03** | 1.19 ± 0.04** | 1.13 ± 0.08**
Week 14 | 1.36 ± 0.06 | 1.54 ± 0.07 | 1.52 ± 0.09 | 1.48 ± 0.05 | 1.41 ± 0.05
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 3 | 7.04 ± 0.33 | 7.99 ± 0.26 | 7.40 ± 0.36 | 7.34 ± 0.58 | 6.88 ± 0.25
Day 23 | 5.92 ± 0.55 | 5.68 ± 0.31 | 6.10 ± 0.56 | 6.28 ± 0.56 | 5.13 ± 0.35
Week 14 | 5.46 ± 0.33 | 5.08 ± 0.38 | 5.18 ± 0.45 | 5.15 ± 0.39 | 5.61 ± 0.20
Monocytes (10^3^/μL)
Day 3 | 0.23 ± 0.03 | 0.26 ± 0.04 | 0.12 ± 0.04 | 0.16 ± 0.05 | 0.15 ± 0.05
Day 23 | 0.12 ± 0.04 | 0.07 ± 0.02 | 0.12 ± 0.03 | 0.11 ± 0.04 | 0.13 ± 0.04
Week 14 | 0.30 ± 0.07 | 0.23 ± 0.06 | 0.36 ± 0.07 | 0.17 ± 0.06 | 0.12 ± 0.05
Basophils (10^3^/μL)
Day 3 | 0.008 ± 0.002 | 0.007 ± 0.002 | 0.006 ± 0.002 | 0.005 ± 0.002 | 0.010 ± 0.001
Day 23 | 0.010 ± 0.003 | 0.007 ± 0.002 | 0.009 ± 0.003 | 0.008 ± 0.003 | 0.008 ± 0.004
Week 14 | 0.009 ± 0.003 | 0.005 ± 0.002 | 0.010 ± 0.005 | 0.003 ± 0.002 | 0.002 ± 0.001
Eosinophils (10^3^/μL)
Day 3 | 0.08 ± 0.01 | 0.11 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01
Day 23 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.05 ± 0.01
Week 14 | 0.12 ± 0.01 | 0.13 ± 0.02 | 0.11 ± 0.02 | 0.16 ± 0.02 | 0.13 ± 0.02
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 8.0 ± 0.4 | 8.0 ± 0.5 | 8.1 ± 0.4 | 8.9 ± 0.4 | 16.5 ± 1.1**
Day 23 | 11.0 ± 0.5 | 10.9 ± 0.4 | 9.7 ± 0.4 | 9.9 ± 0.5 | 8.6 ± 0.4**
Week 14 | 13.4 ± 0.3 | 13.9 ± 0.3 | 14.5 ± 0.5 | 14.1 ± 0.6 | 13.2 ± 0.5
Creatinine (mg/dL)
Day 3 | 0.23 ± 0.02 | 0.25 ± 0.02 | 0.26 ± 0.02 | 0.25 ± 0.02 | 0.22 ± 0.01
Day 23 | 0.28 ± 0.01 | 0.26 ± 0.02 | 0.30 ± 0.00 | 0.32 ± 0.01 | 0.30 ± 0.00
Week 14 | 0.34 ± 0.02 | 0.38 ± 0.01 | 0.36 ± 0.02 | 0.37 ± 0.02 | 0.42 ± 0.01**
Glucose (mg/dL)
Day 3 | 135 ± 2 | 138 ± 1 | 134 ± 2 | 136 ± 1 | 129 ± 4
Day 23 | 132 ± 3 | 132 ± 4 | 143 ± 9 | 139 ± 8 | 120 ± 2
Week 14 | 126 ± 3 | 128 ± 3 | 118 ± 5* | 111 ± 3** | 104 ± 4**
Total protein (g/dL)
Day 3 | 6.1 ± 0.1 | 5.9 ± 0.0 | 6.0 ± 0.0 | 6.1 ± 0.1 | 6.3 ± 0.1*
Day 23 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1
Week 14 | 7.4 ± 0.1 | 7.3 ± 0.0 | 7.4 ± 0.1 | 7.3 ± 0.1 | 7.1 ± 0.1**
Albumin (g/dL)
Day 3 | 4.3 ± 0.0 | 4.1 ± 0.0** | 4.2 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0
Day 23 | 4.6 ± 0.1 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0
Week 14 | 4.9 ± 0.1 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.8 ± 0.0
Globulin (g/dL)
Day 3 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 2.0 ± 0.0**
Day 23 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.1 ± 0.1 | 2.0 ± 0.0 | 2.0 ± 0.0
Week 14 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.3 ± 0.0**
Albumin to globulin ratio
Day 3 | 2.4 ± 0.3 | 2.4 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.1 | 2.1 ± 0.0**
Day 23 | 2.3 ± 0.1 | 2.3 ± 0.0 | 2.2 ± 0.1 | 2.2 ± 0.0 | 2.3 ± 0.0
Week 14 | 1.9 ± 0.0 | 2.0 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0 | 2.1 ± 0.0
Cholesterol (mg/dL)
Day 3 | 95 ± 2 | 87 ± 1* | 84 ± 1** | 79 ± 2** | 81 ± 2**
Day 23 | 79 ± 1 | 76 ± 2 | 70 ± 1** | 73 ± 2** | 63 ± 1**
Week 14 | 91 ± 1 | 91 ± 1 | 88 ± 2 | 79 ± 2** | 67 ± 1**
Triglycerides (mg/dL)
Day 3 | 52 ± 3 | 53 ± 3 | 57 ± 3 | 61 ± 4 | 95 ± 6**
Day 23 | 61 ± 5 | 63 ± 8 | 54 ± 5 | 69 ± 5 | 56 ± 4
Week 14 | 112 ± 7 | 122 ± 8 | 137 ± 10 | 141 ± 8 | 130 ± 20
Alanine aminotransferase (IU/L)
Day 3 | 55 ± 1 | 52 ± 1 | 50 ± 1* | 44 ± 1** | 39 ± 1**
Day 23 | 47 ± 3 | 41 ± 1 | 41 ± 1 | 45 ± 1 | 40 ± 1
Week 14 | 88 ± 7 | 99 ± 8 | 106 ± 8 | 97 ± 6 | 77 ± 2
Alkaline phosphatase (IU/L)
Day 3 | 579 ± 6 | 586 ± 8 | 601 ± 6 | 609 ± 10 | 518 ± 12
Day 23 | 387 ± 7 | 392 ± 9 | 410 ± 8 | 415 ± 10 | 458 ± 9**
Week 14 | 236 ± 8 | 238 ± 5 | 238 ± 4 | 249 ± 10 | 235 ± 5
Creatine kinase (IU/L)
Day 3 | 402 ± 29 | 521 ± 55 | 482 ± 29 | 467 ± 30 | 480 ± 65
Day 23 | 378 ± 113 | 418 ± 70 | 569 ± 98 | 630 ± 114 | 467 ± 54
Week 14 | 224 ± 47 | 202 ± 33 | 266 ± 44 | 231 ± 25 | 254 ± 44
Sorbitol dehydrogenase (IU/L)
Day 3 | 15 ± 0 | 13 ± 1* | 14 ± 1 | 14 ± 0 | 12 ± 1**
Day 23 | 15 ± 2 | 13 ± 1 | 13 ± 0 | 14 ± 1 | 14 ± 1
Week 14 | 23 ± 1 | 27 ± 1 | 28 ± 1* | 26 ± 1 | 24 ± 1
Bile salts (µmol/L)
Day 3 | 5.3 ± 0.4 | 5.7 ± 1.3 | 5.3 ± 0.3 | 5.6 ± 0.6 | 7.3 ± 0.8
Day 23 | 4.2 ± 0.4 | 3.9 ± 0.2 | 5.3 ± 1.2 | 4.6 ± 0.6 | 4.1 ± 0.2
Week 14 | 3.2 ± 0.1 | 3.4 ± 0.2 | 3.3 ± 0.3 | 3.6 ± 0.4 | 5.2 ± 1.2
Female
n | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (spun) (%)
Day 3 | 49.0 ± 0.6 | 47.8 ± 0.7 | 47.6 ± 0.5 | 48.9 ± 0.3 | 49.9 ± 0.5
Day 23 | 51.6 ± 0.5 | 50.9 ± 0.3 | 51.0 ± 0.3 | 52.0 ± 0.2 | 53.3 ± 1.9**
Week 14 | 48.3 ± 0.5 | 48.7 ± 0.4 | 52.6 ± 0.6** | 57.3 ± 0.5** | 59.5 ± 0.3**
Packed cell volume (mL/dL)
Day 3 | 47.6 ± 0.6 | 46.7 ± 0.6 | 46.5 ± 0.5 | 47.6 ± 0.3 | 48.3 ± 0.5
Day 23 | 51.3 ± 0.5 | 50.2 ± 0.3 | 50.5 ± 0.3 | 51.0 ± 0.3 | 51.7 ± 1.7
Week 14 | 49.1 ± 0.5 | 49.5 ± 0.4 | 53.1 ± 0.5** | 57.1 ± 0.5** | 60.0 ± 0.4**
Hemoglobin (g/dL)
Day 3 | 14.8 ± 0.2 | 14.4 ± 0.2 | 14.5 ± 0.2 | 14.7 ± 0.1 | 15.2 ± 0.2
Day 23 | 16.1 ± 0.1 | 15.8 ± 0.1 | 16.0 ± 0.1 | 16.2 ± 0.1 | 16.4 ± 0.6*
Week 14 | 15.5 ± 0.2 | 15.8 ± 0.1* | 16.9 ± 0.2** | 18.3 ± 0.1** | 19.1 ± 0.1**
Erythrocytes (10^6^/µL)
Day 3 | 7.79 ± 0.12 | 7.62 ± 0.13 | 7.65 ± 0.09 | 7.77 ± 0.08 | 8.07 ± 0.12
Day 23 | 8.49 ± 0.09 | 8.24 ± 0.07 | 8.43 ± 0.10 | 8.56 ± 0.05 | 8.75 ± 0.31*
Week 14 | 8.55 ± 0.09 | 8.69 ± 0.06 | 9.30 ± 0.10** | 10.05 ± 0.07** | 10.47 ± 0.09**
Reticulocytes (10^3^/µL)
Day 3 | 489.3 ± 22.4 | 497.7 ± 30.8 | 544.1 ± 28.1 | 511.9 ± 25.5 | 520.0 ± 23.6
Day 23 | 184.1 ± 11.1 | 244.2 ± 9.9** | 212.9 ± 12.4* | 276.7 ± 18.9** | 386.6 ± 20.4**
Week 14 | 202.5 ± 13.0 | 224.5 ± 13.0 | 222.2 ± 8.8 | 246.5 ± 10.8* | 316.7 ± 25.0**
Nucleated erythrocytes/100 leukocytes
Day 3 | 1.3 ± 0.4 | 1.6 ± 0.3 | 1.3 ± 0.7 | 2.5 ± 0.3 | 1.5 ± 0.3
Day 23 | 0.6 ± 0.2 | 0.9 ± 0.3 | 0.7 ± 0.3 | 0.6 ± 0.2 | 1.2 ± 0.4
Week 14 | 0.4 ± 0.2 | 0.2 ± 0.2 | 0.6 ± 0.3 | 0.2 ± 0.2 | 0.3 ± 0.2
Total nucleated cells (10^3^/µL)
Day 3 | 11.7 ± 0.7 | 9.2 ± 0.4* | 10.0 ± 0.5 | 9.6 ± 0.4 | 9.1 ± 0.6*
Day 23 | 12.7 ± 0.5 | 12.8 ± 0.3 | 12.7 ± 0.4 | 11.3 ± 0.5 | 10.5 ± 0.4**
Week 14 | 6.2 ± 0.3 | 6.3 ± 0.3 | 7.0 ± 0.3 | 6.8 ± 0.3 | 6.6 ± 0.2
Mean cell volume (fL)
Day 3 | 61.1 ± 0.3 | 61.4 ± 0.4 | 60.7 ± 0.3 | 61.3 ± 0.2 | 59.8 ± 0.4
Day 23 | 60.4 ± 0.3 | 60.9 ± 0.3 | 59.9 ± 0.4 | 59.5 ± 0.4 | 59.2 ± 0.3*
Week 14 | 57.4 ± 0.2 | 56.9 ± 0.2 | 57.2 ± 0.2 | 56.8 ± 0.3 | 57.2 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.9 ± 0.1 | 19.0 ± 0.1 | 18.8 ± 0.1
Day 23 | 19.0 ± 0.1 | 19.2 ± 0.1 | 19.0 ± 0.1 | 19.0 ± 0.1 | 18.7 ± 0.1
Week 14 | 18.1 ± 0.1 | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.2 ± 0.1 | 18.3 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 31.0 ± 0.1 | 30.7 ± 0.2 | 31.2 ± 0.2 | 31.0 ± 0.1 | 31.5 ± 0.2
Day 23 | 31.5 ± 0.1 | 31.5 ± 0.1 | 31.8 ± 0.1 | 31.9 ± 0.2 | 31.7 ± 0.2
Week 14 | 31.6 ± 0.1 | 32.0 ± 0.1* | 31.8 ± 0.1 | 32.1 ± 0.2 | 31.9 ± 0.1
Platelets (10^3^/µL)
Day 3 | 905.6 ± 27.8 | 841.4 ± 22.5 | 914.7 ± 18.8 | 912.4 ± 20.1 | 875.0 ± 27.4
Day 23 | 783.1 ± 20.5 | 799.2 ± 13.2 | 763.0 ± 25.7 | 800.7 ± 21.5 | 807.9 ± 22.2
Week 14 | 702.1 ± 8.0 | 660.2 ± 14.7* | 646.6 ± 17.3** | 575.3 ± 16.7**^b^ | 608.0 ± 16.8**
Leukocytes (10^3^/µL)
Day 3 | 11.57 ± 0.66 | 9.09 ± 0.45* | 9.85 ± 0.52 | 9.41 ± 0.38 | 9.00 ± 0.57*
Day 23 | 12.66 ± 0.52 | 12.72 ± 0.30 | 12.61 ± 0.44 | 11.21 ± 0.50 | 10.37 ± 0.40**
Week 14 | 6.16 ± 0.32 | 6.26 ± 0.29 | 6.93 ± 0.35 | 6.80 ± 0.30 | 6.58 ± 0.21
Segmented neutrophils (10^3^/µL)
Day 3 | 0.93 ± 0.06 | 0.88 ± 0.07 | 0.98 ± 0.05 | 1.06 ± 0.03 | 0.98 ± 0.09
Day 23 | 1.16 ± 0.07 | 1.28 ± 0.09 | 1.37 ± 0.10 | 1.07 ± 0.05 | 1.25 ± 0.13
Week 14 | 1.00 ± 0.07 | 1.20 ± 0.09 | 1.32 ± 0.10 | 1.25 ± 0.06 | 1.17 ± 0.04
Bands (10^3^/µL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 3 | 10.33 ± 0.61 | 7.93 ± 0.45* | 8.56 ± 0.48 | 8.10 ± 0.36 | 7.80 ± 0.54*
Day 23 | 11.18 ± 0.52 | 11.12 ± 0.32 | 10.89 ± 0.43 | 9.84 ± 0.44 | 8.82 ± 0.30**
Week 14 | 4.83 ± 0.26 | 4.64 ± 0.20 | 5.36 ± 0.28 | 5.17 ± 0.24 | 4.94 ± 0.22
Monocytes (10^3^/μL)
Day 3 | 0.16 ± 0.03 | 0.14 ± 0.03 | 0.18 ± 0.05 | 0.11 ± 0.03 | 0.09 ± 0.02
Day 23 | 0.14 ± 0.03 | 0.15 ± 0.03 | 0.17 ± 0.03 | 0.15 ± 0.03 | 0.15 ± 0.03
Week 14 | 0.24 ± 0.07 | 0.32 ± 0.06 | 0.14 ± 0.05 | 0.25 ± 0.08 | 0.34 ± 0.05
Basophils (10^3^/μL)
Day 3 | 0.016 ± 0.004 | 0.012 ± 0.004 | 0.017 ± 0.004 | 0.014 ± 0.003 | 0.011 ± 0.003
Day 23 | 0.012 ± 0.003 | 0.024 ± 0.002* | 0.022 ± 0.003 | 0.015 ± 0.003 | 0.012 ± 0.004
Week 14 | 0.006 ± 0.003 | 0.006 ± 0.002 | 0.002 ± 0.001 | 0.007 ± 0.003 | 0.008 ± 0.002
Eosinophils (10^3^/μL)
Day 3 | 0.13 ± 0.02 | 0.13 ± 0.02 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.02
Day 23 | 0.17 ± 0.02 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.14 ± 0.01
Week 14 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.01 | 0.11 ± 0.01
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 10.7 ± 0.6 | 8.7 ± 0.6* | 8.7 ± 0.5 | 9.3 ± 0.4 | 10.8 ± 0.2
Day 23 | 11.8 ± 0.4 | 12.5 ± 0.8 | 12.4 ± 0.4 | 10.3 ± 0.3* | 10.1 ± 0.4*
Week 14 | 15.0 ± 0.4 | 16.7 ± 0.4 | 15.0 ± 0.4 | 15.6 ± 0.6 | 13.5 ± 0.5
Creatinine (mg/dL)
Day 3 | 0.25 ± 0.02 | 0.24 ± 0.02 | 0.23 ± 0.02 | 0.23 ± 0.02 | 0.22 ± 0.01
Day 23 | 0.26 ± 0.02 | 0.28 ± 0.01 | 0.28 ± 0.02 | 0.29 ± 0.01 | 0.29 ± 0.02
Week 14 | 0.39 ± 0.01 | 0.37 ± 0.02 | 0.37 ± 0.02 | 0.39 ± 0.01 | 0.41 ± 0.01
Glucose (mg/dL)
Day 3 | 137 ± 3 | 136 ± 3 | 139 ± 2 | 136 ± 1 | 125 ± 3
Day 23 | 140 ± 4 | 141 ± 2 | 147 ± 7 | 141 ± 3 | 132 ± 5
Week 14 | 130 ± 7 | 133 ± 7 | 131 ± 11 | 112 ± 3 | 123 ± 10
Total protein (g/dL)
Day 3 | 6.2 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.0
Day 23 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1
Week 14 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.4 ± 0.1 | 7.4 ± 0.1* | 7.0 ± 0.1**
Albumin (g/dL)
Day 3 | 4.6 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.0 | 4.4 ± 0.0
Day 23 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.1
Week 14 | 5.3 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.0 | 5.0 ± 0.1**
Globulin (g/dL)
Day 3 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.7 ± 0.1 | 1.6 ± 0.0 | 1.8 ± 0.0**
Day 23 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 1.9 ± 0.0 | 1.9 ± 0.1
Week 14 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.1 | 2.3 ± 0.0 | 2.1 ± 0.1**
Albumin to globulin ratio
Day 3 | 2.8 ± 0.0 | 2.8 ± 0.0 | 2.6 ± 0.1 | 2.7 ± 0.0 | 2.5 ± 0.0**
Day 23 | 2.6 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1
Week 14 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.4 ± 0.0
Cholesterol (mg/dL)
Day 3 | 98 ± 2 | 95 ± 2 | 91 ± 2* | 91 ± 2* | 93 ± 2
Day 23 | 102 ± 3 | 97 ± 2 | 97 ± 2 | 93 ± 3* | 89 ± 3**
Week 14 | 102 ± 3 | 100 ± 2 | 92 ± 3* | 91 ± 3** | 76 ± 2**
Triglycerides (mg/dL)
Day 3 | 63 ± 4 | 60 ± 5 | 59 ± 4 | 63 ± 4 | 78 ± 7
Day 23 | 79 ± 6 | 79 ± 4 | 89 ± 10 | 67 ± 6 | 80 ± 7
Week 14 | 98 ± 10 | 134 ± 15 | 91 ± 9 | 93 ± 8 | 71 ± 3
Alanine aminotransferase (IU/L)
Day 3 | 49 ± 2 | 49 ± 1 | 48 ± 1 | 46 ± 1 | 43 ± 1*
Day 23 | 39 ± 2 | 38 ± 1 | 40 ± 1 | 39 ± 1 | 37 ± 1
Week 14 | 68 ± 6 | 75 ± 6 | 65 ± 6 | 65 ± 5 | 58 ± 6
Alkaline phosphatase (IU/L)
Day 3 | 506 ± 13 | 539 ± 9 | 521 ± 10 | 530 ± 10 | 487 ± 15
Day 23 | 336 ± 10 | 359 ± 7 | 332 ± 10 | 354 ± 9 | 348 ± 13
Week 14 | 203 ± 7 | 216 ± 7 | 208 ± 5 | 225 ± 6 | 202 ± 7
Creatine kinase (IU/L)
Day 3 | 538 ± 60 | 375 ± 36* | 519 ± 74 | 367 ± 18 | 421 ± 39
Day 23 | 431 ± 67 | 323 ± 42 | 411 ± 65 | 340 ± 39 | 393 ± 45
Week 14 | 189 ± 15 | 209 ± 25 | 172 ± 18 | 195 ± 20 | 225 ± 32
Sorbitol dehydrogenase (IU/L)
Day 3 | 15 ± 1 | 14 ± 0 | 14 ± 1 | 14 ± 0 | 13 ± 0**
Day 23 | 17 ± 1 | 18 ± 0 | 19 ± 1* | 17 ± 1 | 16 ± 1
Week 14 | 19 ± 1 | 20 ± 1 | 19 ± 1 | 20 ± 1 | 18 ± 1
Bile salts (µmol/L)
Day 3 | 5.3 ± 0.6 | 5.8 ± 0.8 | 5.5 ± 0.4 | 5.0 ± 0.3 | 6.1 ± 0.7
Day 23 | 4.4 ± 1.0 | 4.0 ± 0.5 | 5.6 ± 1.3 | 4.7 ± 0.6 | 4.9 ± 0.6
Week 14 | 4.8 ± 0.3 | 5.4 ± 0.5 | 5.4 ± 0.8 | 4.6 ± 0.3 | 10.6 ± 2.5

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table F-2 Hematology Data for Mice in the Three-month Inhalation Study of Cobalt Metal^a^

| Chamber Control | 0.625 mg/m^3^ | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^ | 10 mg/m^3^
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (spun) (%) | 50.1 ± 0.4 | 50.6 ± 0.4 | 50.7 ± 0.4 | 51.0 ± 0.3 | 50.7 ± 0.3 | 51.3 ± 0.5
Packed cell volume (%) | 51.3 ± 0.5 | 51.8 ± 0.3 | 51.9 ± 0.5 | 52.3 ± 0.3 | 51.8 ± 0.3 | 52.0 ± 0.5
Hemoglobin (g/dL) | 15.7 ± 0.1 | 15.9 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 16.0 ± 0.1 | 16.2 ± 0.1**
Erythrocytes (106/µL) | 10.51 ± 0.08 | 10.59 ± 0.05 | 10.54 ± 0.08 | 10.61 ± 0.07 | 10.63 ± 0.07 | 10.91 ± 0.14*
Reticulocytes (103/µL) | 238.60 ± 13.00 | 211.70 ± 16.50 | 227.70 ± 21.50 | 254.00 ± 15.30 | 192.90 ± 23.40 | 230.50 ± 16.30
Nucleated erythrocytes/ 100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Total nucleated erythrocytes (10^3^/µL) | 2.9 ± 0.3 | 3.4 ± 0.3 | 3.3 ± 0.4* | 2.8 ± 0.3 | 3.5 ± 0.3 | 3.3 ± 0.2
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0
Mean cell volume (fL) | 48.8 ± 0.2 | 48.9 ± 0.3 | 49.2 ± 0.2 | 49.4 ± 0.2 | 48.7 ± 0.1 | 47.6 ± 0.2
Mean cell hemoglobin (pg) | 14.9 ± 0.1 | 15.0 ± 0.0 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.0 ± 0.1 | 14.8 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 30.5 ± 0.1 | 30.6 ± 0.1 | 30.6 ± 0.1 | 30.5 ± 0.1 | 30.8 ± 0.1 | 31.0 ± 0.1**
Platelets (10^3^/µL) | 903.7 ± 19.5 | 929.8 ± 18.5 | 883.7 ± 13.6 | 919.5 ± 11.7 | 894.7 ± 10.0 | 834.2 ± 11.6**
Leukocytes (10^3^/µL) | 2.85 ± 0.27 | 3.38 ± 0.25 | 3.33 ± 0.36 | 2.76 ± 0.32 | 3.46 ± 0.33 | 3.33 ± 0.23
Segmented neutrophils (10^3^/µL) | 0.34 ± 0.04 | 0.42 ± 0.04 | 0.37 ± 0.06 | 0.36 ± 0.05 | 0.59 ± 0.09* | 0.49 ± 0.03*
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.44 ± 0.24 | 2.86 ± 0.22 | 2.88 ± 0.34 | 2.27 ± 0.27 | 2.74 ± 0.31 | 2.74 ± 0.22
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.08 ± 0.02 | 0.07 ± 0.02 | 0.03 ± 0.01
Basophils (10^3^/µL) | 0.013 ± 0.002 | 0.020 ± 0.005 | 0.014 ± 0.003 | 0.024 ± 0.003 | 0.019 ± 0.003 | 0.019 ± 0.005
Eosinophils (10^3^/µL) | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01
Female
n | 10 | 10 | 10 | 9 | 10 | 10
Hematocrit spun (%) | 49.8 ± 0.7 | 50.2 ± 0.5 | 50.2 ± 0.4 | 50.2 ± 0.6 | 50.2 ± 0.3 | 51.2 ± 0.5
Packed cell volume (%) | 50.9 ± 0.6 | 51.6 ± 0.4 | 51.8 ± 0.4 | 51.4 ± 0.6 | 51.1 ± 0.3 | 52.3 ± 0.4
Hemoglobin (g/dL) | 15.7 ± 0.2 | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.2 | 15.9 ± 0.1 | 16.1 ± 0.1
Erythrocytes (10^6^/µL) | 10.12 ± 0.15 | 10.24 ± 0.08 | 10.25 ± 0.07 | 10.24 ± 0.11 | 10.37 ± 0.06 | 10.60 ± 0.09**
Reticulocytes (10^3^/µL) | 290.00 ± 19.00 | 289.10 ± 24.90 | 250.00 ± 15.30 | 259.40 ± 16.30 | 260.30 ± 13.20 | 281.70 ± 21.20
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Total nucleated erythrocytes (10^3^/µL) | 2.8 ± 0.3 | 3.0 ± 0.4 | 3.2 ± 0.3 | 3.3 ± 0.3 | 3.6 ± 0.2 | 3.3 ± 0.2
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 50.3 ± 0.2 | 50.4 ± 0.1 | 50.6 ± 0.1 | 50.1 ± 0.1 | 49.3 ± 0.2** | 49.4 ± 0.2**
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.5 ± 0.0 | 15.6 ± 0.1 | 15.5 ± 0.1 | 15.3 ± 0.1* | 15.2 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 30.8 ± 0.1 | 30.8 ± 0.1 | 30.8 ± 0.1 | 30.9 ± 0.1 | 31.0 ± 0.1 | 30.8 ± 0.1
Platelets (10^3^/µL) | 755.2 ± 19.5 | 826.6 ± 7.4** | 819.1 ± 9.9* | 811.1 ± 16.4 | 801.1 ± 15.0 | 722.7 ± 35.7
Leukocytes (10^3^/µL) | 2.75 ± 0.30 | 2.98 ± 0.39 | 3.16 ± 0.29 | 3.29 ± 0.27 | 3.57 ± 0.21 | 3.30 ± 0.23
Segmented neutrophils (10^3^/µL) | 0.33 ± 0.04 | 0.38 ± 0.08 | 0.32 ± 0.03 | 0.41 ± 0.06 | 0.58 ± 0.06** | 0.52 ± 0.05**
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.33 ± 0.26 | 2.52 ± 0.31 | 2.74 ± 0.28 | 2.79 ± 0.23 | 2.87 ± 0.17 | 2.65 ± 0.23
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.014 ± 0.003 | 0.010 ± 0.002 | 0.018 ± 0.002 | 0.017 ± 0.002 | 0.019 ± 0.002 | 0.024 ± 0.004*
Eosinophils (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.06 ± 0.01* | 0.07 ± 0.01*

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.