# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those reported by Zeiger et al.^262^ Coded samples of cobalt metal [the same chemical lot (P32 3040-1) that was used in the 2-week, 3-month, and 2-year studies] were incubated with the Salmonella typhimurium (TA98, TA100) and Escherichia coli (WP2 uvrA/pKM101) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following 2 days incubation at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of cobalt metal. The highest dose was limited by toxicity. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^263^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs; mature erythrocytes) in each of five animals per exposure group. In addition, the percentage of circulating polychromatic erythrocytes (PCEs; reticulocytes) in 1,000 total erythrocytes per animal was scored for each exposure group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month study were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

Results of the bacterial mutagenicity tests conducted with cobalt metal are presented in Table E-1 and Table E-2. Cobalt metal (100 to 5,000 μg/plate) gave an equivocal response in S. typhimurium strain TA100 in the absence of S9 activation mix; with 10% rat liver S9, doses up to 7,500 μg/plate did not induce an increase in mutant colonies in TA100. In S. typhimurium strain TA98 without S9, cobalt metal (100 to 3,500 µg/plate) was mutagenic, although the responses observed were weak and not well correlated with dose level; with S9, no mutagenic activity was observed. In E. coli strain WP2 uvrA/pKM101, doses of cobalt metal up to 450 μg/plate were not associated with mutagenic activity, with or without S9. No increases in the frequencies of NCEs were observed in peripheral blood of male or female mice exposed to cobalt metal (0.625 to 10 mg/m^3^) for 3 months by inhalation (Table E-3). No significant alterations in the percentages of reticulocytes were seen in male or female mice, suggesting that exposure to cobalt metal under these conditions did not cause bone marrow toxicity.

Table E-1 Mutagenicity of Cobalt Metal in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 78 ± 2 | 85 ± 7 | 57 ± 5 | 96 ± 4 | 84 ± 8
| 100 | 81 ± 2 | 77 ± 12 | 85 ± 5
| 500 | 97 ± 3 | 146 ± 10 | 107 ± 1 | 101 ± 5 | 83 ± 1
| 1,000 | 91 ± 4 | 165 ± 4 | 133 ± 4 | 97 ± 2 | 92 ± 10^b^
| 2,500 | 86 ± 4 | 128 ± 11 | 118 ± 3 | 80 ± 9 | 80 ± 6^b^
| 5,000 | 84 ± 5 | 25 ± 16 | 104 ± 1 | 85 ± 7 | 44 ± 16^b^
| 7,500 | | | | 96 ± 4 | 55 ± 9^b^
Trial summary | | Negative | Equivocal | Equivocal | Negative | Negative
Positive control^c^ | | 304 ± 1 | 400 ± 62 | 206 ± 2 | 511 ± 15 | 949 ± 38
TA98
| 0 | 35 ± 3 | 22 ± 3 | 19 ± 2 | 34 ± 2 | 28 ± 2 | 29 ± 2
| 100 | 24 ± 4 | 43 ± 7 | 66 ± 5
| 500 | 54 ± 3 | 47 ± 7 | 33 ± 3 | 22 ± 2 | 37 ± 6 | 18 ± 1
| 1,000 | 70 ± 5 | | | 20 ± 1 | 20 ± 1^b^ | 12 ± 1
| 1,500 | | 52 ± 8 | 12 ± 1
| 2,500 | 18 ± 6 | 11 ± 1 | 10 ± 0 | 26 ± 2 | 16 ± 5^b^ | 11 ± 2
| 3,500 | | 2 ± 1 | 0 ± 0
| 5,000 | Toxic | | | 21 ± 1 | 12 ± 4^b^ | 12 ± 2
| 7,500 | | | | 15 ± 2 | 5 ± 2^b^ | 2 ± 1
Trial summary | | Equivocal | Positive | Positive | Negative | Negative | Negative
Positive control | | 517 ± 30 | 254 ± 20 | 461 ± 18 | 353 ± 28 | 751 ± 72 | 474 ± 44

Table E-2 Mutagenicity of Cobalt Metal in Bacterial Tester Strains (Escherichia coli)

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | Without S9
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 201 ± 7 | 197 ± 9 | 272 ± 4 | 163 ± 13
| 5 | | | 283 ± 13
| 25 | 148 ± 9 | 238 ± 6 | 297 ± 9
| 50 | 90 ± 8 | 184 ± 16 | 268 ± 1 | 237 ± 5
| 75 | | | 243 ± 3
| 100 | 134 ± 9 | 42 ± 1 | 224 ± 2 | 206 ± 22
| 150 | 0 ± 0 | 0 ± 0 | | 235 ± 4
| 200 | 0 ± 0 | 0 ± 0
| 300 | | | | Toxic
| 450 | | | | Toxic
| Trial summary | Negative | Negative | Negative | Negative
| Positive control | 1,237 ± 56 | 1,531 ± 43 | 1,981 ± 23 | 1,485 ± 205
| | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
| 0 | 233 ± 4 | 250 ± 10 | 291 ± 2 | 220 ± 37
| 25 | | | 319 ± 9
| 50 | 58 ± 6 | 238 ± 9 | 278 ± 10 | 239 ± 6
| 75 | | | 276 ± 10
| 100 | 41 ± 3 | 175 ± 4 | 255 ± 3 | 130 ± 7
| 150 | 16 ± 4 | 73 ± 6 | 261 ± 4 | 220 ± 18
| 300 | 1 ± 1 | 4 ± 1 | | Toxic
| 450 | 1 ± 1 | 1 ± 0 | | Toxic
| Trial summary | Negative | Negative | Negative | Negative
| Positive control | 855 ± 5 | 886 ± 9 | 1,172 ± 36 | 1,017 ± 151

^a^ Study was performed at SITEK Research Laboratories. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluorene (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Exposure to Cobalt Metal by Inhalation for Three Months^a^

| Dose (mg/m^3^) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Air^d^ | 0 | 5 | 2.40 ± 0.33 | | 2.56 ± 0.17
Cobalt metal | 0.625 | 5 | 2.40 ± 0.33 | 0.5000 | 3.04 ± 0.29
| 1.25 | 5 | 2.30 ± 0.37 | 0.5581 | 2.64 ± 0.14
| 2.5 | 5 | 3.10 ± 0.19 | 0.1723 | 2.70 ± 0.15
| 5 | 5 | 2.80 ± 0.34 | 0.2893 | 2.34 ± 0.02
| 10 | 5 | 2.80 ± 0.37 | 0.2893 | 2.64 ± 0.07
| | | P = 0.236^e^
Female
Air | 0 | 5 | 2.50 ± 0.35 | | 2.62 ± 0.18
Cobalt metal | 0.625 | 5 | 2.60 ± 0.29 | 0.4442 | 2.64 ± 0.29
| 1.25 | 5 | 2.00 ± 0.22 | 0.7722 | 2.54 ± 0.16
| 2.5 | 5 | 2.80 ± 0.30 | 0.3399 | 2.32 ± 0.15
| 5 | 5 | 2.00 ± 0.32 | 0.7722 | 2.30 ± 0.11
| 10 | 5 | 2.30 ± 0.34 | 0.6137 | 2.22 ± 0.20
| | | P = 0.664

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^263^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.005.

^d^ Chamber control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.