# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of Cobalt Metal

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 9 | 12 | 19 | 21
Natural deaths | 5 | 2 | 4 | 3
Survivors
Died last week of study | – | 2 | – | –
Terminal kill | 36 | 34 | 27 | 26
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (44) | (41) | (38) | (46)
Intestine large, cecum | (46) | (47) | (49) | (48)
Intestine large, colon | (46) | (48) | (49) | (49)
Intestine large, rectum | (46) | (48) | (48) | (49)
Intestine small, duodenum | (45) | (47) | (48) | (49)
Intestine small, ileum | (45) | (46) | (49) | (49)
Carcinoma | 1 (2%) | – | – | –
Intestine small, jejunum | (45) | (47) | (49) | (49)
Carcinoma | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma | 2 (4%) | 1 (2%) | – | –
Hepatocellular adenoma | 9 (18%) | 13 (26%) | 6 (12%) | 2 (4%)
Hepatocellular adenoma, multiple | 10 (20%) | 5 (10%) | 4 (8%)
Hepatocellular carcinoma | 6 (12%) | 4 (8%) | 5 (10%) | 2 (4%)
Hepatocellular carcinoma, multiple | 4 (8%) | 3 (6%) | – | –
Hepatocholangiocarcinoma | – | 1 (2%) | – | –
Mast cell tumor malignant | 1 (2%) | – | – | –
Mesentery | (18) | (13) | (10) | (8)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (13%)
Sarcoma | – | 1 (8%) | – | –
Pancreas | (50) | (50) | (50) | (49)
Sarcoma, metastatic, skin | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (48) | (50) | (49) | (49)
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | 2 (4%)
Hemangiosarcoma | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (48)
Subcapsular, carcinoma | – | – | 2 (4%) | –
Adrenal medulla | (50) | (50) | (49) | (48)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (49)
Parathyroid gland | (28) | (28) | (24) | (32)
Pituitary gland | (47) | (50) | (48) | (49)
Pars distalis, adenoma | 3 (6%) | 4 (8%) | 1 (2%) | –
Pars intermedia, adenoma | – | 1 (2%) | – | –
Thyroid gland | (50) | (50) | (50) | (49)
Follicular cell, adenoma | 1 (2%) | – | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (43) | (44) | (41) | (43)
Ovary | (48) | (50) | (50) | (50)
Cystadenoma | 1 (2%) | 4 (8%) | – | 3 (6%)
Hemangiosarcoma | – | 1 (2%) | 1 (2%) | –
Osteosarcoma, metastatic, bone | – | – | 1 (2%) | –
Yolk sac carcinoma | 1 (2%) | – | – | –
Uterus | (49) | (50) | (50) | (50)
Hemangiosarcoma | – | 2 (4%) | – | –
Polyp stromal | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Endometrium, carcinoma | – | 1 (2%) | – | –
Vagina | (0) | (0) | (1) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Mast cell tumor malignant | 1 (2%) | – | – | –
Lymph node | (11) | (8) | (7) | (1)
Lumbar, carcinoma, metastatic, kidney | 1 (9%) | – | – | –
Lymph node, bronchial | (22) | (33) | (34) | (22)
Alveolar/bronchiolar carcinoma, metastatic, lung | 2 (9%) | 1 (3%) | 1 (3%) | 1 (5%)
Lymph node, mandibular | (40) | (41) | (38) | (31)
Mast cell tumor malignant | 1 (3%) | – | – | –
Lymph node, mediastinal | (42) | (39) | (44) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | 2 (5%) | 1 (3%) | 3 (7%) | 3 (7%)
Mast cell tumor malignant | 1 (2%) | – | – | –
Lymph node, mesenteric | (49) | (49) | (47) | (47)
Sarcoma, metastatic, skin | 1 (2%) | 1 (2%) | – | –
Spleen | (49) | (49) | (48) | (49)
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | 2 (4%) | – | 1 (2%) | –
Mast cell tumor malignant | 1 (2%) | – | – | –
Thymus | (46) | (46) | (46) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | 2 (4%)
Neoplasm NOS | 1 (2%) | – | – | –
Osteosarcoma, metastatic, bone | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (48) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | 1 (2%) | –
Skin | (50) | (50) | (49) | (50)
Subcutaneous tissue, hemangioma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | 2 (4%) | – | –
Subcutaneous tissue, neural crest tumor | 1 (2%) | – | – | –
Subcutaneous tissue, sarcoma | 2 (4%) | 2 (4%) | 2 (4%) | –
Subcutaneous tissue, sarcoma, multiple | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | – | – | 1 (2%) | –
Vertebra, schwannoma malignant, metastatic, peripheral nerve | – | – | 1 (2%) | –
Skeletal muscle | (0) | (2) | (1) | (0)
Thoracic, alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (50%) | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (0) | (0) | (1) | (0)
Schwannoma malignant | – | – | 1 (100%) | –
Respiratory System
Larynx | (47) | (50) | (50) | (47)
Lung | (49) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 8 (16%) | 8 (16%) | 9 (18%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | 1 (2%)
Alveolar/bronchiolar carcinoma | 4 (8%) | 18 (36%) | 18 (36%) | 19 (38%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | 7 (14%) | 20 (40%) | 24 (48%)
Hepatocellular carcinoma, metastatic, liver | 5 (10%) | 2 (4%) | 1 (2%) | –
Osteosarcoma, metastatic, bone | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Pleura | (0) | (1) | (0) | (1)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (100%) | – | 1 (100%)
Trachea | (48) | (50) | (48) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Special Senses System
Eye | (46) | (46) | (48) | (48)
Carcinoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Harderian gland | (49) | (49) | (49) | (50)
Adenoma | 3 (6%) | 5 (10%) | 4 (8%) | 3 (6%)
Carcinoma | – | 2 (4%) | – | –
Zymbal’s gland | (0) | (1) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (4%)
Renal tubule, adenoma | – | – | – | 1 (2%)
Transitional epithelium, carcinoma | 1 (2%) | – | – | –
Urinary bladder | (49) | (49) | (48) | (49)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Lymphoma malignant | 14 (28%) | 14 (28%) | 12 (24%) | 4 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 40 | 47 | 49 | 47
Total primary neoplasms | 81 | 105 | 90 | 72
Total animals with benign neoplasms | 29 | 31 | 20 | 17
Total benign neoplasms | 34 | 44 | 24 | 22
Total animals with malignant neoplasms | 31 | 41 | 46 | 44
Total malignant neoplasms | 45 | 61 | 66 | 50
Total animals with metastatic neoplasms | 8 | 5 | 8 | 4
Total metastatic neoplasms | 14 | 8 | 11 | 12
Total animals with uncertain neoplasms- benign or malignant | 2 | – | – | –
Total uncertain neoplasms | 2 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Harderian Gland: Adenoma
Overall rate^a^ | 3/50 (6%) | 5/50 (10%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate^b^ | 6.8% | 11.2% | 9.3% | 7.4%
Terminal rate^c^ | 2/36 (6%) | 4/35 (11%) | 1/27 (4%) | 1/26 (4%)
First incidence (days) | 697 | 712 | 562 | 618
Poly-3 test^d^ | P = 0.535N | P = 0.363 | P = 0.487 | P = 0.626
Harderian Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 6.8% | 15.7% | 9.3% | 7.4%
Terminal rate | 2/36 (6%) | 5/35 (14%) | 1/27 (4%) | 1/26 (4%)
First incidence (days) | 697 | 671 | 562 | 618
Poly-3 test | P = 0.438N | P = 0.164 | P = 0.487 | P = 0.626
Liver: Hepatocellular Adenoma
Overall rate | 19/50 (38%) | 18/50 (36%) | 10/50 (20%) | 2/50 (4%)
Adjusted rate | 42.6% | 40.5% | 23.7% | 5.0%
Terminal rate | 16/36 (44%) | 17/35 (49%) | 7/27 (26%) | 2/26 (8%)
First incidence (days) | 499 | 712 | 646 | 731 (T)
Poly-3 test | P < 0.001N | P = 0.505N | P = 0.046N | P < 0.001N
Liver: Hepatocellular Carcinoma
Overall rate | 10/50 (20%) | 7/50 (14%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 22.2% | 15.7% | 11.9% | 4.9%
Terminal rate | 7/36 (19%) | 6/35 (17%) | 3/27 (11%) | 0/26 (0%)
First incidence (days) | 499 | 661 | 646 | 506
Poly-3 test | P = 0.013N | P = 0.302N | P = 0.162N | P = 0.020N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 25/50 (50%) | 21/50 (42%) | 13/50 (26%) | 4/50 (8%)
Adjusted rate | 55.3% | 46.9% | 30.7% | 9.8%
Terminal rate | 20/36 (56%) | 19/35 (54%) | 9/27 (33%) | 2/26 (8%)
First incidence (days) | 499 | 661 | 646 | 506
Poly-3 test | P < 0.001N | P = 0.277N | P = 0.014N | P < 0.001N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/49 (6%) | 9/50 (18%) | 8/50 (16%) | 10/50 (20%)
Adjusted rate | 6.9% | 19.9% | 18.9% | 24.5%
Terminal rate | 3/36 (8%) | 7/35 (20%) | 6/27 (22%) | 6/26 (23%)
First incidence (days) | 731 (T) | 505 | 626 | 593
Poly-3 test | P = 0.037 | P = 0.067 | P = 0.087 | P = 0.024
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 5/49 (10%) | 25/50 (50%) | 38/50 (76%) | 43/50 (86%)
Adjusted rate | 11.3% | 53.8% | 78.9% | 87.7%
Terminal rate | 3/36 (8%) | 18/35 (51%) | 19/27 (70%) | 21/26 (81%)
First incidence (days) | 583 | 537 | 457 | 478
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 8/49 (16%) | 30/50 (60%) | 41/50 (82%) | 45/50 (90%)
Adjusted rate | 18.0% | 63.7% | 84.6% | 91.6%
Terminal rate | 6/36 (17%) | 22/35 (63%) | 21/27 (78%) | 22/26 (85%)
First incidence (days) | 583 | 505 | 457 | 478
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Ovary: Cystadenoma
Overall rate | 1/48 (2%) | 4/50 (8%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.3% | 8.9% | 0.0% | 7.4%
Terminal rate | 1/35 (3%) | 3/35 (9%) | 0/27 (0%) | 2/26 (8%)
First incidence (days) | 731 (T) | 614 | –^e^ | 618
Poly-3 test | P = 0.374 | P = 0.194 | P = 0.505N | P = 0.285
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 3/47 (6%) | 4/50 (8%) | 1/48 (2%) | 0/49 (0%)
Adjusted rate | 7.2% | 9.0% | 2.5% | 0.0%
Terminal rate | 2/34 (6%) | 3/35 (9%) | 0/27 (0%) | 0/25 (0%)
First incidence (days) | 649 | 671 | 646 | –
Poly-3 test | P = 0.052N | P = 0.534 | P = 0.321N | P = 0.132N
Skin (Subcutaneous Tissue): Sarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 4.5% | 6.6% | 4.8% | 0.0%
Terminal rate | 1/36 (3%) | 0/35 (0%) | 0/27 (0%) | 0/26 (0%)
First incidence (days) | 649 | 506 | 626 | –
Poly-3 test | P = 0.163N | P = 0.517 | P = 0.677 | P = 0.260N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 6.9% | 13.5% | 7.2% | 0.0%
Terminal rate | 2/36 (6%) | 5/35 (14%) | 2/27 (7%) | 0/26 (0%)
First incidence (days) | 725 | 712 | 709 | –
Poly-3 test | P = 0.070N | P = 0.249 | P = 0.639 | P = 0.136N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 6.9% | 15.6% | 7.2% | 2.5%
Terminal rate | 2/36 (6%) | 5/35 (14%) | 2/27 (7%) | 0/26 (0%)
First incidence (days) | 725 | 649 | 709 | 660
Poly-3 test | P = 0.140N | P = 0.165 | P = 0.639 | P = 0.336N
All Organs: Malignant Lymphoma
Overall rate | 14/50 (28%) | 14/50 (28%) | 12/50 (24%) | 4/50 (8%)
Adjusted rate | 31.7% | 29.8% | 28.0% | 10.0%
Terminal rate | 11/36 (31%) | 8/35 (23%) | 8/27 (30%) | 3/26 (12%)
First incidence (days) | 697 | 391 | 537 | 673
Poly-3 test | P = 0.011N | P = 0.513N | P = 0.444N | P = 0.013N
All Organs: Benign Neoplasms
Overall rate | 29/50 (58%) | 31/50 (62%) | 20/50 (40%) | 17/50 (34%)
Adjusted rate | 63.0% | 66.1% | 45.8% | 40.5%
Terminal rate | 23/36 (64%) | 24/35 (69%) | 14/27 (52%) | 10/26 (39%)
First incidence (days) | 223 | 505 | 562 | 593
Poly-3 test | P = 0.005N | P = 0.460 | P = 0.070N | P = 0.024N
All Organs: Malignant Neoplasms
Overall rate | 31/50 (62%) | 41/50 (82%) | 46/50 (92%) | 44/50 (88%)
Adjusted rate | 66.1% | 82.0% | 92.0% | 89.8%
Terminal rate | 21/36 (58%) | 26/35 (74%) | 23/27 (85%) | 22/26 (85%)
First incidence (days) | 499 | 391 | 457 | 478
Poly-3 test | P = 0.002 | P = 0.057 | P < 0.001 | P = 0.004
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 47/50 (94%) | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 83.6% | 94.0% | 98.0% | 95.7%
Terminal rate | 29/36 (81%) | 32/35 (91%) | 26/27 (96%) | 24/26 (92%)
First incidence (days) | 223 | 391 | 457 | 478
Poly-3 test | P = 0.026 | P = 0.088 | P = 0.012 | P = 0.045

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table D-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 1/50 | 0/50 | 1/50
CIMSTAR 3800 (May 2008) | 1/50 | 4/50 | 4/50
Cobalt metal (May 2006) | 3/49 | 5/49 | 8/49
Diethylamine (August 2003) | 2/50 | 3/50 | 5/50
Tetralin (June 2003) | 6/50 | 0/50 | 6/50
Vinylidene chloride (June 2005) | 3/50 | 1/50 | 4/50
Total (%) | 16/299 (5.4%) | 13/299 (4.4%) | 28/299 (9.4%)
Mean ± standard deviation | 5.4% ± 3.7% | 4.4% ± 4.3% | 9.4% ± 4.8%
Range | 2%–12% | 0%–10% | 2%–16%
Overall Historical Incidence: All Routes
Total (%) | 54/949 (5.7%) | 38/949 (4.0%) | 90/949 (9.5%)
Mean ± standard deviation | 5.7% ± 3.6% | 4.0% ± 3.6% | 9.5% ± 4.8%
Range | 0%–12% | 0%–14% | 2%–22%

^a^ Data as of May 2013.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 9 | 12 | 19 | 21
Natural deaths | 5 | 2 | 4 | 3
Survivors
Died last week of study | – | 2 | – | –
Terminal kill | 36 | 34 | 27 | 26
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (44) | (41) | (38) | (46)
Intestine large, cecum | (46) | (47) | (49) | (48)
Hemorrhage | 1 (2%) | – | – | –
Intestine large, colon | (46) | (48) | (49) | (49)
Intestine large, rectum | (46) | (48) | (48) | (49)
Intestine small, duodenum | (45) | (47) | (48) | (49)
Inflammation, acute | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Intestine small, ileum | (45) | (46) | (49) | (49)
Intestine small, jejunum | (45) | (47) | (49) | (49)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Basophilic focus | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Clear cell focus | 1 (2%) | 1 (2%) | 1 (2%) | –
Eosinophilic focus | 3 (6%) | 2 (4%) | 4 (8%) | –
Fatty change | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hepatodiaphragmatic nodule | – | – | 1 (2%) | 1 (2%)
Mixed cell focus | – | 1 (2%) | 1 (2%) | –
Necrosis | 6 (12%) | 3 (6%) | 2 (4%) | 1 (2%)
Tension lipidosis | 5 (10%) | 5 (10%) | 3 (6%) | 2 (4%)
Vacuolization cytoplasmic | 1 (2%) | 1 (2%) | – | 1 (2%)
Bile duct, cyst | – | – | – | 1 (2%)
Mesentery | (18) | (13) | (10) | (8)
Congestion | – | – | 1 (10%) | –
Inflammation, chronic active | – | 1 (8%) | – | –
Fat, hemorrhage | 1 (6%) | – | – | –
Fat, necrosis | 18 (100%) | 11 (85%) | 10 (100%) | 8 (100%)
Pancreas | (50) | (50) | (50) | (49)
Atrophy | 1 (2%) | – | 2 (4%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | – | 3 (6%) | 1 (2%)
Metaplasia, hepatocyte | – | – | – | 1 (2%)
Ulcer | 2 (4%) | 2 (4%) | 1 (2%) | –
Stomach, glandular | (48) | (50) | (49) | (49)
Metaplasia, hepatocyte | – | – | 1 (2%) | –
Ulcer | 1 (2%) | 2 (4%) | – | –
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 6 (12%) | 3 (6%) | 11 (22%) | 9 (18%)
Inflammation, suppurative | – | – | – | 1 (2%)
Mineralization | 1 (2%) | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | 1 (2%)
Thrombosis | 1 (2%) | – | – | 1 (2%)
Capillary, hyperplasia | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (48)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Hypertrophy | – | 2 (4%) | – | –
Adrenal medulla | (50) | (50) | (49) | (48)
Hyperplasia | 2 (4%) | 1 (2%) | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (49)
Hyperplasia | – | 2 (4%) | – | 1 (2%)
Parathyroid gland | (28) | (28) | (24) | (32)
Pituitary gland | (47) | (50) | (48) | (49)
Pars distalis, angiectasis | 2 (4%) | 1 (2%) | – | –
Pars distalis, hyperplasia | 12 (26%) | 5 (10%) | 6 (13%) | 5 (10%)
Thyroid gland | (50) | (50) | (50) | (49)
Follicular cell, hyperplasia | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (43) | (44) | (41) | (43)
Ovary | (48) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Cyst | 8 (17%) | 2 (4%) | 11 (22%) | 10 (20%)
Inflammation, suppurative | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | 1 (2%) | –
Uterus | (49) | (50) | (50) | (50)
Angiectasis | – | 4 (8%) | – | –
Inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Thrombosis | – | 2 (4%) | – | 1 (2%)
Endometrium, hyperplasia, cystic | 41 (84%) | 38 (76%) | 40 (80%) | 34 (68%)
Vagina | (0) | (0) | (1) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (11) | (8) | (7) | (1)
Iliac, ectasia | 3 (27%) | – | 1 (14%) | –
Lumbar, ectasia | – | 1 (13%) | – | –
Renal, ectasia | 2 (18%) | 2 (25%) | – | –
Renal, erythrophagocytosis | – | 1 (13%) | – | –
Renal, hyperplasia, lymphoid | 1 (9%) | – | – | –
Lymph node, bronchial | (22) | (33) | (34) | (22)
Inflammation, suppurative | – | – | – | 1 (5%)
Lymph node, mandibular | (40) | (41) | (38) | (31)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Lymph node, mediastinal | (42) | (39) | (44) | (46)
Hyperplasia, lymphoid | 1 (2%) | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Lymph node, mesenteric | (49) | (49) | (47) | (47)
Ectasia | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | – | –
Spleen | (49) | (49) | (48) | (49)
Hematopoietic cell proliferation | 5 (10%) | 4 (8%) | 4 (8%) | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Necrosis | 1 (2%) | – | – | –
Thymus | (46) | (46) | (46) | (46)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (48) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Skin | (50) | (50) | (49) | (50)
Inflammation, chronic active | 2 (4%) | 1 (2%) | 2 (4%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | 1 (2%) | – | – | –
Skeletal muscle | (0) | (2) | (1) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Meninges, infiltration cellular, mononuclear cell | – | 2 (4%) | – | –
Peripheral nerve | (0) | (0) | (1) | (0)
Respiratory System
Larynx | (47) | (50) | (50) | (47)
Inflammation, suppurative | – | 1 (2%) | – | 2 (4%)
Inflammation, chronic | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Respiratory epithelium, metaplasia, squamous | 2 (4%) | 49 (98%) | 50 (100%) | 47 (100%)
Respiratory epithelium, vacuolization cytoplasmic | – | 24 (48%) | 31 (62%) | 34 (72%)
Squamous epithelium, erosion | 1 (2%) | 2 (4%) | 7 (14%) | 4 (9%)
Squamous epithelium, hyperplasia | 2 (4%) | 13 (26%) | 21 (42%) | 21 (45%)
Lung | (49) | (50) | (50) | (50)
Infiltration cellular, histiocyte | – | – | 1 (2%) | –
Inflammation, suppurative | – | 3 (6%) | 2 (4%) | 15 (30%)
Proteinosis | – | 45 (90%) | 50 (100%) | 50 (100%)
Thrombosis | – | – | 1 (2%) | –
Alveolar/bronchiolar epithelium, hyperplasia | – | 49 (98%) | 49 (98%) | 50 (100%)
Alveolar/bronchiolar epithelium, vacuolization cytoplasmic | – | 48 (96%) | 49 (98%) | 48 (96%)
Alveolar epithelium, hyperplasia | 2 (4%) | 27 (54%) | 26 (52%) | 41 (82%)
Alveolar epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 10 (20%) | 49 (98%) | 50 (100%) | 49 (98%)
Bronchiole, epithelium, erosion | – | – | 4 (8%) | 3 (6%)
Bronchiole, epithelium, hyperplasia | – | 3 (6%) | 12 (24%) | 26 (52%)
Nose | (50) | (50) | (50) | (50)
Inflammation, suppurative | 3 (6%) | 47 (94%) | 50 (100%) | 50 (100%)
Olfactory epithelium, atrophy | 4 (8%) | 44 (88%) | 39 (78%) | 24 (48%)
Olfactory epithelium, hyperplasia | 1 (2%) | 22 (44%) | 16 (32%) | 8 (16%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | 26 (52%) | 44 (88%) | 50 (100%)
Olfactory epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Olfactory epithelium, respiratory metaplasia, atypical | – | 18 (36%) | 14 (28%) | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 12 (24%) | 38 (76%) | 40 (80%) | 10 (20%)
Respiratory epithelium, hyperplasia | 43 (86%) | 40 (80%) | 40 (80%) | 9 (18%)
Respiratory epithelium, hyperplasia, histiocytic | 1 (2%) | – | – | –
Respiratory epithelium, metaplasia, squamous | – | 49 (98%) | 49 (98%) | 50 (100%)
Respiratory epithelium, vacuolization cytoplasmic | – | 40 (80%) | 47 (94%) | 47 (94%)
Squamous epithelium, erosion | – | 7 (14%) | 1 (2%) | 5 (10%)
Turbinate, atrophy | – | 44 (88%) | 50 (100%) | 50 (100%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (48) | (50) | (48) | (49)
Inflammation, suppurative | – | 1 (2%) | – | 1 (2%)
Epithelium, vacuolization cytoplasmic | – | 26 (52%) | 37 (77%) | 39 (80%)
Special Senses System
Eye | (46) | (46) | (48) | (48)
Phthisis bulbi | – | 2 (4%) | – | –
Cornea, inflammation, chronic active | – | 2 (4%) | 1 (2%) | –
Harderian gland | (49) | (49) | (49) | (50)
Hyperplasia | 4 (8%) | 1 (2%) | 1 (2%) | –
Zymbal’s gland | (0) | (1) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Amyloid deposition | 1 (2%) | – | – | –
Cyst | 1 (2%) | – | – | –
Infarct | – | 2 (4%) | 2 (4%) | 1 (2%)
Nephropathy | 35 (70%) | 31 (62%) | 20 (40%) | 19 (38%)
Renal tubule, hyperplasia | 1 (2%) | – | – | –
Renal tubule, necrosis | 1 (2%) | 1 (2%) | – | –
Urinary bladder | (49) | (49) | (48) | (49)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.