# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of Cobalt Metal

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 5 | 13 | 12 | 17
Natural deaths | 6 | 6 | 9 | 8
Survivors
Died last week of study | – | – | 1 | 3
Terminal kill | 39 | 31 | 28 | 22
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (43) | (37) | (34) | (35)
Intestine large, cecum | (45) | (45) | (44) | (45)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Intestine large, colon | (47) | (45) | (45) | (46)
Intestine large, rectum | (44) | (44) | (45) | (48)
Intestine small, duodenum | (45) | (44) | (44) | (44)
Adenoma | 1 (2%) | – | – | –
Intestine small, ileum | (45) | (45) | (43) | (44)
Adenoma | 1 (2%) | – | – | –
Intestine small, jejunum | (45) | (45) | (43) | (44)
Liver | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | 1 (2%)
Cholangiocarcinoma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | 3 (6%) | 1 (2%) | 3 (6%) | –
Hemangiosarcoma, multiple | 1 (2%) | 1 (2%) | – | –
Hepatoblastoma | 2 (4%) | 2 (4%) | – | –
Hepatocellular adenoma | 15 (30%) | 9 (18%) | 13 (26%) | 11 (22%)
Hepatocellular adenoma, multiple | 13 (26%) | 16 (32%) | 8 (16%) | 1 (2%)
Hepatocellular carcinoma | 15 (30%) | 15 (30%) | 11 (22%) | 8 (16%)
Hepatocellular carcinoma, multiple | 10 (20%) | 6 (12%) | 3 (6%) | 1 (2%)
Sarcoma, metastatic, mesentery | – | 1 (2%) | – | –
Mesentery | (5) | (5) | (5) | (3)
Sarcoma | – | 1 (20%) | – | –
Pancreas | (50) | (47) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Carcinoma, metastatic, islets, pancreatic | – | 1 (2%) | – | –
Salivary glands | (50) | (49) | (50) | (50)
Stomach, forestomach | (50) | (48) | (50) | (50)
Sarcoma, metastatic, mesentery | – | 1 (2%) | – | –
Stomach, glandular | (48) | (46) | (48) | (49)
Sarcoma, metastatic, mesentery | – | 1 (2%) | – | –
Tooth | (8) | (2) | (2) | (1)
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | 1 (2%) | 2 (4%)
Hemangiosarcoma | 1 (2%) | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Bilateral, subcapsular, adenoma | 1 (2%) | – | – | –
Subcapsular, adenoma | – | 4 (8%) | 1 (2%) | 1 (2%)
Adrenal medulla | (50) | (49) | (50) | (48)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Islets, pancreatic | (49) | (47) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinoma | – | 2 (4%) | – | –
Parathyroid gland | (29) | (25) | (26) | (27)
Pituitary gland | (47) | (49) | (48) | (48)
Thyroid gland | (49) | (49) | (50) | (49)
General Body System
Tissue NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (0) | (1) | (0) | (1)
Adenoma | – | 1 (100%) | – | –
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (100%)
Epididymis | (50) | (49) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | – | 1 (2%) | – | –
Penis | (0) | (0) | (0) | (1)
Preputial gland | (49) | (50) | (49) | (50)
Prostate | (50) | (49) | (48) | (50)
Seminal vesicle | (48) | (48) | (49) | (50)
Testes | (50) | (49) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | 1 (2%)
Interstitial cell, adenoma | 1 (2%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (49)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Lymph node | (2) | (0) | (1) | (1)
Lymph node, bronchial | (26) | (32) | (20) | (24)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (6%) | 1 (5%) | 2 (8%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (3%) | – | –
Lymph node, mandibular | (37) | (23) | (27) | (37)
Lymph node, mediastinal | (34) | (34) | (36) | (44)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (6%) | 3 (8%) | –
Hepatocellular carcinoma, metastatic, liver | – | 1 (3%) | 1 (3%) | –
Lymph node, mesenteric | (47) | (44) | (44) | (42)
Hemangiosarcoma | – | – | 1 (2%) | –
Spleen | (50) | (48) | (49) | (48)
Hemangioma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | 3 (6%) | – | 4 (8%) | 3 (6%)
Thymus | (42) | (44) | (40) | (38)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (3%) | 1 (3%)
Hemangiosarcoma | – | – | 1 (3%) | –
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Integumentary System
Skin | (50) | (50) | (50) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Subcutaneous tissue, fibrous histiocytoma | – | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, neural crest tumor | 1 (2%) | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (49) | (50) | (50)
Skeletal muscle | (0) | (3) | (3) | (1)
Head, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (33%) | –
Thoracic, alveolar/bronchiolar carcinoma, metastatic, lung | – | 3 (100%) | 3 (100%) | 1 (100%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (1) | (0) | (0) | (1)
Spinal cord | (1) | (0) | (0) | (1)
Respiratory System
Larynx | (48) | (47) | (49) | (50)
Lung | (50) | (49) | (50) | (50)
Alveolar/bronchiolar adenoma | 7 (14%) | 10 (20%) | 14 (28%) | 3 (6%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | 1 (2%) | –
Alveolar/bronchiolar carcinoma | 8 (16%) | 20 (41%) | 18 (36%) | 10 (20%)
Alveolar/bronchiolar carcinoma, multiple | 3 (6%) | 18 (37%) | 24 (48%) | 36 (72%)
Carcinoma, metastatic, islets, pancreatic | – | 1 (2%) | – | –
Cholangiocarcinoma, metastatic, liver | – | – | – | 1 (2%)
Hepatoblastoma, metastatic, liver | – | 2 (4%) | – | –
Hepatocellular carcinoma, metastatic, liver | 9 (18%) | 6 (12%) | 7 (14%) | 1 (2%)
Nose | (50) | (49) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Glands, olfactory epithelium, adenoma | – | 1 (2%) | – | –
Trachea | (48) | (47) | (48) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Special Senses System
Eye | (47) | (46) | (43) | (45)
Harderian gland | (49) | (48) | (48) | (50)
Adenoma | 6 (12%) | 3 (6%) | 4 (8%) | 4 (8%)
Carcinoma | 2 (4%) | 1 (2%) | – | –
Zymbal’s gland | (0) | (1) | (0) | (0)
Urinary System
Kidney | (50) | (49) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 3 (6%) | 1 (2%) | 2 (4%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Urinary bladder | (48) | (48) | (50) | (47)
Hemangiosarcoma | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | – | –
Lymphoma malignant | 4 (8%) | 1 (2%) | 1 (2%) | 3 (6%)
Neoplasm Summary
Total animals with primary neoplasmsc | 45 | 49 | 50 | 49
Total primary neoplasms | 100 | 119 | 113 | 83
Total animals with benign neoplasms | 35 | 32 | 34 | 19
Total benign neoplasms | 45 | 47 | 41 | 21
Total animals with malignant neoplasms | 36 | 46 | 46 | 48
Total malignant neoplasms | 54 | 72 | 71 | 62
Total animals with metastatic neoplasms | 9 | 13 | 11 | 5
Total metastatic neoplasms | 10 | 33 | 21 | 17
Total animals with uncertain neoplasms- benign or malignant | 1 | – | 1 | –
Total uncertain neoplasms | 1 | – | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Adrenal Cortex: Adenoma
Overall rate^a^ | 1/50 (2%) | 4/49 (8%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate^b^ | 2.1% | 9.1% | 2.4% | 2.5%
Terminal rate^c^ | 1/39 (3%) | 3/31 (10%) | 1/29 (3%) | 1/25 (4%)
First incidence (days) | 729 (T) | 715 | 729 (T) | 729 (T)
Poly-3 test^d^ | P = 0.444N | P = 0.157 | P = 0.730 | P = 0.724
Harderian Gland: Adenoma
Overall rate | 6/50 (12%) | 3/50 (6%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 12.6% | 6.8% | 9.6% | 9.7%
Terminal rate | 5/39 (13%) | 3/31 (10%) | 3/29 (10%) | 2/25 (8%)
First incidence (days) | 651 | 729 (T) | 706 | 635
Poly-3 test | P = 0.454N | P = 0.281N | P = 0.460N | P = 0.465N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 4/50 (8%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 16.6% | 9.0% | 9.6% | 9.7%
Terminal rate | 6/39 (15%) | 4/31 (13%) | 3/29 (10%) | 2/25 (8%)
First incidence (days) | 646 | 729 (T) | 706 | 635
Poly-3 test | P = 0.224N | P = 0.220N | P = 0.255N | P = 0.260N
Liver: Hemangiosarcoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 8.4% | 4.5% | 7.1% | 0.0%
Terminal rate | 2/39 (5%) | 1/31 (3%) | 0/29 (0%) | 0/25 (0%)
First incidence (days) | 682 | 611 | 597 | –^e^
Poly-3 test | P = 0.083N | P = 0.369N | P = 0.563N | P = 0.084N
Liver: Hepatocellular Adenoma
Overall rate | 28/50 (56%) | 25/50 (50%) | 21/50 (42%) | 12/50 (24%)
Adjusted rate | 57.5% | 56.0% | 46.7% | 29.1%
Terminal rate | 22/39 (56%) | 20/31 (65%) | 14/29 (48%) | 8/25 (32%)
First incidence (days) | 646 | 684 | 361 | 635
Poly-3 test | P = 0.002N | P = 0.527N | P = 0.199N | P = 0.005N
Liver: Hepatocellular Carcinoma
Overall rate | 25/50 (50%) | 21/50 (42%) | 14/50 (28%) | 9/50 (18%)
Adjusted rate | 50.0% | 43.6% | 31.5% | 21.9%
Terminal rate | 14/39 (36%) | 9/31 (29%) | 5/29 (17%) | 6/25 (24%)
First incidence (days) | 561 | 457 | 394 | 649
Poly-3 test | P = 0.002N | P = 0.334N | P = 0.052N | P = 0.004N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 38/50 (76%) | 38/50 (76%) | 32/50 (64%) | 18/50 (36%)
Adjusted rate | 76.0% | 78.7% | 68.4% | 43.1%
Terminal rate | 27/39 (69%) | 23/31 (74%) | 19/29 (66%) | 11/25 (44%)
First incidence (days) | 561 | 457 | 361 | 635
Poly-3 test | P < 0.001N | P = 0.469 | P = 0.269N | P < 0.001N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 27/50 (54%) | 22/50 (44%) | 14/50 (28%) | 9/50 (18%)
Adjusted rate | 54.0% | 45.7% | 31.5% | 21.9%
Terminal rate | 16/39 (41%) | 10/31 (32%) | 5/29 (17%) | 6/25 (24%)
First incidence (days) | 561 | 457 | 394 | 649
Poly-3 test | P < 0.001N | P = 0.268N | P = 0.021N | P < 0.001N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 39/50 (78%) | 39/50 (78%) | 32/50 (64%) | 18/50 (36%)
Adjusted rate | 78.0% | 80.8% | 68.4% | 43.1%
Terminal rate | 28/39 (72%) | 24/31 (77%) | 19/29 (66%) | 11/25 (44%)
First incidence (days) | 561 | 457 | 361 | 635
Poly-3 test | P < 0.001N | P = 0.464 | P = 0.197N | P < 0.001N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 7/50 (14%) | 11/49 (22%) | 15/50 (30%) | 3/50 (6%)
Adjusted rate | 14.7% | 24.5% | 35.9% | 7.3%
Terminal rate | 5/39 (13%) | 7/31 (23%) | 14/29 (48%) | 2/25 (8%)
First incidence (days) | 684 | 571 | 660 | 571
Poly-3 test | P = 0.254N | P = 0.176 | P = 0.016* | P = 0.226N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 11/50 (22%) | 38/49 (78%) | 42/50 (84%) | 46/50 (92%)
Adjusted rate | 22.8% | 79.4% | 87.6% | 93.8%
Terminal rate | 8/39 (21%) | 24/31 (77%) | 25/29 (86%) | 22/25 (88%)
First incidence (days) | 561 | 551 | 382 | 425
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 16/50 (32%) | 41/49 (84%) | 43/50 (86%) | 47/50 (94%)
Adjusted rate | 33.0% | 85.0% | 89.7% | 95.9%
Terminal rate | 11/39 (28%) | 26/31 (84%) | 26/29 (90%) | 23/25 (92%)
First incidence (days) | 561 | 551 | 382 | 425
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 0/49 (0%) | 3/47 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.0% | 0.0% | 0.0%
Terminal rate | 0/39 (0%) | 0/31 (0%) | 0/29 (0%) | 0/25 (0%)
First incidence (days) | – | 589 | – | –
Poly-3 test | P = 0.357N | P = 0.104 | –^f^ | –
Spleen: Hemangiosarcoma
Overall rate | 3/50 (6%) | 0/48 (0%) | 4/49 (8%) | 3/48 (6%)
Adjusted rate | 6.3% | 0.0% | 9.6% | 7.7%
Terminal rate | 2/39 (5%) | 0/31 (0%) | 1/29 (3%) | 2/25 (8%)
First incidence (days) | 708 | – | 652 | 649
Poly-3 test | P = 0.292 | P = 0.137N | P = 0.431 | P = 0.568
All Organs: Hemangiosarcoma
Overall rate | 7/50 (14%) | 3/50 (6%) | 7/50 (14%) | 3/50 (6%)
Adjusted rate | 14.7% | 6.7% | 16.4% | 7.3%
Terminal rate | 5/39 (13%) | 2/31 (7%) | 2/29 (7%) | 2/25 (8%)
First incidence (days) | 682 | 611 | 597 | 649
Poly-3 test | P = 0.291N | P = 0.186N | P = 0.526 | P = 0.228N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 7/50 (14%) | 3/50 (6%) | 7/50 (14%) | 4/50 (8%)
Adjusted rate | 14.7% | 6.7% | 16.4% | 9.8%
Terminal rate | 5/39 (13%) | 2/31 (7%) | 2/29 (7%) | 3/25 (12%)
First incidence (days) | 682 | 611 | 597 | 649
Poly-3 test | P = 0.428N | P = 0.186N | P = 0.526 | P = 0.357N
All Organs: Malignant Lymphoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 8.3% | 2.3% | 2.4% | 7.2%
Terminal rate | 1/39 (3%) | 1/31 (3%) | 0/29 (0%) | 1/25 (4%)
First incidence (days) | 646 | 729 (T) | 627 | 227
Poly-3 test | P = 0.551N | P = 0.207N | P = 0.226N | P = 0.578N
All Organs: Benign Neoplasms
Overall rate | 35/50 (70%) | 32/50 (64%) | 34/50 (68%) | 19/50 (38%)
Adjusted rate | 71.8% | 70.3% | 75.1% | 45.2%
Terminal rate | 28/39 (72%) | 24/31 (77%) | 25/29 (86%) | 13/25 (52%)
First incidence (days) | 646 | 571 | 361 | 571
Poly-3 test | P = 0.004N | P = 0.528N | P = 0.446 | P = 0.006N
All Organs: Malignant Neoplasms
Overall rate | 36/50 (72%) | 46/50 (92%) | 46/50 (92%) | 48/50 (96%)
Adjusted rate | 72.0% | 92.0% | 93.7% | 96.0%
Terminal rate | 25/39 (64%) | 27/31 (87%) | 26/29 (90%) | 23/25 (92%)
First incidence (days) | 561 | 457 | 382 | 227
Poly-3 test | P < 0.001 | P = 0.008 | P = 0.004 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 45/50 (90%) | 49/50 (98%) | 50/50 (100%) | 49/50 (98%)
Adjusted rate | 90.0% | 98.0% | 100.0% | 98.0%
Terminal rate | 34/39 (87%) | 30/31 (97%) | 29/29 (100%) | 24/25 (96%)
First incidence (days) | 561 | 457 | 361 | 227
Poly-3 test | P = 0.050 | P = 0.102 | P = 0.031 | P = 0.102

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, lung, pancreatic islets, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
1-Bromopropane (July 2003) | 6/50 | 8/50 | 13/50
CIMSTAR 3800 (May 2008) | 5/50 | 8/50 | 13/50
Cobalt metal (May 2006) | 7/50 | 11/50 | 16/50
Diethylamine (August 2003) | 4/50 | 12/50 | 15/50
Tetralin (June 2003) | 10/50 | 11/50 | 20/50
Vinylidene chloride (June 2005) | 7/50 | 9/50 | 13/50
Total (%) | 39/300 (13.0%) | 59/300 (19.7%) | 90/300 (30.0%)
Mean ± standard deviation | 13.0% ± 4.2% | 19.7% ± 3.4% | 30.0% ± 5.5%
Range | 8%–20% | 16%–24% | 26%–40%
Overall Historical Incidence: All Routes
Total (%) | 145/950 (15.3%) | 132/950 (13.9%) | 263/950 (27.7%)
Mean ± standard deviation | 15.3% ± 6.2% | 13.9% ± 7.1% | 27.7% ± 5.7%
Range | 2%–26% | 4%–24% | 16%–40%

^a^ Data as of May 2013.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 5 | 13 | 12 | 17
Natural deaths | 6 | 6 | 9 | 8
Survivors
Died last week of study | – | – | 1 | 3
Terminal kill | 39 | 31 | 28 | 22
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Arteriole, inflammation, acute | – | – | 1 (2%) | –
Gallbladder | (43) | (37) | (34) | (35)
Degeneration, hyaline | – | – | 1 (3%) | –
Intestine large, cecum | (45) | (45) | (44) | (45)
Intestine large, colon | (47) | (45) | (45) | (46)
Intestine large, rectum | (44) | (44) | (45) | (48)
Intestine small, duodenum | (45) | (44) | (44) | (44)
Inflammation, chronic active | 1 (2%) | – | – | –
Ulcer | – | – | 1 (2%) | –
Intestine small, ileum | (45) | (45) | (43) | (44)
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Intestine small, jejunum | (45) | (45) | (43) | (44)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | 1 (2%)
Basophilic focus | 4 (8%) | 4 (8%) | 6 (12%) | 4 (8%)
Clear cell focus | 17 (34%) | 17 (34%) | 8 (16%) | –
Eosinophilic focus | 6 (12%) | 5 (10%) | 4 (8%) | 2 (4%)
Fatty change | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Hepatodiaphragmatic nodule | – | 3 (6%) | – | 3 (6%)
Inflammation, chronic | – | – | 1 (2%) | –
Mixed cell focus | 1 (2%) | – | – | –
Necrosis | 2 (4%) | 3 (6%) | 1 (2%) | 1 (2%)
Tension lipidosis | 2 (4%) | – | 2 (4%) | –
Mesentery | (5) | (5) | (5) | (3)
Fat, necrosis | 5 (100%) | 4 (80%) | 5 (100%) | 3 (100%)
Pancreas | (50) | (47) | (50) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Salivary glands | (50) | (49) | (50) | (50)
Inflammation, chronic | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (48) | (50) | (50)
Hyperplasia, squamous | 1 (2%) | 2 (4%) | 2 (4%) | 4 (8%)
Inflammation, chronic active | – | 1 (2%) | – | 3 (6%)
Ulcer | 1 (2%) | 5 (10%) | 3 (6%) | 1 (2%)
Stomach, glandular | (48) | (46) | (48) | (49)
Necrosis | 1 (2%) | 1 (2%) | 1 (2%) | –
Ulcer | – | 1 (2%) | – | 1 (2%)
Arteriole, inflammation, acute | – | – | 1 (2%) | –
Tooth | (8) | (2) | (2) | (1)
Dysplasia | 8 (100%) | 1 (50%) | 2 (100%) | 1 (100%)
Inflammation, chronic active | – | 1 (50%) | – | –
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 13 (26%) | 5 (10%) | 12 (24%) | 8 (16%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | – | 1 (2%) | – | –
Mineralization | 1 (2%) | 1 (2%) | – | –
Necrosis | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Pericardium, inflammation, chronic | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Hyperplasia | 6 (12%) | 10 (20%) | 2 (4%) | 1 (2%)
Hypertrophy | 18 (36%) | 9 (18%) | 12 (24%) | 2 (4%)
Necrosis | 1 (2%) | – | – | –
Adrenal medulla | (50) | (49) | (50) | (48)
Hyperplasia | 2 (4%) | 2 (4%) | – | –
Islets, pancreatic | (49) | (47) | (50) | (50)
Hyperplasia | 2 (4%) | 3 (6%) | – | 2 (4%)
Parathyroid gland | (29) | (25) | (26) | (27)
Pituitary gland | (47) | (49) | (48) | (48)
Pars distalis, hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | –
Thyroid gland | (49) | (49) | (50) | (49)
General Body System
Tissue NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (0) | (1) | (0) | (1)
Epididymis | (50) | (49) | (50) | (50)
Granuloma sperm | 2 (4%) | – | 1 (2%) | –
Penis | (0) | (0) | (0) | (1)
Inflammation, acute | – | – | – | 1 (100%)
Preputial gland | (49) | (50) | (49) | (50)
Ectasia | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Prostate gland | (50) | (49) | (48) | (50)
Inflammation, acute | – | 1 (2%) | – | –
Seminal vesicle | (48) | (48) | (49) | (50)
Congestion | – | 1 (2%) | – | –
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Testes | (50) | (49) | (50) | (50)
Germinal epithelium, degeneration | 9 (18%) | 14 (29%) | 8 (16%) | 21 (42%)
Interstitial cell, hyperplasia | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (49)
Angiectasis | – | – | – | 1 (2%)
Thrombosis | – | – | – | 1 (2%)
Lymph node | (2) | (0) | (1) | (1)
Renal, hemorrhage | 1 (50%) | – | – | –
Lymph node, bronchial | (26) | (32) | (20) | (24)
Lymph node, mandibular | (37) | (23) | (27) | (37)
Lymph node, mediastinal | (34) | (34) | (36) | (44)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Lymph node, mesenteric | (47) | (44) | (44) | (42)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Arteriole, inflammation, chronic active | – | – | – | 1 (2%)
Spleen | (50) | (48) | (49) | (48)
Hematopoietic cell proliferation | 5 (10%) | – | – | –
Infarct | – | 1 (2%) | – | –
Thymus | (42) | (44) | (40) | (38)
Integumentary System
Skin | (50) | (50) | (50) | (49)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Metaplasia, osseous | – | – | 1 (2%) | –
Subcutaneous tissue, edema | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (49) | (50) | (50)
Skeletal muscle | (0) | (3) | (3) | (1)
Nervous System
Brain | (50) | (50) | (50) | (50)
Infiltration cellular, histiocyte | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Peripheral nerve | (1) | (0) | (0) | (1)
Degeneration | 1 (100%) | – | – | –
Spinal cord | (1) | (0) | (0) | (1)
Respiratory System
Larynx | (48) | (47) | (49) | (50)
Inflammation, suppurative | 7 (15%) | 2 (4%) | 2 (4%) | 4 (8%)
Inflammation, chronic | 1 (2%) | 1 (2%) | – | –
Arteriole, inflammation, acute | – | – | 1 (2%) | –
Respiratory epithelium, erosion | – | – | – | 1 (2%)
Respiratory epithelium, metaplasia, squamous | 7 (15%) | 47 (100%) | 49 (100%) | 49 (98%)
Respiratory epithelium, vacuolization cytoplasmic | – | 20 (43%) | 24 (49%) | 32 (64%)
Squamous epithelium, erosion | 1 (2%) | 3 (6%) | – | 1 (2%)
Squamous epithelium, hyperplasia | 2 (4%) | 5 (11%) | 5 (10%) | 8 (16%)
Lung | (50) | (49) | (50) | (50)
Inflammation, suppurative | 1 (2%) | 2 (4%) | 6 (12%) | 16 (32%)
Proteinosis | 2 (4%) | 46 (94%) | 49 (98%) | 50 (100%)
Alveolar/bronchiolar epithelium, hyperplasia | – | 46 (94%) | 49 (98%) | 50 (100%)
Alveolar/bronchiolar epithelium, vacuolization cytoplasmic | – | 49 (100%) | 47 (94%) | 48 (96%)
Alveolar epithelium, hyperplasia | 4 (8%) | 29 (59%) | 24 (48%) | 43 (86%)
Alveolus, infiltration cellular, histiocyte | 10 (20%) | 49 (100%) | 48 (96%) | 48 (96%)
Bronchiole, epithelium, erosion | – | 4 (8%) | 10 (20%) | 2 (4%)
Bronchiole, epithelium, hyperplasia | 4 (8%) | 7 (14%) | 9 (18%) | 11 (22%)
Nose | (50) | (49) | (50) | (50)
Inflammation, suppurative | 16 (32%) | 32 (65%) | 49 (98%) | 50 (100%)
Olfactory epithelium, atrophy | 3 (6%) | 46 (94%) | 42 (84%) | 31 (62%)
Olfactory epithelium, hyperplasia | – | 25 (51%) | 17 (34%) | 8 (16%)
Olfactory epithelium, metaplasia, respiratory | 5 (10%) | 24 (49%) | 44 (88%) | 50 (100%)
Olfactory epithelium, respiratory metaplasia, atypical | – | 14 (29%) | 9 (18%) | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 13 (26%) | 29 (59%) | 29 (58%) | 7 (14%)
Respiratory epithelium, erosion | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 44 (88%) | 41 (84%) | 36 (72%) | 19 (38%)
Respiratory epithelium, metaplasia, squamous | 3 (6%) | 45 (92%) | 35 (70%) | 33 (66%)
Respiratory epithelium, vacuolization cytoplasmic | – | 41 (84%) | 39 (78%) | 37 (74%)
Squamous epithelium, erosion | 1 (2%) | 1 (2%) | 2 (4%) | –
Turbinate, atrophy | 3 (6%) | 25 (51%) | 49 (98%) | 50 (100%)
Trachea | (48) | (47) | (48) | (50)
Inflammation, suppurative | – | – | – | 1 (2%)
Epithelium, vacuolization cytoplasmic | – | 14 (30%) | 31 (65%) | 37 (74%)
Special Senses System
Eye | (47) | (46) | (43) | (45)
Cataract | 1 (2%) | – | – | 1 (2%)
Cornea, inflammation, chronic active | 4 (9%) | 1 (2%) | 1 (2%) | –
Harderian gland | (49) | (48) | (48) | (50)
Hyperplasia | 1 (2%) | – | – | 2 (4%)
Zymbal’s gland | (0) | (1) | (0) | (0)
Inflammation, suppurative | – | 1 (100%) | – | –
Urinary System
Kidney | (50) | (49) | (49) | (50)
Cyst | 1 (2%) | 1 (2%) | – | –
Infarct | 2 (4%) | 4 (8%) | 1 (2%) | 3 (6%)
Nephropathy | 46 (92%) | 44 (90%) | 42 (86%) | 37 (74%)
Thrombosis | – | – | 1 (2%) | –
Arteriole, inflammation, chronic active | – | – | – | 1 (2%)
Capsule, hemorrhage | 1 (2%) | – | – | –
Pelvis, inflammation, suppurative | 1 (2%) | – | – | –
Renal tubule, hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%)
Renal tubule, necrosis | – | – | 1 (2%) | –
Urinary bladder | (48) | (48) | (50) | (47)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | –
Arteriole, inflammation, chronic active | – | – | – | 1 (2%)
Transitional epithelium, hyperplasia | 1 (2%) | – | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.