# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of Cobalt Metal

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 11 | 20 | 19 | 24
Natural deaths | 4 | 4 | 7 | 1
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 35 | 26 | 24 | 24
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (49) | (48)
Intestine large, cecum | (50) | (50) | (49) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (49) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Intestine large, rectum | (50) | (50) | (50) | (49)
Intestine small, duodenum | (48) | (50) | (50) | (50)
Intestine small, ileum | (49) | (50) | (48) | (50)
Carcinoma | 1 (2%) | – | – | –
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (50) | (47) | (50)
Carcinoma | 1 (2%) | – | – | –
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Fibrous histiocytoma, metastatic, skin | 1 (2%) | 1 (2%) | – | –
Hepatocellular adenoma | – | 1 (2%) | – | –
Hepatocellular carcinoma | – | 1 (2%) | – | –
Mesentery | (13) | (15) | (8) | (9)
Carcinoma, metastatic, islets, pancreatic | 1 (8%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Acinus, carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 1 (2%) | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (1) | (0) | (1) | (0)
Squamous cell carcinoma | – | – | 1 (100%) | –
Squamous cell papilloma | 1 (100%) | – | – | –
Tooth | (1) | (0) | (2) | (2)
Cardiovascular System
Blood vessel | (0) | (1) | (0) | (0)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (100%) | – | –
Aorta, alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (100%) | – | –
Heart | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%)
Schwannoma malignant | – | – | 1 (2%) | –
Pericardium, rhabdomyosarcoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 4 (8%) | 8 (16%) | 14 (28%) | 17 (34%)
Pheochromocytoma malignant | – | 1 (2%) | 2 (4%) | 7 (14%)
Bilateral, fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Bilateral, pheochromocytoma benign | 2 (4%) | 4 (8%) | 8 (16%) | 19 (38%)
Bilateral, pheochromocytoma malignant | – | 1 (2%) | 1 (2%) | 4 (8%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Carcinoma | 1 (2%) | – | – | 3 (6%)
Parathyroid gland | (42) | (45) | (38) | (45)
Pituitary gland | (50) | (50) | (49) | (50)
Pars distalis, adenoma | 29 (58%) | 23 (46%) | 26 (53%) | 22 (44%)
Pars distalis, carcinoma | – | 3 (6%) | 1 (2%) | 1 (2%)
Thyroid gland | (50) | (49) | (49) | (50)
Bilateral, C-cell, adenoma | 1 (2%) | – | 2 (4%) | –
C-cell, adenoma | 7 (14%) | 6 (12%) | 2 (4%) | 2 (4%)
C-cell, carcinoma | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Follicular cell, adenoma | – | – | 1 (2%) | 1 (2%)
Follicular cell, carcinoma | 1 (2%) | – | – | –
General Body System
Peritoneum | (1) | (1) | (0) | (0)
Carcinoma, metastatic, islets, pancreatic | 1 (100%) | – | – | –
Fibrous histiocytoma, metastatic, skin | – | 1 (100%) | – | –
Genital System
Clitoral gland | (49) | (47) | (47) | (46)
Adenoma | 2 (4%) | 4 (9%) | 6 (13%) | 2 (4%)
Carcinoma | 4 (8%) | 5 (11%) | 3 (6%) | 4 (9%)
Bilateral, adenoma | – | 1 (2%) | – | –
Ovary | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Cystadenocarcinoma | – | 1 (2%) | – | –
Granulosa cell tumor malignant | – | – | 1 (2%) | –
Thecoma benign | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | 1 (2%) | –
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | – | – | –
Leiomyoma | 1 (2%) | 1 (2%) | – | –
Polyp stromal | 10 (20%) | 7 (14%) | 6 (12%) | 10 (20%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (4) | (3) | (7) | (5)
Deep cervical, fibrous histiocytoma, metastatic, skin | 1 (25%) | – | – | –
Lumbar, renal, carcinoma, metastatic, islets, pancreatic | 1 (25%) | – | – | –
Lymph node, bronchial | (26) | (18) | (22) | (17)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (6%)
Fibrous histiocytoma, metastatic, skin | 1 (4%) | – | – | –
Lymph node, mandibular | (48) | (48) | (47) | (47)
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Lymph node, mediastinal | (42) | (43) | (48) | (48)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Thymus | (47) | (46) | (46) | (47)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenocarcinoma | – | – | 1 (2%) | –
Adenoma | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Carcinoma | 2 (4%) | 5 (10%) | – | 3 (6%)
Fibroadenoma | 17 (34%) | 21 (42%) | 15 (30%) | 5 (10%)
Fibroadenoma, multiple | 1 (2%) | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 1 (2%) | – | – | –
Keratoacanthoma | – | – | 2 (4%) | 1 (2%)
Papilloma | – | 1 (2%) | – | –
Squamous cell papilloma | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, fibroma | 2 (4%) | 1 (2%) | – | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 2 (4%) | – | –
Subcutaneous tissue, lipoma | 1 (2%) | – | – | –
Subcutaneous tissue, schwannoma malignant | 1 (2%) | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (1) | (1) | (0) | (1)
Carcinoma, metastatic, islets, pancreatic | 1 (100%) | – | – | –
Lipoma | – | 1 (100%) | – | –
Schwannoma malignant, metastatic, skin | – | – | – | 1 (100%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pituitary gland | – | 3 (6%) | 1 (2%) | 1 (2%)
Glioma malignant | – | – | 1 (2%) | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 2 (4%) | 6 (12%) | 6 (12%) | 9 (18%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | 3 (6%) | 4 (8%)
Alveolar/bronchiolar carcinoma | – | 5 (10%) | 14 (28%) | 12 (24%)
Alveolar/bronchiolar carcinoma, multiple | – | 4 (8%) | 3 (6%) | 18 (36%)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Cystic keratinizing epithelioma | – | 4 (8%) | 1 (2%) | 2 (4%)
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%)
Squamous cell carcinoma | – | – | – | 1 (2%)
Mediastinum, alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | – | 1 (2%)
Mediastinum, fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Nose | (50) | (50) | (49) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (4) | (4) | (0) | (3)
Eye | (50) | (50) | (49) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (0) | (1) | (0) | (0)
Adenoma | – | 1 (100%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Transitional epithelium, papilloma | – | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, skin | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | 16 (32%) | 29 (58%) | 28 (56%) | 27 (54%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 48 | 50 | 50 | 49
Total primary neoplasms | 114 | 155 | 153 | 181
Total animals with benign neoplasms | 44 | 44 | 43 | 43
Total benign neoplasms | 84 | 95 | 94 | 99
Total animals with malignant neoplasms | 25 | 42 | 42 | 48
Total malignant neoplasms | 30 | 60 | 59 | 82
Total animals with metastatic neoplasms | 2 | 5 | 1 | 6
Total metastatic neoplasms | 30 | 9 | 1 | 9
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 6/50 (12%) | 12/50 (24%) | 22/50 (44%) | 36/50 (72%)
Adjusted rate^b^ | 13.6% | 27.2% | 52.1% | 80.6%
Terminal rate^c^ | 6/35 (17%) | 5/26 (19%) | 13/24 (54%) | 21/25 (84%)
First incidence (days) | 730 (T) | 598 | 590 | 579
Poly-3 test^d^ | P < 0.001 | P = 0.091 | P < 0.001 | P < 0.001
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 3/50 (6%) | 11/50 (22%)
Adjusted rate | 0.0% | 4.7% | 7.5% | 27.0%
Terminal rate | 0/35 (0%) | 2/26 (8%) | 2/24 (8%) | 9/25 (36%)
First incidence (days) | –^e^ | 730 (T) | 715 | 712
Poly-3 test | P < 0.001 | P = 0.228 | P = 0.102 | P < 0.001
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 6/50 (12%) | 13/50 (26%) | 23/50 (46%) | 40/50 (80%)
Adjusted rate | 13.6% | 29.4% | 54.5% | 89.4%
Terminal rate | 6/35 (17%) | 6/26 (23%) | 14/24 (58%) | 24/25 (96%)
First incidence (days) | 730 (T) | 598 | 590 | 579
Poly-3 test | P < 0.001 | P = 0.058 | P < 0.001 | P < 0.001
Clitoral Gland: Adenoma
Overall rate | 2/49 (4%) | 5/47 (11%) | 6/47 (13%) | 2/46 (4%)
Adjusted rate | 4.5% | 12.3% | 16.1% | 5.4%
Terminal rate | 1/35 (3%) | 1/23 (4%) | 6/22 (27%) | 1/22 (5%)
First incidence (days) | 674 | 593 | 730 (T) | 691
Poly-3 test | P = 0.517N | P = 0.181 | P = 0.083 | P = 0.631
Clitoral Gland: Carcinoma
Overall rate | 4/49 (8%) | 5/47 (11%) | 3/47 (6%) | 4/46 (9%)
Adjusted rate | 9.1% | 12.5% | 8.0% | 10.6%
Terminal rate | 3/35 (9%) | 1/23 (4%) | 1/22 (5%) | 2/22 (9%)
First incidence (days) | 722 | 646 | 618 | 478
Poly-3 test | P = 0.524N | P = 0.438 | P = 0.585N | P = 0.558
Clitoral Gland: Adenoma or Carcinoma
Overall rate | 6/49 (12%) | 10/47 (21%) | 9/47 (19%) | 6/46 (13%)
Adjusted rate | 13.5% | 24.3% | 23.9% | 15.8%
Terminal rate | 4/35 (11%) | 2/23 (9%) | 7/22 (32%) | 3/22 (14%)
First incidence (days) | 674 | 593 | 618 | 478
Poly-3 test | P = 0.480N | P = 0.159 | P = 0.179 | P = 0.511
Lung: Cystic Keratinizing Epithelioma
Overall rate | 0/50 (0%) | 4/50 (8%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 0.0% | 9.5% | 2.5% | 4.9%
Terminal rate | 0/35 (0%) | 4/26 (15%) | 1/24 (4%) | 1/25 (4%)
First incidence (days) | – | 730 (T) | 730 (T) | 603
Poly-3 test | P = 0.582 | P = 0.055 | P = 0.481 | P = 0.222
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 2/50 (4%) | 7/50 (14%) | 9/50 (18%) | 13/50 (26%)
Adjusted rate | 4.5% | 16.2% | 22.1% | 30.9%
Terminal rate | 1/35 (3%) | 5/26 (19%) | 6/24 (25%) | 8/25 (32%)
First incidence (days) | 698 | 590 | 587 | 579
Poly-3 test | P = 0.002 | P = 0.072 | P = 0.016 | P < 0.001
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 0/50 (0%) | 9/50 (18%) | 17/50 (34%) | 30/50 (60%)
Adjusted rate | 0.0% | 21.3% | 42.0% | 69.2%
Terminal rate | 0/35 (0%) | 9/26 (35%) | 14/24 (58%) | 20/25 (80%)
First incidence (days) | – | 730 (T) | 690 | 471
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 15/50 (30%) | 20/50 (40%) | 38/50 (76%)
Adjusted rate | 4.5% | 34.7% | 48.5% | 86.2%
Terminal rate | 1/35 (3%) | 13/26 (50%) | 14/24 (58%) | 25/25 (100%)
First incidence (days) | 698 | 590 | 587 | 471
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Mammary Gland: Fibroadenoma
Overall rate | 18/50 (36%) | 22/50 (44%) | 15/50 (30%) | 5/50 (10%)
Adjusted rate | 39.3% | 49.5% | 36.0% | 12.3%
Terminal rate | 14/35 (40%) | 16/26 (62%) | 9/24 (38%) | 5/25 (20%)
First incidence (days) | 316 | 516 | 590 | 730 (T)
Poly-3 test | P < 0.001N | P = 0.220 | P = 0.459N | P = 0.003N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 19/50 (38%) | 23/50 (46%) | 16/50 (32%) | 6/50 (12%)
Adjusted rate | 41.5% | 51.3% | 38.4% | 14.7%
Terminal rate | 15/35 (43%) | 16/26 (62%) | 10/24 (42%) | 6/25 (24%)
First incidence (days) | 316 | 516 | 590 | 730 (T)
Poly-3 test | P < 0.001N | P = 0.231 | P = 0.467N | P = 0.005N
Mammary Gland: Carcinoma
Overall rate | 2/50 (4%) | 5/50 (10%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 4.5% | 11.7% | 2.5% | 7.4%
Terminal rate | 1/35 (3%) | 3/26 (12%) | 1/24 (4%) | 3/25 (12%)
First incidence (days) | 698 | 578 | 730 (T) | 730 (T)
Poly-3 test | P = 0.446N | P = 0.203 | P = 0.534N | P = 0.462
Mammary Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 6.8% | 16.2% | 2.5% | 9.8%
Terminal rate | 2/35 (6%) | 4/26 (15%) | 1/24 (4%) | 4/25 (16%)
First incidence (days) | 698 | 578 | 730 (T) | 730 (T)
Poly-3 test | P = 0.345N | P = 0.147 | P = 0.341N | P = 0.455
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 20/50 (40%) | 26/50 (52%) | 16/50 (32%) | 9/50 (18%)
Adjusted rate | 43.6% | 57.2% | 38.4% | 22.1%
Terminal rate | 15/35 (43%) | 17/26 (65%) | 10/24 (42%) | 9/25 (36%)
First incidence (days) | 316 | 516 | 590 | 730 (T)
Poly-3 test | P < 0.001N | P = 0.131 | P = 0.389N | P = 0.026N
Pancreatic Islets: Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 7.2%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/24 (0%) | 1/25 (4%)
First incidence (days) | 234 | – | – | 506
Poly-3 test | P = 0.060 | P = 0.512N | P = 0.523N | P = 0.279
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 7.2%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/24 (0%) | 1/25 (4%)
First incidence (days) | 234 | – | – | 506
Poly-3 test | P = 0.060 | P = 0.512N | P = 0.523N | P = 0.279
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 29/50 (58%) | 23/50 (46%) | 26/49 (53%) | 22/50 (44%)
Adjusted rate | 61.5% | 51.6% | 59.9% | 50.1%
Terminal rate | 20/35 (57%) | 14/26 (54%) | 15/24 (63%) | 11/25 (44%)
First incidence (days) | 511 | 593 | 291 | 506
Poly-3 test | P = 0.287N | P = 0.223N | P = 0.525N | P = 0.183N
Pituitary Gland (Pars Distalis): Carcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/49 (2%) | 1/50 (2%)
Adjusted rate | 0.0% | 6.9% | 2.5% | 2.5%
Terminal rate | 0/35 (0%) | 1/26 (4%) | 1/24 (4%) | 1/25 (4%)
First incidence (days) | – | 578 | 730 (T) | 730 (T)
Poly-3 test | P = 0.497N | P = 0.115 | P = 0.478 | P = 0.484
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 29/50 (58%) | 26/50 (52%) | 27/49 (55%) | 23/50 (46%)
Adjusted rate | 61.5% | 57.1% | 62.2% | 52.3%
Terminal rate | 20/35 (57%) | 15/26 (58%) | 16/24 (67%) | 12/25 (48%)
First incidence (days) | 511 | 578 | 291 | 506
Poly-3 test | P = 0.279N | P = 0.412N | P = 0.559 | P = 0.247N
Skin: Papilloma, Squamous Cell Papilloma, or Keratoacanthoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.3% | 2.4% | 7.5% | 2.5%
Terminal rate | 1/35 (3%) | 1/26 (4%) | 3/24 (13%) | 1/25 (4%)
First incidence (days) | 730 (T) | 730 (T) | 730 (T) | 730 (T)
Poly-3 test | P = 0.469 | P = 0.752 | P = 0.272 | P = 0.743
Skin: Papilloma, Squamous Cell Papilloma, Keratoacanthoma, or Basal Cell Adenoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.5% | 2.4% | 7.5% | 2.5%
Terminal rate | 2/35 (6%) | 1/26 (4%) | 3/24 (13%) | 1/25 (4%)
First incidence (days) | 730 (T) | 730 (T) | 730 (T) | 730 (T)
Poly-3 test | P = 0.570N | P = 0.514N | P = 0.457 | P = 0.528N
Skin (Subcutaneous Tissue): Fibroma or Fibrous Histiocytoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 6.6% | 7.0% | 0.0% | 2.5%
Terminal rate | 1/35 (3%) | 1/26 (4%) | 0/24 (0%) | 1/25 (4%)
First incidence (days) | 316 | 422 | – | 730 (T)
Poly-3 test | P = 0.118N | P = 0.641 | P = 0.141N | P = 0.344N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 8/50 (16%) | 6/49 (12%) | 4/49 (8%) | 2/50 (4%)
Adjusted rate | 18.1% | 14.5% | 10.2% | 4.8%
Terminal rate | 7/35 (20%) | 5/25 (20%) | 4/24 (17%) | 1/25 (4%)
First incidence (days) | 674 | 684 | 730 (T) | 506
Poly-3 test | P = 0.036N | P = 0.437N | P = 0.237N | P = 0.056N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 9/50 (18%) | 8/49 (16%) | 5/49 (10%) | 3/50 (6%)
Adjusted rate | 20.3% | 19.3% | 12.7% | 7.2%
Terminal rate | 8/35 (23%) | 7/25 (28%) | 5/24 (21%) | 1/25 (4%)
First incidence (days) | 674 | 684 | 730 (T) | 506
Poly-3 test | P = 0.035N | P = 0.560N | P = 0.262N | P = 0.072N
Uterus: Stromal Polyp
Overall rate | 10/50 (20%) | 7/50 (14%) | 6/50 (12%) | 10/50 (20%)
Adjusted rate | 22.3% | 16.2% | 14.5% | 24.1%
Terminal rate | 7/35 (20%) | 4/26 (15%) | 3/24 (13%) | 6/25 (24%)
First incidence (days) | 646 | 624 | 541 | 646
Poly-3 test | P = 0.377 | P = 0.326N | P = 0.253N | P = 0.524
All Organs: Mononuclear Cell Leukemia
Overall rate | 16/50 (32%) | 29/50 (58%) | 28/50 (56%) | 27/50 (54%)
Adjusted rate | 35.7% | 62.4% | 60.5% | 58.9%
Terminal rate | 12/35 (34%) | 15/26 (58%) | 12/24 (50%) | 13/25 (52%)
First incidence (days) | 663 | 590 | 117 | 473
Poly-3 test | P = 0.118 | P = 0.007 | P = 0.013 | P = 0.019
All Organs: Benign Neoplasms
Overall rate | 44/50 (88%) | 44/50 (88%) | 43/50 (86%) | 43/50 (86%)
Adjusted rate | 89.7% | 91.4% | 92.5% | 92.6%
Terminal rate | 30/35 (86%) | 24/26 (92%) | 24/24 (100%) | 24/25 (96%)
First incidence (days) | 316 | 516 | 291 | 506
Poly-3 test | P = 0.373 | P = 0.525 | P = 0.454 | P = 0.447
All Organs: Malignant Neoplasms
Overall rate | 25/50 (50%) | 42/50 (84%) | 42/50 (84%) | 49/50 (98%)
Adjusted rate | 52.5% | 86.6% | 89.0% | 98.7%
Terminal rate | 16/35 (46%) | 23/26 (89%) | 22/24 (92%) | 25/25 (100%)
First incidence (days) | 234 | 422 | 117 | 471
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 48/50 (96%) | 50/50 (100%) | 50/50 (100%) | 50/50 (100%)
Adjusted rate | 96.0% | 100.0% | 100.0% | 100.0%
Terminal rate | 33/35 (94%) | 26/26 (100%) | 24/24 (100%) | 25/25 (100%)
First incidence (days) | 234 | 422 | 117 | 471
Poly-3 test | P = 0.185 | P = 0.237 | P = 0.237 | P = 0.237

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, clitoral gland, lung, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table B-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Female F344/NTac Rats^a^

| Adenoma | Carcinoma | Adenoma or Carcinoma
Overall Historical Incidence: All Routes
Total (%) | 2/100 (2.0%) | 0/100 | 2/100 (2.0%)
Mean ± standard deviation | 2.0% ± 2.8% | – | 2.0% ± 2.8%
Range | 0%–4% | – | 0%–4%

^a^ Data as of June 2013.

Table B-4 Historical Incidence of Pheochromocytoma of the Adrenal Medulla in Control Female F344/NTac Rats^a^

| Benign | Malignant | Benign or Malignant
Overall Historical Incidence: All Routes
Total (%) | 7/100 (7.0%) | 1/100 (1.0%) | 8/100 (8.0%)
Mean ± standard deviation | 7.0% ± 7.1% | 1.0% ± 1.4% | 8.0% ± 5.7%
Range | 2%–12% | 0%–2% | 4%–12%

^a^ Data as of June 2013.

Table B-5 Historical Incidence of Pancreatic Islet Neoplasms in Control Female F344/NTac Rats^a^

| Adenoma | Carcinoma | Adenoma or Carcinoma
Overall Historical Incidence: All Routes
Total (%) | 1/100 (1.0%) | 1/100 (1.0%) | 2/100 (2.0%)
Mean ± standard deviation | 1.0% ± 1.4% | 1.0% ± 1.4% | 2.0% ± 0.0%
Range | 0%–2% | 0%–2% | 2%

^a^ Data as of June 2013.

Table B-6 Historical Incidence of Mononuclear Cell Leukemia in Control Female F344/NTac Rats^a^

| Incidence in Controls
Overall Historical Incidence: All Routes
Total (%) | 35/100 (35.0%)
Mean ± standard deviation | 35.0% ± 4.2%
Range | 32%–38%

^a^ Data as of June 2013.

Table B-7 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 11 | 20 | 19 | 24
Natural deaths | 4 | 4 | 7 | 1
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 35 | 26 | 24 | 24
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (49) | (48)
Intestine large, cecum | (50) | (50) | (49) | (50)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Intestine large, colon | (50) | (50) | (49) | (50)
Mucosa, hyperplasia | – | 2 (4%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (49)
Intestine small, duodenum | (48) | (50) | (50) | (50)
Infiltration cellular, chronic active | – | 1 (2%) | – | –
Intestine small, ileum | (49) | (50) | (48) | (50)
Intestine small, jejunum | (50) | (50) | (47) | (50)
Congestion | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, suppurative | – | – | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | 1 (2%)
Atrophy | 1 (2%) | – | – | –
Basophilic focus | 16 (32%) | 20 (40%) | 22 (44%) | 33 (66%)
Clear cell focus | 12 (24%) | 6 (12%) | 3 (6%) | 6 (12%)
Eosinophilic focus | – | 1 (2%) | 2 (4%) | 2 (4%)
Fatty change | 13 (26%) | 9 (18%) | 6 (12%) | 3 (6%)
Fibrosis | – | 1 (2%) | – | –
Hepatodiaphragmatic nodule | 6 (12%) | 11 (22%) | 12 (24%) | 15 (30%)
Inflammation, chronic active | 1 (2%) | – | – | 2 (4%)
Mixed cell focus | 1 (2%) | 4 (8%) | 2 (4%) | –
Necrosis | 6 (12%) | 3 (6%) | 2 (4%) | 2 (4%)
Regeneration | 2 (4%) | 3 (6%) | 5 (10%) | 4(8%)
Bile duct, cyst | – | – | 1 (2%) | –
Serosa, thrombosis | 1 (2%) | – | – | –
Mesentery | (13) | (15) | (8) | (9)
Fibrosis | – | 1 (7%) | – | –
Fat, necrosis | 12 (92%) | 14 (93%) | 8 (100%) | 9 (100%)
Pancreas | (50) | (50) | (50) | (50)
Basophilic focus | – | 1 (2%) | – | –
Acinus, atrophy | 18 (36%) | 23 (46%) | 27 (54%) | 32 (64%)
Acinus, hyperplasia | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | –
Duct, hyperplasia | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Edema | – | – | 1 (2%) | 1 (2%)
Erosion | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Hyperplasia, squamous | 5 (10%) | 10 (20%) | 2 (4%) | 3 (6%)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Ulcer | 1 (2%) | 5 (10%) | 2 (4%) | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Edema | 2 (4%) | – | – | –
Erosion | 1 (2%) | – | 1 (2%) | –
Inflammation, suppurative | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Thrombosis | – | – | 1 (2%) | –
Ulcer | – | 3 (6%) | 1 (2%) | 1 (2%)
Tongue | (1) | (0) | (1) | (0)
Tooth | (1) | (0) | (2) | (2)
Inflammation, chronic active | 1 (100%) | – | 2 (100%) | 2 (100%)
Cardiovascular System
Blood vessel | (0) | (1) | (0) | (0)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 41 (82%) | 34 (68%) | 42 (84%) | 35 (70%)
Thrombosis | 2 (4%) | 4 (8%) | 2 (4%) | –
Artery, inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Atrium, congestion | 1 (2%) | – | – | –
Pericardium, hyperplasia | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 5 (10%) | – | 3 (6%) | 4 (8%)
Atrophy | 1 (2%) | – | 1 (2%) | –
Degeneration | 3 (6%) | 1 (2%) | 3 (6%) | 3 (6%)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia | 25 (50%) | 27 (54%) | 28 (56%) | 28 (56%)
Necrosis | 1 (2%) | – | 1 (2%) | 2 (4%)
Adrenal medulla | (50) | (50) | (50) | (50)
Degeneration, cystic | 1 (2%) | – | – | –
Hyperplasia | 12 (24%) | 27 (54%) | 27 (54%) | 10 (20%)
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Parathyroid gland | (42) | (45) | (38) | (45)
Pituitary gland | (50) | (50) | (49) | (50)
Angiectasis | – | – | 1 (2%) | 2 (4%)
Cyst | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 19 (38%) | 20 (40%) | 18 (37%) | 19 (38%)
Thyroid gland | (50) | (49) | (49) | (50)
Hemorrhage | – | – | – | 1 (2%)
C-cell, hyperplasia | 9 (18%) | 9 (18%) | 8 (16%) | 6 (12%)
Follicular cell, hyperplasia | 1 (2%) | – | – | –
General Body System
Peritoneum | (1) | (1) | (0) | (0)
Genital System
Clitoral gland | (49) | (47) | (47) | (46)
Cyst | – | – | – | 1 (2%)
Hyperplasia | 2 (4%) | 1 (2%) | 1 (2%) | –
Inflammation, suppurative | 2 (4%) | – | – | 1 (2%)
Inflammation, chronic active | – | 4 (9%) | – | 2 (4%)
Ovary | (50) | (50) | (50) | (50)
Cyst | 5 (10%) | 6 (12%) | 7 (14%) | 5 (10%)
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | – | –
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Cyst | 1 (2%) | – | – | –
Inflammation, suppurative | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic active | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Necrosis | 2 (4%) | – | – | –
Thrombosis | – | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 4 (8%) | 2 (4%) | 1 (2%) | 4 (8%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Lymph node | (4) | (3) | (7) | (5)
Deep cervical, infiltration cellular | – | 1 (33%) | – | –
Iliac, ectasia | – | 1 (33%) | – | 1 (20%)
Inguinal, fibrosis | – | – | – | 1 (20%)
Renal, ectasia | 1 (25%) | – | 1 (14%) | –
Lymph node, bronchial | (26) | (18) | (22) | (17)
Lymph node, mandibular | (48) | (48) | (47) | (47)
Atrophy | 1 (2%) | – | – | –
Ectasia | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Lymph node, mediastinal | (42) | (43) | (48) | (48)
Atrophy | 1 (2%) | – | – | –
Ectasia | 1 (2%) | 1 (2%) | – | –
Hyperplasia | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Ectasia | – | 1 (2%) | – | –
Fibrosis | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (50)
Fibrosis | – | 1 (2%) | 5 (10%) | 3 (6%)
Hematopoietic cell proliferation | 2 (4%) | 5 (10%) | 3 (6%) | 2 (4%)
Hemorrhage | – | – | 3 (6%) | –
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | – | 2 (4%)
Thymus | (47) | (46) | (46) | (47)
Thrombosis | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 1 (2%) | 1 (2%) | 4 (8%) | 1 (2%)
Hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 5 (10%)
Inflammation, chronic active | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | 1 (2%) | – | –
Hyperkeratosis | 1 (2%) | – | – | –
Hyperplasia, squamous | 1 (2%) | 1 (2%) | – | 2 (4%)
Inflammation | – | 1 (2%) | 1 (2%) | –
Ulcer | – | – | – | 1 (2%)
Subcutaneous tissue, inflammation | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fracture | 1 (2%) | – | – | –
Femur, hyperostosis | 4 (8%) | 2 (4%) | 5 (10%) | 2 (4%)
Maxilla, inflammation, chronic active | 2 (4%) | – | – | 1 (2%)
Skeletal muscle | (1) | (1) | (0) | (1)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 16 (32%) | 14 (28%) | 14 (28%) | 17 (34%)
Hemorrhage | – | 2 (4%) | – | 3 (6%)
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | –
Necrosis | – | – | 1 (2%) | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | 3 (6%) | 6 (12%) | 2 (4%)
Inflammation | 22 (44%) | 23 (46%) | 14 (28%) | 13 (26%)
Metaplasia, squamous | 4 (8%) | 4 (8%) | 3 (6%) | 5 (10%)
Respiratory epithelium, hyperplasia | – | 4 (8%) | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | 20 (40%) | 50 (100%) | 50 (100%) | 50 (100%)
Necrosis | – | – | – | 1 (2%)
Pigmentation | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 9 (18%) | 49 (98%) | 50 (100%) | 49 (98%)
Alveolar epithelium, metaplasia, squamous | – | 2 (4%) | 1 (2%) | –
Alveolus, proteinosis | – | 50 (100%) | 50 (100%) | 50 (100%)
Bronchiole, epithelium, hyperplasia | – | 47 (94%) | 46 (92%) | 48 (96%)
Interstitium, fibrosis | 1 (2%) | – | – | –
Mediastinum, inflammation | 1 (2%) | – | – | –
Nose | (50) | (50) | (49) | (50)
Foreign body | 5 (10%) | 3 (6%) | – | –
Inflammation | – | – | 1 (2%) | –
Inflammation, suppurative | 6 (12%) | 4 (8%) | 4 (8%) | 42 (84%)
Inflammation, chronic active | 22 (44%) | 42 (84%) | 39 (80%) | 50 (100%)
Thrombosis | 1 (2%) | 4 (8%) | 6 (12%) | 3 (6%)
Olfactory epithelium, accumulation, hyaline droplet | 8 (16%) | 2 (4%) | – | –
Olfactory epithelium, atrophy | – | 22 (44%) | 35 (71%) | 35 (70%)
Olfactory epithelium, hyperplasia | – | – | 3 (6%) | 5 (10%)
Olfactory epithelium, hyperplasia, basal cell | – | – | 1 (2%) | 19 (38%)
Olfactory epithelium, metaplasia, respiratory | 6 (12%) | 18 (36%) | 24 (49%) | 47 (94%)
Olfactory epithelium, necrosis | – | 2 (4%) | – | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 1 (2%) | – | – | –
Respiratory epithelium, hyperplasia | 15 (30%) | 43 (86%) | 48 (98%) | 49 (98%)
Respiratory epithelium, metaplasia, squamous | 2 (4%) | – | 3 (6%) | 45 (90%)
Respiratory epithelium, necrosis | 1 (2%) | 1 (2%) | 1 (2%) | 15 (30%)
Turbinate, atrophy | 1 (2%) | 38 (76%) | 27 (55%) | 45 (90%)
Turbinate, hyperostosis | 3 (6%) | 2 (4%) | 5 (10%) | 2 (4%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (4) | (4) | (0) | (3)
Inflammation, chronic active | 4 (100%) | 4 (100%) | – | 3 (100%)
Eye | (50) | (50) | (49) | (50)
Cataract | 8 (16%) | 10 (20%) | 11 (22%) | 3 (6%)
Hemorrhage | – | 1 (2%) | – | –
Metaplasia, osseous | 24 (48%) | 19 (38%) | 26 (53%) | 13 (26%)
Cornea, inflammation, chronic active | – | 1 (2%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Hyperplasia | – | – | 1 (2%) | –
Inflammation, chronic active | 3 (6%) | – | – | 2 (4%)
Zymbal’s gland | (0) | (1) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | – | 1 (2%)
Infarct | – | 1 (2%) | – | 2 (4%)
Mineralization | – | – | 1 (2%) | –
Necrosis, focal | 1 (2%) | – | – | –
Nephropathy | 48 (96%) | 48 (96%) | 47 (94%) | 48 (96%)
Renal tubule, hyperplasia | – | 2 (4%) | – | –
Renal tubule, necrosis | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.