# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of Cobalt Metal

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | 1 | –
Moribund | 28 | 28 | 27 | 32
Natural deaths | 5 | 2 | 6 | 2
Survivors
Terminal kill | 17 | 20 | 16 | 16
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (48) | (48)
Intestine large, cecum | (49) | (50) | (49) | (50)
Intestine large, colon | (50) | (50) | (49) | (50)
Carcinoma | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (49) | (49) | (49)
Intestine small, duodenum | (50) | (50) | (49) | (50)
Intestine small, ileum | (48) | (50) | (47) | (50)
Intestine small, jejunum | (48) | (49) | (48) | (49)
Liver | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocellular adenoma | – | 1 (2%) | – | 1 (2%)
Mesentery | (18) | (4) | (9) | (3)
Lipoma | – | – | 1 (11%) | –
Pancreas | (50) | (50) | (49) | (50)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Mixed tumor malignant | 1 (2%) | – | – | –
Acinus, adenoma | | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Adenoma, tubular | 1 (2%) | – | – | –
Schwannoma malignant | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | 1 (2%) | – | –
Stomach, glandular | (50) | (50) | (49) | (50)
Tooth | (0) | (2) | (0) | (0)
Cardiovascular System
Blood vessel | (1) | (1) | (0) | (0)
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic | – | – | 1 (2%) | 2 (4%)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | – | 1 (2%)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%)
Schwannoma malignant | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 11 (22%) | 10 (20%) | 15 (30%) | 13 (26%)
Pheochromocytoma malignant | 2 (4%) | 2 (4%) | 9 (18%) | 9 (18%)
Bilateral, pheochromocytoma benign | 4 (8%) | 13 (26%) | 22 (44%) | 21 (42%)
Bilateral, pheochromocytoma malignant | – | – | – | 7 (14%)
Islets, pancreatic | (50) | (50) | (48) | (49)
Adenoma | – | 1 (2%) | 6 (13%) | 3 (6%)
Carcinoma | 2 (4%) | 1 (2%) | 5 (10%) | 6 (12%)
Parathyroid gland | (45) | (45) | (47) | (46)
Pituitary gland | (50) | (50) | (49) | (49)
Pars distalis, adenoma | 27 (54%) | 32 (64%) | 31 (63%) | 24 (49%)
Pars intermedia, adenoma | – | 1 (2%) | – | –
Thyroid gland | (49) | (50) | (50) | (49)
Bilateral, C-cell, adenoma | – | – | – | 1 (2%)
C-cell, adenoma | 4 (8%) | 8 (16%) | 8 (16%) | 6 (12%)
C-cell, carcinoma | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Follicular cell, carcinoma | 2 (4%) | 2 (4%) | – | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Penis | (0) | (1) | (0) | (0)
Preputial gland | (50) | (50) | (49) | (48)
Adenoma | 1 (2%) | 1 (2%) | – | –
Carcinoma | 2 (4%) | – | 1 (2%) | 3 (6%)
Prostate gland | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (2%) | –
Seminal vesicle | (50) | (50) | (50) | (50)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Bilateral, interstitial cell, adenoma | 23 (46%) | 21 (42%) | 17 (34%) | 12 (24%)
Interstitial cell, adenoma | 12 (24%) | 18 (36%) | 17 (34%) | 17 (34%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (12) | (9) | (5) | (9)
Renal, pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (11%)
Lymph node, bronchial | (27) | (25) | (21) | (20)
Lymph node, mandibular | (48) | (49) | (50) | (48)
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | –
Lymph node, mediastinal | (46) | (48) | (46) | (48)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 3 (6%)
Lymph node, mesenteric | (49) | (50) | (49) | (49)
Spleen | (50) | (50) | (50) | (50)
Thymus | (46) | (44) | (47) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (4%)
Integumentary System
Mammary gland | (31) | (32) | (30) | (31)
Carcinoma | 1 (3%) | – | – | –
Fibroadenoma | 1 (3%) | 1 (3%) | – | 1 (3%)
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 2 (4%) | – | 1 (2%) | 3 (6%)
Basal cell carcinoma | – | – | 1 (2%) | –
Hematoma | 1 (2%) | – | – | –
Keratoacanthoma | 4 (8%) | 6 (12%) | 7 (14%) | 2 (4%)
Squamous cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | – | 1 (2%) | – | –
Trichoepithelioma | 2 (4%) | – | – | 1 (2%)
Lip, squamous cell papilloma | – | 1 (2%) | – | –
Pinna, neural crest tumor | – | 1 (2%) | – | –
Sebaceous gland, adenoma | – | – | 1 (2%) | –
Subcutaneous tissue, fibroma | 2 (4%) | 3 (6%) | 3 (6%) | –
Subcutaneous tissue, fibrous histiocytoma | – | – | – | 2 (4%)
Subcutaneous tissue, lipoma | 2 (4%) | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Skeletal muscle | (1) | (0) | (0) | (4)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (50%)
Carcinoma, metastatic, kidney | – | – | – | 1 (25%)
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (25%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Astrocytoma malignant | 1 (2%) | – | – | –
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | –
Oligodendroglioma malignant | – | 2 (4%) | – | –
Spinal cord | (1) | (0) | (0) | (0)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | 7 (14%) | 8 (16%) | 8 (16%)
Alveolar/bronchiolar adenoma, multiple | 1 (2%) | 3 (6%) | 2 (4%) | 6 (12%)
Alveolar/bronchiolar carcinoma | – | 10 (20%) | 20 (40%) | 6 (12%)
Alveolar/bronchiolar carcinoma, multiple | – | 6 (12%) | 14 (28%) | 30 (60%)
Carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Carcinoma, metastatic, Zymbal’s gland | – | 1 (2%) | – | 1 (2%)
Cystic keratinizing epithelioma | – | 1 (2%) | – | 1 (2%)
Pheochromocytoma malignant, metastatic, adrenal medulla | 1 (2%) | – | – | 1 (2%)
Squamous cell carcinoma, metastatic, skin | 1 (2%) | – | – | –
Mediastinum, alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | 5 (10%) | 3 (6%)
Mediastinum, carcinoma, metastatic, kidney | – | – | – | 1 (2%)
Mediastinum, carcinoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Nose | (48) | (47) | (45) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (1) | (5) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (4) | (3) | (0) | (1)
Adenoma | 1 (25%) | – | – | –
Carcinoma | 3 (75%) | 3 (100%) | – | 1 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | 1 (2%)
Renal tubule, adenoma | – | 1 (2%) | – | 2 (4%)
Renal tubule, adenoma, multiple | – | – | – | 1 (2%)
Renal tubule, carcinoma | – | – | – | 2 (4%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 1 (2%) | –
Leukemia mononuclear | 21 (42%) | 25 (50%) | 22 (44%) | 22 (44%)
Mesothelioma malignant | 2 (4%) | 3 (6%) | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 50 | 50 | 49 | 50
Total primary neoplasms | 141 | 191 | 218 | 216
Total animals with benign neoplasms | 47 | 49 | 49 | 47
Total benign neoplasms | 101 | 133 | 139 | 123
Total animals with malignant neoplasms | 31 | 37 | 42 | 48
Total malignant neoplasms | 40 | 57 | 79 | 93
Total animals with metastatic neoplasms | 2 | 4 | 6 | 12
Total metastatic neoplasms | 2 | 7 | 8 | 28
Total animals with malignant neoplasms of uncertain primary site | – | – | – | 1
Total animals with uncertain neoplasms- benign or malignant | – | 1 | – | –
Total uncertain neoplasms | – | 1 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of Cobalt Metal

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 15/50 (30%) | 23/50 (46%) | 37/50 (74%) | 34/50 (68%)
Adjusted rate^b^ | 35.8% | 54.3% | 81.2% | 76.4%
Terminal rate^c^ | 3/17 (18%) | 12/20 (60%) | 15/16 (94%) | 14/16 (88%)
First incidence (days) | 519 | 583 | 582 | 572
Poly-3 test^d^ | P < 0.001 | P = 0.059 | P < 0.001 | P < 0.001
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 9/50 (18%) | 16/50 (32%)
Adjusted rate | 5.0% | 5.0% | 21.4% | 39.1%
Terminal rate | 0/17 (0%) | 2/20 (10%) | 3/16 (19%) | 9/16 (56%)
First incidence (days) | 668 | 729 (T) | 628 | 646
Poly-3 test | P < 0.001 | P = 0.693N | P = 0.030 | P < 0.001
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 17/50 (34%) | 23/50 (46%) | 38/50 (76%) | 41/50 (82%)
Adjusted rate | 40.2% | 54.3% | 82.7% | 90.7%
Terminal rate | 3/17 (18%) | 12/20 (60%) | 15/16 (94%) | 16/16 (100%)
First incidence (days) | 519 | 583 | 582 | 572
Poly-3 test | P < 0.001 | P = 0.130 | P < 0.001 | P < 0.001
Kidney (Renal Tubule): Adenoma (Single Sections)
Overall rate | 0/50 (0%) | 1/50 (2%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.5% | 0.0% | 7.5%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 0/16 (0%) | 2/16 (13%)
First incidence (days) | –^e^ | 729 (T) | – | 696
Poly-3 test | P = 0.061 | P = 0.503 | –^f^ | P = 0.120
Kidney (Renal Tubule): Adenoma (Step Sections)
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 7.5% | 2.5% | 2.4% | 7.5%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 1/16 (6%) | 1/16 (6%)
First incidence (days) | 678 | 729 (T) | 729 (T) | 691
Poly-3 test | P = 0.424 | P = 0.302N | P = 0.294N | P = 0.660N
Kidney (Renal Tubule): Adenoma (Single and Step Sections)
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 6/50 (12%)
Adjusted rate | 7.5% | 2.5% | 2.4% | 14.9%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 1/16 (6%) | 3/16 (19%)
First incidence (days) | 678 | 729 (T) | 729 (T) | 691
Poly-3 test | P = 0.056 | P = 0.302N | P = 0.294N | P = 0.244
Kidney (Renal Tubule): Adenoma or Carcinoma (Single Sections)
Overall rate | 0/50 (0%) | 1/50 (2%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 2.5% | 0.0% | 10.0%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 0/16 (0%) | 3/16 (19%)
First incidence (days) | – | 729 (T) | – | 696
Poly-3 test | P = 0.018 | P = 0.503 | – | P = 0.061
Kidney (Renal Tubule): Adenoma or Carcinoma (Step Sections)
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 5/50 (10%)
Adjusted rate | 7.5% | 2.5% | 2.4% | 12.4%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 1/16 (6%) | 2/16 (13%)
First incidence (days) | 678 | 729 (T) | 729 (T) | 691
Poly-3 test | P = 0.123 | P = 0.302N | P = 0.294N | P = 0.361
Kidney (Renal Tubule): Adenoma or Carcinoma (Single and Step Sections)
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 7/50 (14%)
Adjusted rate | 7.5% | 2.5% | 2.4% | 17.4%
Terminal rate | 0/17 (0%) | 1/20 (5%) | 1/16 (6%) | 4/16 (25%)
First incidence (days) | 678 | 729 (T) | 729 (T) | 691
Poly-3 test | P = 0.023 | P = 0.302N | P = 0.294N | P = 0.158
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 2/50 (4%) | 10/50 (20%) | 10/50 (20%) | 14/50 (28%)
Adjusted rate | 5.0% | 24.1% | 23.3% | 32.5%
Terminal rate | 1/17 (6%) | 6/20 (30%) | 2/16 (13%) | 4/16 (25%)
First incidence (days) | 611 | 577 | 535 | 478
Poly-3 test | P = 0.011 | P = 0.015 | P = 0.018 | P < 0.001
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 0/50 (0%) | 16/50 (32%) | 34/50 (68%) | 36/50 (72%)
Adjusted rate | 0.0% | 38.2% | 76.8% | 80.6%
Terminal rate | 0/17 (0%) | 7/20 (35%) | 16/16 (100%) | 14/16 (88%)
First incidence (days) | – | 580 | 472 | 552
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 25/50 (50%) | 39/50 (50%) | 44/50 (88%)
Adjusted rate | 5.0% | 58.0% | 84.6% | 93.6%
Terminal rate | 1/17 (6%) | 13/20 (65%) | 16/16 (100%) | 16/16 (100%)
First incidence (days) | 611 | 577 | 472 | 478
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Pancreatic Islets: Adenoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 6/48 (13%) | 3/49 (6%)
Adjusted rate | 0.0% | 2.5% | 15.1% | 7.7%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 1/16 (6%) | 3/16 (19%)
First incidence (days) | – | 684 | 618 | 729 (T)
Poly-3 test | P = 0.052 | P = 0.504 | P = 0.015 | P = 0.116
Pancreatic Islets: Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 5/48 (10%) | 6/49 (12%)
Adjusted rate | 5.0% | 2.5% | 12.6% | 15.1%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 3/16 (19%) | 2/16 (13%)
First incidence (days) | 675 | 675 | 618 | 679
Poly-3 test | P = 0.021 | P = 0.496N | P = 0.213 | P = 0.129
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 10/48 (21%) | 9/49 (18%)
Adjusted rate | 5.0% | 4.9% | 24.7% | 22.6%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 3/16 (19%) | 5/16 (31%)
First incidence (days) | 675 | 675 | 618 | 679
Poly-3 test | P = 0.002 | P = 0.689N | P = 0.013 | P = 0.022
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 27/50 (54%) | 32/50 (64%) | 31/49 (63%) | 24/49 (49%)
Adjusted rate | 60.5% | 67.7% | 68.2% | 55.1%
Terminal rate | 8/17 (47%) | 10/20 (50%) | 10/15 (67%) | 6/15 (40%)
First incidence (days) | 441 | 413 | 472 | 470
Poly-3 test | P = 0.219N | P = 0.305 | P = 0.289 | P = 0.377N
Preputial Gland: Carcinoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 1/49 (2%) | 3/48 (6%)
Adjusted rate | 5.0% | 0.0% | 2.5% | 7.8%
Terminal rate | 0/17 (0%) | 0/20 (0%) | 0/16 (0%) | 1/15 (7%)
First incidence (days) | 562 | – | 598 | 572
Poly-3 test | P = 0.155 | P = 0.237N | P = 0.497N | P = 0.483
Preputial Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/49 (2%) | 3/48 (6%)
Adjusted rate | 7.5% | 2.5% | 2.5% | 7.8%
Terminal rate | 1/17 (6%) | 1/20 (5%) | 0/16 (0%) | 1/15 (7%)
First incidence (days) | 562 | 729 (T) | 598 | 572
Poly-3 test | P = 0.406 | P = 0.305N | P = 0.301N | P = 0.646
Skin: Keratoacanthoma
Overall rate | 4/50 (8%) | 6/50 (12%) | 7/50 (14%) | 2/50 (4%)
Adjusted rate | 9.9% | 14.7% | 16.4% | 5.0%
Terminal rate | 3/17 (18%) | 3/20 (15%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 376 | 580 | 582 | 652
Poly-3 test | P = 0.212N | P = 0.376 | P = 0.292 | P = 0.337N
Skin: Basal Cell Adenoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 5.0% | 0.0% | 2.4% | 7.5%
Terminal rate | 1/17 (6%) | 0/20 (0%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 542 | – | 705 | 689
Poly-3 test | P = 0.165 | P = 0.236N | P = 0.492N | P = 0.502
Skin: Trichoepithelioma or Basal Cell Adenoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 9.9% | 0.0% | 2.4% | 9.9%
Terminal rate | 1/17 (6%) | 0/20 (0%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 542 | – | 705 | 689
Poly-3 test | P = 0.248 | P = 0.060N | P = 0.172N | P = 0.643
Skin: Trichoepithelioma, Basal Cell Adenoma, or Basal Cell Carcinoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 9.9% | 0.0% | 4.8% | 9.9%
Terminal rate | 1/17 (6%) | 0/20 (0%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 542 | – | 652 | 689
Poly-3 test | P = 0.229 | P = 0.060N | P = 0.326N | P = 0.643
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 4/50 (8%) | 8/50 (16%) | 7/50 (14%) | 2/50 (4%)
Adjusted rate | 9.9% | 19.3% | 16.4% | 5.0%
Terminal rate | 3/17 (18%) | 3/20 (15%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 376 | 580 | 582 | 652
Poly-3 test | P = 0.120N | P = 0.186 | P = 0.292 | P = 0.337N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 5/50 (10%) | 8/50 (16%) | 7/50 (14%) | 2/50 (4%)
Adjusted rate | 12.4% | 19.3% | 16.4% | 5.0%
Terminal rate | 3/17 (18%) | 3/20 (15%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 376 | 580 | 582 | 652
Poly-3 test | P = 0.086N | P = 0.290 | P = 0.418 | P = 0.215N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Trichoepithelioma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 8/50 (16%) | 8/50 (16%) | 8/50 (16%) | 6/50 (12%)
Adjusted rate | 19.4% | 19.3% | 18.6% | 14.8%
Terminal rate | 3/17 (18%) | 3/20 (15%) | 0/16 (0%) | 2/16 (13%)
First incidence (days) | 376 | 580 | 582 | 652
Poly-3 test | P = 0.322N | P = 0.605N | P = 0.574N | P = 0.398N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 2/50 (4%) | 3/50 (6%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 5.0% | 7.5% | 7.2% | 0.0%
Terminal rate | 0/17 (0%) | 2/20 (10%) | 1/16 (6%) | 0/16 (0%)
First incidence (days) | 682 | 674 | 628 | –
Poly-3 test | P = 0.137N | P = 0.506 | P = 0.519 | P = 0.236N
Skin (Subcutaneous Tissue): Fibrous Histiocytoma or Fibroma
Overall rate | 2/50 (4%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 5.0% | 7.5% | 7.2% | 4.9%
Terminal rate | 0/17 (0%) | 2/20 (10%) | 1/16 (6%) | 0/16 (0%)
First incidence (days) | 682 | 674 | 628 | 516
Poly-3 test | P = 0.487N | P = 0.506 | P = 0.519 | P = 0.683N
Testes: Adenoma
Overall rate | 35/50 (70%) | 39/50 (78%) | 34/50 (68%) | 29/50 (58%)
Adjusted rate | 78.6% | 87.3% | 76.3% | 65.2%
Terminal rate | 15/17(88%) | 19/20 (95%) | 15/16 (94%) | 10/16 (63%)
First incidence (days) | 441 | 540 | 548 | 552
Poly-3 test | P = 0.008N | P = 0.176 | P = 0.499N | P = 0.103N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 4/49 (8%) | 8/50 (16%) | 8/50 (16%) | 7/49 (14%)
Adjusted rate | 10.2% | 19.5% | 18.9% | 17.5%
Terminal rate | 2/17 (12%) | 5/20 (25%) | 2/16 (13%) | 4/16 (25%)
First incidence (days) | 613 | 562 | 548 | 618
Poly-3 test | P = 0.379 | P = 0.196 | P = 0.213 | P = 0.271
Thyroid Gland (C-Cell): Carcinoma
Overall rate | 1/49 (2%) | 2/50 (4%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 2.6% | 5.0% | 7.3% | 2.5%
Terminal rate | 0/17 (0%) | 2/20 (10%) | 2/16 (13%) | 0/16 (0%)
First incidence (days) | 670 | 729 (T) | 618 | 717
Poly-3 test | P = 0.545N | P = 0.512 | P = 0.328 | P = 0.757N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 5/49 (10%) | 10/50 (20%) | 11/50 (22%) | 8/49 (16%)
Adjusted rate | 12.7% | 24.4% | 25.8% | 20.0%
Terminal rate | 2/17 (12%) | 7/20 (35%) | 4/16 (25%) | 4/16 (25%)
First incidence (days) | 613 | 562 | 548 | 618
Poly-3 test | P = 0.411 | P = 0.143 | P = 0.110 | P = 0.284
Zymbal’s Gland: Carcinoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 7.4% | 7.4% | 0.0% | 2.5%
Terminal rate | 1/17 (6%) | 1/20 (5%) | 0/16 (0%) | 0/16 (0%)
First incidence (days) | 383 | 603 | – | 717
Poly-3 test | P = 0.102N | P = 0.662 | P = 0.117N | P = 0.311N
Zymbal’s Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 9.7% | 7.4% | 0.0% | 2.5%
Terminal rate | 1/17 (6%) | 1/20 (5%) | 0/16 (0%) | 0/16 (0%)
First incidence (days) | 383 | 603 | – | 717
Poly-3 test | P = 0.063N | P = 0.508N | P = 0.060N | P = 0.186N
All Organs: Malignant Mesothelioma
Overall rate | 2/50 (4%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 5.0% | 7.4% | 0.0% | 2.5%
Terminal rate | 1/17 (6%) | 1/20 (5%) | 0/16 (0%) | 1/16 (6%)
First incidence (days) | 441 | 663 | – | 729 (T)
Poly-3 test | P = 0.163N | P = 0.503 | P = 0.233N | P = 0.503N
All Organs: Mononuclear Cell Leukemia
Overall rate | 21/50 (42%) | 25/50 (50%) | 22/50 (44%) | 22/50 (44%)
Adjusted rate | 48.9% | 58.0% | 50.2% | 47.9%
Terminal rate | 7/17 (41%) | 15/20 (75%) | 7/16 (44%) | 4/16 (25%)
First incidence (days) | 519 | 540 | 582 | 478
Poly-3 test | P = 0.296N | P = 0.257 | P = 0.541 | P = 0.547N
All Organs: Benign Neoplasms
Overall rate | 47/50 (94%) | 49/50 (98%) | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 97.4% | 98.9% | 98.8% | 96.9%
Terminal rate | 17/17 (100%) | 20/20 (100%) | 16/16 (100%) | 16/16 (100%)
First incidence (days) | 376 | 413 | 472 | 470
Poly-3 test | P = 0.436N | P = 0.613 | P = 0.627 | P = 0.719N
All Organs: Malignant Neoplasms
Overall rate | 31/50 (62%) | 37/50 (74%) | 42/50 (84%) | 48/50 (96%)
Adjusted rate | 66.3% | 82.4% | 89.7% | 97.4%
Terminal rate | 7/17 (41%) | 18/20 (90%) | 16/16 (100%) | 15/16 (94%)
First incidence (days) | 383 | 540 | 472 | 478
Poly-3 test | P < 0.001 | P = 0.051 | P = 0.003 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 50/50 (100%) | 50/50 (100%) | 49/50 (98%) | 50/50 (100%)
Adjusted rate | 100.0% | 100.0% | 98.8% | 100.0%
Terminal rate | 17/17 (100%) | 20/20 (100%) | 16/16 (100%) | 16/16 (100%)
First incidence (days) | 376 | 413 | 472 | 470
Poly-3 test | P = 0.776N | – | P = 0.761N | –

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, kidney, lung, pancreatic islets, pituitary gland, preputial gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Male F344/NTac Rats^a^

| Adenoma | Carcinoma | Adenoma or Carcinoma
Overall Historical Incidence: All Routes
Total (%) | 5/100 (5.0%) | 0/100 | 5/100 (5.0%)
Mean ± standard deviation | 5.0% ± 1.4% | – | 5.0% ± 1.4%
Range | 4%–6% | – | 4%–6%

^a^ Data as of June 2013.

Table A-4 Historical Incidence of Pheochromocytoma of the Adrenal Medulla in Control Male F344/NTac Rats^a^

| Benign | Malignant | Benign or Malignant
Overall Historical Incidence: All Routes
Total (%) | 25/100 (25.0%) | 2/100 (2.0%) | 27/100 (27.0%)
Mean ± standard deviation | 25.0% ± 7.1% | 2.0% ± 2.8% | 27.0% ± 9.9%
Range | 20%–30% | 0%–4% | 20%–34%

^a^ Data as of June 2013.

Table A-5 Historical Incidence of Pancreatic Islet Neoplasms in Control Male F344/NTac Rats^a^

| Adenoma | Carcinoma | Adenoma or Carcinoma
Overall Historical Incidence: All Routes
Total (%) | 0/100 | 2/100 (2.0%) | 2/100 (2.0%)
Mean ± standard deviation | – | 2.0% ± 2.8% | 2.0% ± 2.8%
Range | – | 0%–4% | 0%–4%

^a^ Data as of June 2013.

Table A-6 Historical Incidence of Renal Tubule Neoplasms in Control Male F344/NTac Rats^a^

| Adenoma | Carcinoma | Adenoma or Carcinoma
Overall Historical Incidence: All Routes
Total (%) | 1/100 (1.0%) | 0/100 | 1/100 (1.0%)
Mean ± standard deviation | 1.0% ± 1.41% | – | 1.0% ± 1.41%
Range | 0%–2% | – | 0%–2%

^a^ Data as of June 2013.

Table A-7 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of Cobalt Metal^a^

| Chamber Control | 1.25 mg/m^3^ | 2.5 mg/m^3^ | 5 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | 1 | –
Moribund | 28 | 28 | 27 | 32
Natural deaths | 5 | 2 | 6 | 2
Survivors
Terminal kill | 17 | 20 | 16 | 16
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (48) | (48)
Inflammation, suppurative | 1 (2%) | – | – | –
Intestine large, cecum | (49) | (50) | (49) | (50)
Inflammation, granulomatous | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (49) | (50)
Epithelium, hyperplasia | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (49) | (49) | (49)
Intestine small, duodenum | (50) | (50) | (49) | (50)
Inflammation, chronic active | – | – | 5 (10%) | –
Necrosis | – | – | 1 (2%) | 1 (2%)
Intestine small, ileum | (48) | (50) | (47) | (50)
Inflammation, suppurative | – | – | 1 (2%) | –
Epithelium, hyperplasia | – | – | 1 (2%) | –
Intestine small, jejunum | (48) | (49) | (48) | (49)
Epithelium, hyperplasia | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | 2 (4%)
Basophilic focus | 5 (10%) | 17 (34%) | 17 (34%) | 19 (38%)
Clear cell focus | 9 (18%) | 11 (22%) | 7 (14%) | 9 (18%)
Degeneration, cystic | – | 5 (10%) | – | 1 (2%)
Eosinophilic focus | 3 (6%) | 2 (4%) | – | 1 (2%)
Fatty change | 2 (4%) | 4 (8%) | 3 (6%) | 4 (8%)
Hepatodiaphragmatic nodule | 4 (8%) | 9 (18%) | 11 (22%) | 9 (18%)
Inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Mixed cell focus | – | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis | 5 (10%) | 6 (12%) | 4 (8%) | 2 (4%)
Regeneration | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Bile duct, hyperplasia | 1 (2%) | – | – | –
Mesentery | (18) | (4) | (9) | (3)
Infiltration cellular | – | – | 1 (11%) | –
Artery, inflammation, chronic active | – | – | – | 1 (33%)
Artery, thrombosis | 1 (6%) | – | – | –
Fat, necrosis | 14 (78%) | 4 (100%) | 8 (89%) | 1 (33%)
Pancreas | (50) | (50) | (49) | (50)
Acinus, atrophy | 23 (46%) | 35 (70%) | 28 (57%) | 30 (60%)
Acinus, hyperplasia | 1 (2%) | – | – | –
Artery, mineralization | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Degeneration | – | – | – | 1 (2%)
Stomach, forestomac^h^ | (50) | (50) | (50) | (50)
Edema | 2 (4%) | – | – | –
Hyperplasia, squamous | 10 (20%) | 14 (28%) | 13 (26%) | 11 (22%)
Inflammation, chronic active | 2 (4%) | 4 (8%) | 2 (4%) | 1 (2%)
Mineralization | 2 (4%) | – | – | –
Ulcer | 4 (8%) | 4 (8%) | 10 (20%) | 2 (4%)
Stomach, glandular | (50) | (50) | (49) | (50)
Edema | 1 (2%) | – | – | –
Erosion | – | 1 (2%) | 2 (4%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | 1 (2%)
Mineralization | 1 (2%) | – | – | –
Ulcer | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Tooth | (0) | (2) | (0) | (0)
Inflammation, chronic active | – | 2 (100%) | – | –
Cardiovascular System
Blood vessel | (1) | (1) | (0) | (0)
Aorta, mineralization | 1 (100%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 45 (90%) | 44 (88%) | 46 (92%) | 39 (78%)
Inflammation, suppurative | – | 1 (2%) | 2 (4%) | –
Thrombosis | 4 (8%) | 2 (4%) | 2 (4%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Atrium, congestion | – | 1 (2%) | 1 (2%) | –
Epicardium, hyperplasia | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 3 (6%) | – | 2 (4%) | 3 (6%)
Atrophy | – | 1 (2%) | – | –
Degeneration | 1 (2%) | – | – | –
Hyperplasia | 35 (70%) | 24(48%) | 23 (46%) | 29 (58%)
Necrosis | – | 1 (2%) | 1 (2%) | –
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 19 (38%) | 21(42%) | 9 (18%) | 9 (18%)
Necrosis | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (48) | (49)
Hyperplasia | – | 1 (2%) | 1 (2%) | 3 (6%)
Parathyroid gland | (45) | (45) | (47) | (46)
Pituitary gland | (50) | (50) | (49) | (49)
Angiectasis | 1 (2%) | – | – | 1 (2%)
Cyst | 1 (2%) | – | – | –
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Pars distalis, hyperplasia | 18 (36%) | 12 (24%) | 14 (29%) | 22 (45%)
Thyroid gland | (49) | (50) | (50) | (49)
Hemorrhage | 1 (2%) | – | – | –
C-cell, hyperplasia | 7 (14%) | 8 (16%) | 5 (10%) | 9 (18%)
Follicle, cyst | – | – | – | 1 (2%)
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Penis | (0) | (1) | (0) | (0)
Concretion | – | 1 (100%) | – | –
Preputial gland | (50) | (50) | (49) | (48)
Atrophy | – | – | – | 1 (2%)
Ectasia | 3 (6%) | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | 5 (10%) | 4 (8%) | 3 (6%) | 3 (6%)
Prostate gland | (50) | (50) | (50) | (50)
Fibrosis | – | – | 1 (2%) | –
Hyperplasia | 1 (2%) | 6 (12%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | 36 (72%) | 39 (78%) | 42 (84%) | 28 (56%)
Seminal vesicle | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Atrophy | 35 (70%) | 34 (68%) | 36 (72%) | 39 (78%)
Infarct | 1 (2%) | – | 2 (4%) | 12 (24%)
Arteriole, inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Interstitial cell, hyperplasia | 7 (14%) | 10 (20%) | 12 (24%) | 12 (24%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Necrosis | – | – | 1 (2%) | –
Lymph node | (12) | (9) | (5) | (9)
Iliac, ectasia | 1 (8%) | – | – | –
Iliac, lumbar, ectasia | – | 1 (11%) | – | –
Iliac, renal, ectasia | – | 1 (11%) | – | –
Lumbar, hyperplasia | – | 1 (11%) | – | –
Pancreatic, ectasia | 1 (8%) | – | – | 1 (11%)
Pancreatic, infiltration cellular, histiocyte | – | – | 1 (20%) | –
Pancreatic, necrosis | – | 1 (11%) | – | –
Renal, ectasia | 2 (17%) | 3 (33%) | 1 (20%) | 1 (11%)
Renal, hemorrhage | – | – | – | 1 (11%)
Lymph node, bronchial | (27) | (25) | (21) | (20)
Lymph node, mandibular | (48) | (49) | (50) | (48)
Atrophy | 1 (2%) | – | – | –
Congestion | – | 1 (2%) | – | –
Ectasia | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Necrosis | 1 (2%) | 1 (2%) | – | –
Lymph node, mediastinal | (46) | (48) | (46) | (48)
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Lymph node, mesenteric | (49) | (50) | (49) | (49)
Hemorrhage | 1 (2%) | – | – | –
Infiltration cellular, histiocyte | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Congestion | – | 1 (2%) | – | –
Fibrosis | 8 (16%) | 8 (16%) | 7 (14%) | 4 (8%)
Hematopoietic cell proliferation | 3 (6%) | 2 (4%) | – | 3 (6%)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Necrosis | 3 (6%) | 2 (4%) | 1 (2%) | 6 (12%)
Stromal hyperplasia | – | – | 1 (2%) | –
Capsule, angiectasis | 1 (2%) | – | – | –
Thymus | (46) | (44) | (47) | (46)
Integumentary System
Mammary gland | (31) | (32) | (30) | (31)
Galactocele | 2 (6%) | 1 (3%) | 1 (3%) | –
Hyperplasia | 2 (6%) | 1 (3%) | 1 (3%) | –
Inflammation, chronic active | 1 (3%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | – | 1 (2%)
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia, squamous | 2 (4%) | 2 (4%) | 5 (10%) | 1 (2%)
Inflammation | 7 (14%) | 5 (10%) | 9 (18%) | 4 (8%)
Inflammation, granulomatous | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Cranium, fibrosis | – | 1 (2%) | – | –
Cranium, fracture | – | – | 1 (2%) | –
Cranium, inflammation, chronic active | – | 1 (2%) | – | –
Maxilla, inflammation, chronic active | – | – | – | 1 (2%)
Vertebra, degeneration | – | 1 (2%) | – | –
Skeletal muscle | (1) | (0) | (0) | (4)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 15 (30%) | 14 (28%) | 18 (36%) | 7 (14%)
Edema | 2 (4%) | – | – | 1 (2%)
Hemorrhage | 2 (4%) | 3 (6%) | 4 (8%) | 3 (6%)
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | 1 (2%)
Metaplasia, osseous | 1 (2%) | – | – | –
Meninges, inflammation, suppurative | 1 (2%) | – | – | –
Spinal cord | (1) | (0) | (0) | (0)
Infiltration cellular | 1 (100%) | – | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Autolysis | – | – | 1 (2%) | –
Foreign body | 3 (6%) | – | 2 (4%) | –
Hyperkeratosis | – | – | – | 1 (2%)
Inflammation | 28 (56%) | 18 (36%) | 18 (36%) | 16 (32%)
Metaplasia, squamous | 3 (6%) | 1 (2%) | 1 (2%) | 2 (4%)
Ulcer | 1 (2%) | – | – | –
Respiratory epithelium, hyperplasia | – | – | – | 1 (2%)
Squamous epithelium, hyperplasia | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | 22 (44%) | 50 (100%) | 50 (100%) | 50 (100%)
Metaplasia, osseous | 3 (6%) | 3 (6%) | – | –
Mineralization | 1 (2%) | – | – | –
Thrombosis | 2 (4%) | – | – | –
Alveolar epithelium, hyperplasia | 3 (6%) | 47 (94%) | 49 (98%) | 49 (98%)
Alveolus, proteinosis | – | 48 (96%) | 49 (98%) | 49 (98%)
Artery, mediastinum, inflammation, chronic active | – | 1 (2%) | – | –
Bronchiole, epithelium, hyperplasia | – | 44 (88%) | 47 (94%) | 50 (100%)
Mediastinum, inflammation, suppurative | – | – | 1 (2%) | –
Mediastinum, metaplasia, osseous | – | 1 (2%) | – | –
Nose | (48) | (47) | (45) | (50)
Foreign body | 5 (10%) | 2 (4%) | 4 (9%) | 5 (10%)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, suppurative | 9 (19%) | 12 (26%) | 24 (53%) | 46 (92%)
Inflammation, chronic active | 28 (58%) | 35 (74%) | 40 (89%) | 49 (98%)
Thrombosis | 7 (15%) | 2 (4%) | 4 (9%) | 2 (4%)
Olfactory epithelium, accumulation, hyaline droplet | 2 (4%) | 4 (9%) | 1 (2%) | 2 (4%)
Olfactory epithelium, atrophy | 2 (4%) | 21 (45%) | 34 (76%) | 29 (58%)
Olfactory epithelium, hyperplasia | – | 1 (2%) | 2 (4%) | 7 (14%)
Olfactory epithelium, hyperplasia, basal cell | – | 1 (2%) | – | 13 (26%)
Olfactory epithelium, metaplasia, respiratory | 12 (25%) | 26 (55%) | 37 (82%) | 50 (100%)
Olfactory epithelium, necrosis | – | 1 (2%) | 5 (11%) | 5 (10%)
Respiratory epithelium, hyperplasia | 20 (42%) | 35 (74%) | 45 (100%) | 50 (100%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | 11 (24%) | 35 (70%)
Respiratory epithelium, necrosis | 1 (2%) | 4 (9%) | 5 (11%) | 13 (26%)
Turbinate, atrophy | 1 (2%) | 35 (74%) | 35 (78%) | 41 (82%)
Turbinate, hyperostosis | 2 (4%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | – | – | 1 (2%)
Metaplasia, squamous | – | – | – | 1 (2%)
Special Senses System
Ear | (1) | (5) | (0) | (0)
Inflammation, chronic active | 1 (100%) | 5 (100%) | – | –
Eye | (50) | (50) | (50) | (50)
Cataract | 3 (6%) | 9 (18%) | 9 (18%) | 7 (14%)
Inflammation, suppurative | 1 (2%) | – | – | –
Metaplasia, osseous | 31 (62%) | 36 (72%) | 33 (66%) | 31 (62%)
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (4) | (3) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | 1 (2%) | 4 (8%) | 1 (2%)
Congestion | – | – | 1 (2%) | –
Cyst | – | 3 (6%) | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Infarct | 2 (4%) | – | – | 1 (2%)
Metaplasia, osseous | – | – | – | 1 (2%)
Nephropathy | 49 (98%) | 49 (98%) | 50 (100%) | 50 (100%)
Thrombosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Pelvis, inflammation, suppurative | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | – | – | –
Inflammation | | – | 2 (4%) | 1 (2%)
Inflammation, granulomatous | 2 (4%) | – | – | –
Transitional epithelium, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.