# Peer Review

The draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of β-Picoline (CASRN 108-99-6) in F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Technical Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Stephen M. Roberts, Ph.D., Chairperson
  College of Veterinary Medicine
  University of Florida
  Gainesville, Florida, USA
- Jane Alcorn, D.V.M., Ph.D., Primary Reviewer
  University of Saskatchewan
  Saskatchewan, Canada
- Lucy M. Anderson, Ph.D., Consultant
  Catonsville, Maryland, USA
- Hillary M. Carpenter, III, Ph.D.
  Minnesota Department of Health
  St. Paul, Minnesota, USA
- Russell C. Cattley, V.M.D., Ph.D.
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama, USA
- Michael R. Elwell, D.V.M., Ph.D.
  Covance Laboratories, Inc.
  Chantilly, Virginia, USA
- Jon C. Mirsalis, Ph.D., Primary Reviewer
  SRI International
  Menlo Park, California, USA
- Ofelia A. Olivero, Ph.D.
  National Cancer Institute
  Bethesda, Maryland, USA
- Lisa A. Peterson, Ph.D.
  University of Minnesota
  Minneapolis, Minnesota, USA
- Michael V. Pino, D.V.M., Ph.D., Primary Reviewer
  Sanofi-Aventis
  Bridgewater, New Jersey, USA
- Keith A. Soper, Ph.D.
  Merck Research Laboratories
  West Point, Pennsylvania, USA