# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.E. Wyde, Ph.D., Study Scientist
  S.A. Elmore, D.V.M., M.S., Study Pathologist
  J.B. Bishop, Ph.D.
  R.S. Chhabra, Ph.D.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  J.H. Roycroft, Ph.D.
  C.S. Smith, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.A. Colleton, D.V.M.
  S.L. Grumbein, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  E.T. Adams, D.V.M., Ph.D.
  A.E. Brix, D.V.M., Ph.D.
  R.R. Moore, D.V.M., Ph.D.
  A.K. Pandiri, Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  G.D. Hill, D.V.M., Ph.D., Coordinated 2-year rats (January 14, 2010)
  P. Blackshear, D.V.M., Ph.D., Coordinated 2-year mice (April 13, 2010)
- Gene Logic Laboratories, Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  G.W. Wolfe, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.