# References

1 Budavari Seditor. The Merck Index. 12th ed. Whitehouse Station (NJ): Merck and Company, Inc.; 1996. p. 1273.
2 Hazardous Substance Data Bank (HSDB). 3-Methylpyridine. 2011. http://toxnet.nlm.nih.gov/cgi-bin/sis/search/f?./temp/~4dLAwt:1:BASIC [Accessed: August 8, 2011]
3 Trochimowicz HJ Kennedy GL Krivanek ND Alkylpyridines and miscellaneous organic nitrogen compounds. In: Bingham E Cohrssen B Powell CHeditors. Patty’s Industrial Hygiene and Toxicology. 5th ed. New York (NY): John Wiley and Sons; 2001. p. 1198. http://dx.doi.org/10.1002/0471435139.tox060
4 U. S. Environmental Protection Agency (USEPA). OPPT High Production Volume Chemicals. Washington (DC): USEPA, Office of Pollution Prevention and Toxics; 1998.
5 Lewis RJeditor. Hawley’s condensed chemical dictionary. 14th ed. New York (NY): John Wiley & Sons, Inc.; 2001. p. 878.
6 Jain SM Kant R Sarin AN Dhar SK Dhar KL Synthesis and analgesic activity of nitrogen heterocyclic derivatives of embelin. Indian J Chem Sect B. 1989; 28(9):790–792.
7 Lewis RJeditor. Hawley’s condensed chemical dictionary. 12th ed. New York (NY): Van Nostrand Reinhold Co.; 1993. p. 915.
8 Code of Federal Regulations (CFR). 40:Part 63, Subpart F.
9 Code of Federal Regulations (CFR). 40:Part 721.
10 Code of Federal Regulations (CFR). 40:Part 716.
11 Code of Federal Regulations (CFR). 46:Part 150, Table II.
12 Code of Federal Regulations (CFR). 49:Part 172, Subpart B.
13 Gorrod JW Damani LA Some factors involved in the N-oxidation of 3-substituted pyridines by microsomal preparations in vitro. Xenobiotica. 1979; 9(4):209–218. http://dx.doi.org/10.3109/00498257909038723 483857
14 Gorrod JW Damani LA The metabolic N-oxidation of 3-substituted pyridines in various animal species in vivo. Eur J Drug Metab Pharmacokinet. 1980; 5(1):53–57. http://dx.doi.org/10.1007/BF03189445 7389753
15 Dyer RS Burdette LJ Janssen R Boyes WK Neurophysiological consequences of acute exposure to methylpyridines. Fundam Appl Toxicol. 1985; 5(5):920–932. http://dx.doi.org/10.1016/0272-0590(85)90174-5 4065464
16 Dutertre-Catella H Phu-Lich N Huyen VN Olivier L Truhaut R Claude JC Eye and skin irritation induced by picolines. Arch Toxicol Suppl. 1989; 13:428–432. http://dx.doi.org/10.1007/978-3-642-74117-3_84 2774971
17 National Toxicology Program (NTP). NTP toxicology and carcinogenesis studies of pyridine (CAS No. 110-86-1) in F344/N rats, Wistar rats, and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 470. NIH Publication No. 00-3960.
18 Claxton LD Dearfield KL Spanggord RJ Riccio ES Mortelmans K Comparative mutagenicity of halogenated pyridines in the Salmonella typhimurium/mammalian microsome test. Mutat Res. 1987; 176(2):185–198. http://dx.doi.org/10.1016/0027-5107(87)90049-2 3543664
19 Haworth S Lawlor T Mortelmans K Speck W Zeiger E Salmonella mutagenicity test results for 250 chemicals. Environ Mutagen. 1983; 5 Suppl 1:1–142. http://dx.doi.org/10.1002/em.2860050703 6365529
20 Ho C-H Clark BR Guerin MR Barkenbus BD Rao TK Epler JL Analytical and biological analyses of test materials from the synthetic fuel technologies: IV. Studies of chemical structure-mutagenic activity relationships of aromatic nitrogen compounds relevant to synfuels. Mutat Res. 1981; 85(5):335–345. 10.1016/0165-1161(81)90224-7 7029261
21 Pearce RE McIntyre CJ Madan A Sanzgiri U Draper AJ Bullock PL Cook DC Burton LA Latham J Nevins C Effects of freezing, thawing, and storing human liver microsomes on cytochrome P450 activity. Arch Biochem Biophys. 1996; 331(2):145–169. http://dx.doi.org/10.1006/abbi.1996.0294 8660694
22 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
23 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
24 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
25 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53:457–481. http://dx.doi.org/10.1080/01621459.1958.10501452
26 Cox DR Regression models and life-tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–220.
27 Tarone RE Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–682. http://dx.doi.org/10.1093/biomet/62.3.679
28 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. http://dx.doi.org/10.2307/2531856 3390507
29 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. http://dx.doi.org/10.1016/0272-0590(89)90004-3 2744275
30 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology, Section 6.3.2. London, UK: Chapman and Hall; 1997.
31 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
32 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. http://dx.doi.org/10.2307/2532200 8241374
33 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
34 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
35 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
36 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
37 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
38 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
39 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. http://dx.doi.org/10.1093/biomet/41.1-2.133
40 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill Book Company, Inc.; 1957. p. 276-278; 412. http://dx.doi.org/10.2307/2332898
41 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
42 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
43 Rao GN New diet (NTP-2000) for rats in the National Toxicology Program toxicity and carcinogenicity studies. Fundam Appl Toxicol. 1996; 32(1):102–108. http://dx.doi.org/10.1006/faat.1996.0112 8812243
44 Rao GN New nonpurified diet (NTP-2000) for rodents in the National Toxicology Program’s toxicology and carcinogenesis studies. J Nutr. 1997; 127(5) Suppl:842S–846S. http://dx.doi.org/10.1093/jn/127.5.842S 9164250
45 Code of Federal Regulations (CFR). 21:Part 58.
46 Schmid W The micronucleus test. Mutat Res. 1975; 31(1):9–15. http://dx.doi.org/10.1016/0165-1161(75)90058-8 48190
47 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. http://dx.doi.org/10.1016/0165-1110(83)90047-7 6888413
48 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
49 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
50 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc.; 1972. p. 13–59.
51 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. http://dx.doi.org/10.1016/0165-1110(91)90003-E 1707500
52 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. http://dx.doi.org/10.1126/science.3554512 3554512
53 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. http://dx.doi.org/10.1002/em.2850160502 2091921
54 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. http://dx.doi.org/10.1002/em.2850210210 8444144
55 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. http://dx.doi.org/10.1002/em.2850250407 7607185
56 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. http://dx.doi.org/10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P (http://dx.doi.org/10.1002/1098-2280(2000)36:3%3c163::AID-EM1%3e3.0.CO;2-P) 11044899
57 Kim H Putt D Reddy S Hollenberg PF Novak RF Enhanced expression of rat hepatic CYP2B1/2B2 and 2E1 by pyridine: differential induction kinetics and molecular basis of expression. J Pharmacol Exp Ther. 1993; 267(2):927–936. 8246169
58 Kim H Putt DA Zangar RC Wolf CR Guengerich FP Edwards RJ Hollenberg PF Novak RF Differential induction of rat hepatic cytochromes P450 3A1, 3A2, 2B1, 2B2, and 2E1 in response to pyridine treatment. Drug Metab Dispos. 2001; 29(3):353–360. 11181506
59 Zangar RC Woodcroft KJ Kocarek TA Novak RF Xenobiotic-enhanced expression of cytochrome P450 2E1 and 2B1/2B2 in primary cultured rat hepatocytes. Drug Metab Dispos. 1995; 23(7):681–687. 7587954
60 Doi AM Hill G Seely J Hailey JR Kissling G Bucher JR alpha 2u-globulin nephropathy and renal tumors in national toxicology program studies. Toxicol Pathol. 2007; 35(4):533–540. http://dx.doi.org/10.1080/01926230701338941 17562486
61 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
62 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
63 The Aldrich Library of 13C and 1H FT-NMR Spectra. Milwaukee (WI): Aldrich Chemical Company, Inc.; 1993.
64 The Aldrich Library of FT-IR Spectra Spectrum III:3708B. Milwaukee (WI): Aldrich Chemical Company, Inc.; 1997.
65 Sadtler Standard Spectra, Sadtler Pesticide and Agricultural Chemical Library, Basic Monomers and Polymers Library, Know It All 6.0 Software. Philadelphia, PA: Sadtler Research Laboratories.