# Conclusions

Under the conditions of these 2-year drinking water studies, there was no evidence of carcinogenic activity^a^ of β-picoline in male F344/N rats exposed to 156.25, 312.5, or 625 mg/L. There was some evidence of carcinogenic activity of β-picoline in female F344/N rats based on increased incidences of alveolar/bronchiolar adenoma and alveolar/bronchiolar adenoma or carcinoma (combined). There was equivocal evidence of carcinogenic activity of β-picoline in male B6C3F1/N mice based on increased incidences of alveolar/bronchiolar adenoma and alveolar/bronchiolar adenoma or carcinoma (combined). There was clear evidence of carcinogenic activity of β-picoline in female B6C3F1/N mice based on the increased incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in the lung and of hepatocellular carcinoma and hepatoblastoma in the liver.

a See Explanation of Levels of Evidence of Carcinogenic Activity. A summary of the Peer Review Panel comments and the public discussion on this Technical Report appears in Appendix M.

Exposure to β-picoline caused increased incidences of nonneoplastic lesions of the lung in female mice and the nose in male and female mice.