# Discussion

β-Picoline was nominated by the National Institute of Environmental Health Sciences for toxicologic and carcinogenicity evaluation based on its high production volume and potential for human exposure. β-Picoline is used as a solvent, reagent, and intermediate in various commercial and industrial processes, and has been identified as a contaminant in drinking water and cigarette smoke. β-Picoline is structurally similar to pyridine, differing only in the presence of a methyl group on the 3-carbon in β-picoline. In previous studies by the National Toxicology Program,^17^ exposure to pyridine induced renal tubule neoplasms in male F344/N rats, and malignant hepatocellular neoplasms in male and female B6C3F1 mice. Minimal toxicology data are available, and no carcinogenicity studies are reported in the literature for β-picoline.

In the 3-month rat study, the estimated daily doses of β-picoline in rats exposed to drinking water concentrations of 78, 156, 312, 625, or 1,250 mg/L were 6, 11, 22, 38, or 70 mg β-picoline/kg body weight in males and 6, 12, 23, 38, or 64 mg/kg in females. Decreased body weights and palatability-related decreases in water consumption were observed in both sexes at 625 and 1,250 mg/L. In males, there were minor and transient increases in hematocrit values, erythrocyte counts, and hemoglobin, urea nitrogen, albumin, and total protein concentrations on day 4 that were consistent with the observed palatability-related decreases in water consumption. These effects were not observed in females.

In the kidney of male rats, there were increased concentrations of renal α2u-globulin at 312 mg/L or greater and increased severities of chronic progressive nephropathy at 625 mg/L or greater and hyaline droplet accumulation in the proximal tubules at 1,250 mg/L. These findings in the kidney were suggestive of weak α2u-globulin mediated nephropathy in male rats and are consistent with α2u-globulin-related kidney effects observed in the 3-month pyridine drinking water study.^17^ In the pyridine study, there were significantly increased incidences of protein casts, chronic inflammation, and mineralization and increased severities of renal tubule regeneration in male F344/N rats exposed to 500 or 1,000 ppm pyridine (equivalent to 55 and 90 mg/kg) and renal tubule hyaline degeneration and granular casts at 1,000 ppm. In contrast to pyridine, which significantly induced renal tubule adenomas and carcinomas in males at 400 ppm (equivalent to 33 mg/kg), no renal neoplasms were observed in the 2-year β-picoline study. While both β-picoline and pyridine similarly induced α2u-globulin-related lesions at 3-months, the mechanism for the differences in chronic renal responses between β-picoline and pyridine is unclear. Previous evaluation of results from 3-month and 2-year NTP studies with α2u-globulin-inducing chemicals suggests that none of the characteristic nonneoplastic endpoints or increases in α2u-globulin concentration observed in the 3-month studies were predictive of tumor outcome in the corresponding 2-year studies.^60^

While pyridine induces hepatic hypertrophy, chronic inflammation, centrilobular degeneration, and pigmentation in male and female F344/N and male Wistar rats,^17^ there were no treatment-related liver lesions observed following exposure to β-picoline for 3 months. There was, however, a dose-dependent increase in the activity of 7-pentoxyresorufin-O-dealkylase activity, a marker for cytochrome P4502B1, with significant increases observed at 312 mg/L or greater in males and 156 mg/L or greater in females. While the induction of liver toxicity differed between β-picoline and pyridine, the modulation of CYP2B1 by β-picoline was consistent with dose- and time-dependent expression demonstrated for pyridine.^57-59^

In the 3-month mouse study, exposure to β-picoline in drinking water at concentrations of 78, 156, 312, 625, or 1,250 mg/L resulted in estimated daily doses of 10, 20, 37, 77, or 148 mg/kg in males and 9, 18, 38, 72, or 134 mg/kg in females. Mice were less sensitive to the effects of β-picoline on body weight and drinking water palatability than rats. At estimated average daily doses nearly two-fold greater than in rats, there were no treatment-related effects on survival, body weights, water consumption, or incidences of gross or histopathologic lesions in the 3-month mouse study. The absence of kidney lesions in male and female mice and female rats further suggests a role for α2u-globulin in the lesions observed in the male rats.

The significantly higher probability of extended estrus of female rats in the 312 and 625 mg/L groups as observed through Markov transition matrix analyses of estrous cyclicity suggests a potential for β-picoline to be a reproductive toxicant in female rats exposed to these concentrations.

Based on the lower final mean body weights (16% and 14% less than controls in 1,250 mg/L males and females, respectively), decreased water consumption in both sexes, and the increased severity of nephropathy observed in males at 1,250 mg/L, β-picoline concentrations of 156.25, 312.5, and 625 mg/L in drinking water were selected for the 2-year rat study. These exposures in the 2-year study resulted in average daily doses of 6, 12, and 22 mg/kg β-picoline to male rats and 7, 14, and 26 mg/kg to female rats. Survival rates were comparable between the control and exposed groups of rats. Mean body weights were slightly lower in 625 mg/L males throughout the course of the study, and were decreased by a maximum of 10% at the end of the study. Mean body weights in 625 mg/L females were 9% less than those in controls for a 16-week period toward the end of the study.

In the 2-year rat study, the lung was a target organ. In the female rats, alveolar/bronchiolar adenomas were observed in all of the exposed groups, while none were observed in the concurrent controls. There was a significant increase in the incidence of this neoplasm in the 625 mg/L females that exceeded the historical control ranges for drinking water studies and for all routes of administration. One alveolar/bronchiolar carcinoma occurred in a 156.25 mg/L female. The incidences of alveolar epithelium hyperplasia and metaplasia were increased in exposed groups of females but were not significantly greater than those in the controls. Alveolar/bronchiolar carcinoma occurred in four 312.5 mg/L males and two 625 mg/L males but did not occur in controls or in males exposed to 156.25 mg/L. While the combined incidences of alveolar/bronchiolar adenoma or carcinoma in males were similar between the control and exposed groups, these observations may suggest a treatment-related progression from benign tumors to malignancy. These data suggest that increased incidences of alveolar/bronchiolar adenoma are specific to females, and that females are more sensitive to the induction of lung neoplasms by β-picoline.

Based on the lack of treatment-related effects observed in the 3-month study in mice, β-picoline concentrations of 312.5, 625, and 1,250 mg/L in drinking water were selected for the 2-year study in mice. These exposure concentrations in the 2-year study resulted in average daily doses of 26, 50, and 92 mg/kg β-picoline to male mice and 18, 37, and 68 mg/kg to female mice. These calculated doses reflect a 26% to 30% greater dose of β-picoline to males than to females. Survival of exposed groups of females was similar to that of the controls and there was an exposure concentration-dependent trend for slightly increased survival in males. In groups exposed to 1,250 mg/L, mean body weights were generally 10% less than those in controls with maximal decreases of 19% in males and 12% in females. Additionally, water consumption by 625 and 1,250 mg/L males and 1,250 mg/L females was less than that by the controls after the first 13 weeks of the study.

In the 2-year mouse study, liver and lung were target organs for β-picoline in females. In female mice, the incidences of hepatocellular carcinoma were significantly increased in all exposed groups. A single hepatoblastoma, a neoplasm with a somewhat rare background incidence in female B6C3F1/N mice, was observed in a control female. Hepatoblastomas occurred in three 312.5 mg/L females and four occurred in each of the 625 and 1,250 mg/L groups of females; all of these incidences exceeded the historical control ranges for drinking water studies and for all routes of administration. One female in the 625 mg/L group and one female in the 1,250 mg/L group had multiple hepatoblastomas. There were also increased numbers of animals with multiple hepatocellular adenomas. There was a high background incidence of hepatocellular adenoma (78%) in the current 2-year study, which complicates the determination of a treatment-related effect. However, the evidence for the hepatocarcinogenicity of β-picoline is primarily supported by increased incidences of hepatocellular carcinoma and hepatoblastoma. The increased incidences of those neoplasms suggest a treatment-mediated effect on the progression from benign to malignant tumors. Additionally, metastatic hepatocellular carcinomas were observed with a greater frequency in the lungs of all groups of exposed females (0 mg/L, 1/50; 312.5 mg/L, 5/50; 625 mg/L, 8/49; 1,250 mg/L, 4/50; Table D-1). A metastatic hepatoblastoma was also in one 1,250 mg/L female. There were no treatment-related effects on incidences of liver neoplasms in male mice. There were also no significant increases in the incidences of any nonneoplastic lesions in the liver of males or females.

The induction of liver neoplasms by β-picoline in female B6C3F1/N mice was similar to the effects observed in the 2-year study of pyridine.^17^ In that study, daily pyridine exposure in the drinking water induced hepatocellular neoplasms, including hepatoblastomas, in female mice at doses (15, 35, and 70 mg/kg) similar to those in the current study of β-picoline (18, 37, and 68 mg/kg). Additionally, pyridine administration significantly increased the incidences of multiple hepatocellular adenoma and carcinoma. Similar to β-picoline, there were no significant effects of treatment with pyridine on the incidences of nonneoplastic lesions in the liver. In contrast to β-picoline, the hepatic carcinogenicity of pyridine was not specific to females. Exposure to pyridine for 2 years resulted in significantly increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma in male mice, including treatment-related increases in multiplicities.

Similar to the effects observed in females in the 2-year rat study, the lung was a target organ in females in the 2-year mouse study. There was a positive trend in the incidences of alveolar/bronchiolar adenoma in female mice and a dose-dependent association between exposure and the incidences of alveolar/bronchiolar carcinoma. The incidence of alveolar/bronchiolar adenoma or carcinoma (combined) in 1,250 mg/L females was significantly increased compared to that in the controls. Additionally, incidences of multiple alveolar/bronchiolar adenoma and multiple alveolar/bronchiolar carcinoma occurred in most of the exposed groups of females, but no multiple lung neoplasms occurred in the controls. The incidence of alveolar epithelium hyperplasia, a potential precursor lesion in the neoplastic development of an adenoma, was significantly increased in 1,250 mg/L females. In male mice, the incidence of alveolar/bronchiolar adenoma was significantly increased in the 625 mg/L group compared to controls, and the time to first incidence was 260 days shorter than in controls. Multiple alveolar/bronchiolar adenomas were also observed in two males each from the 625 and 1,250 mg/L groups. Multiple alveolar/bronchiolar carcinomas were observed in two 312.5 mg/L males and three 1,250 mg/L males. However, the incidences in the 312.5 and 1,250 mg/L groups were not significantly different than that in the concurrent controls, and were within the historical control ranges for drinking water studies and for all routes of administration.

The lung was a sex-specific target organ for β-picoline in rats and mice; benign and malignant alveolar/bronchiolar neoplasms occurred in females. While the incidences of alveolar/bronchiolar adenoma in all exposed groups of male mice were greater than those in the controls, there was no dose-response relationship, and most of the incidences were within the historical control ranges. However, the increased incidence of alveolar/bronchiolar adenoma in 625 mg/L male mice was statistically significant, slightly exceeded the historical control ranges for drinking water studies and for all routes of administration, and occurred markedly earlier than in the controls. As a result, it was considered that the increased incidences of alveolar/bronchiolar adenoma in male mice may have been related to treatment. While lung lesions in the current study reflected differences between β-picoline and pyridine, liver lesions observed in female mice in the current study were consistent with the effects observed in both sexes of mice for pyridine.^17^

Administration of β-picoline in drinking water induced significantly increased incidences of olfactory epithelium atrophy in the nose of 1,250 mg/L female mice and olfactory epithelium respiratory metaplasia in 625 and 1,250 mg/L males and 1,250 mg/L females. Since β-picoline is considered a volatile organic compound, it is possible that inhalation of a volatilized fraction may have contributed to the observed olfactory lesions. Alternatively, the effects in the nasal cavity may have resulted from systemic exposure. These nasal effects were only observed in mice; the reason for the species specificity of these effects is unclear.