# Results

## Rats

### Three-month Study

All rats survived to the end of the study (Table 2). Final mean body weights and body weight gains of males and females exposed to 625 or 1,250 mg/L were significantly less than those of the controls (Table 2 and Figure 2). Water consumption by 625 and 1,250 mg/L males and females was less than that by the controls at weeks 1 and 13; this was attributed to unpalatability of the chemical at these concentrations. Drinking water concentrations of 78, 156, 312, 625, and 1,250 mg/L resulted in average daily doses of approximately 6, 11, 22, 38, and 70 mg β-picoline/kg body weight to males and 6, 12, 23, 38, and 64 mg/kg to females. There were no clinical findings related to exposure to β-picoline.

Table 2 Survival, Body Weights, and Water Consumption of Rats in the Three-month Drinking Water Study of β-Picoline^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 13
Male
0 | 10/10 | 101 ± 3 | 356 ± 5 | 255 ± 4 | | 14.3 | 16.1
78 | 10/10 | 101 ± 3 | 349 ± 7 | 248 ± 5 | 98 | 13.8 | 14.8
156 | 10/10 | 101 ± 2 | 352 ± 4 | 251 ± 4 | 99 | 12.9 | 15.4
312 | 10/10 | 103 ± 3 | 356 ± 4 | 253 ± 4 | 100 | 14.1 | 14.7
625 | 10/10 | 100 ± 3 | 332 ± 4** | 231 ± 5** | 93 | 10.2 | 11.4
1,250 | 10/10 | 102 ± 3 | 298 ± 5** | 196 ± 4** | 83 | 6.7 | 12.1
Female
0 | 10/10 | 95 ± 2 | 207 ± 5 | 112 ± 4 | | 11.8 | 10.7
78 | 10/10 | 97 ± 2 | 206 ± 2 | 109 ± 3 | 100 | 12.5 | 9.3
156 | 10/10 | 97 ± 2 | 205 ± 4 | 109 ± 3 | 99 | 12.3 | 10.5
312 | 10/10 | 98 ± 2 | 205 ± 3 | 105 ± 3 | 99 | 11.5 | 10.5
625 | 10/10 | 94 ± 2 | 192 ± 3** | 98 ± 2** | 93 | 7.9 | 8.8
1,250 | 10/10 | 94 ± 3 | 177 ± 4** | 83 ± 3** | 86 | 6.5 | 6.7

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 2

Growth Curves for Rats Exposed to β-Picoline in Drinking Water for Three Months

Pyridine, which is structurally similar to β-picoline, induces CYP2B1 protein and mRNA levels in cultured hepatocytes and rat liver.^57-59^ To investigate the effects of β-picoline on hepatic CYP 2B1, liver samples were collected on day 23 from special study rats. Microsomal suspensions were prepared from the liver samples and were assayed for 7-pentoxyresorufin-O-dealkylase (PROD) activity (a marker for CYP2B1 activity). Hepatic PROD activity was significantly increased in 312 mg/L or greater males and in 156 mg/L or greater females compared to that in the controls (Table 3). These findings indicate a dose-dependent hepatic enzyme induction in these groups.

Table 3 Hepatic 7-Pentoxyresorufin-O-dealkylase (PROD) Activity in Special Study Rats Administered β-Picoline for 23 Days in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
PROD^b^ | 3.736 ± 0.129 | 3.798 ± 0.153 | 3.891 ± 0.120 | 6.839 ± 0.674** | 10.815 ± 0.495** | 30.095 ± 5.443**
Female
PROD | 4.377 ± 0.129 | 4.476 ± 0.126 | 5.640 ± 0.226** | 8.365 ± 0.632** | 12.022 ± 0.492** | 15.450 ± 0.880**

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ pmol/minute per mg microsomal protein.

The hematology and clinical chemistry data for rats are presented in Table F-1, and there were minimal transient increases in hematocrit values, erythrocyte counts, and hemoglobin, urea nitrogen, albumin, and total protein concentrations in 1,250 mg/L male rats on day 4. The transient increases in these variables would be consistent with a reduced circulating plasma volume (i.e., dehydration) and a minor hemoconcentration. This transient effect was supported by the decreased water consumption noted at week 1. On day 23 and at week 13 there were minor decreases in serum albumin and total protein concentrations (in most instances less than 5%). Significant decreases in serum albumin concentrations were only noted in the 625 and 1,250 mg/L males at week 13; females were not affected. The potential significance of the minimal decreases was unknown but may be physiologically related to an altered nutritional status as suggested by the substantially decreased body weights.

Absolute liver weights of 625 and 1,250 mg/L males and absolute and relative liver weights of 625 and 1,250 mg/L females were significantly less than those of the controls (Table G-1). Other organ weight differences were related to reduced body weights.

There were no significant differences in sperm parameters of male rats exposed to 156, 312, or 625 mg/L when compared to the controls (Table H-1). Exposure-related decreases in testis weights were minimal (<10%) and accompanied parallel decreases in terminal body weights. The Markov transition matrix analyses of estrous cyclicity indicated female rats in the 312 and 625 mg/L groups had a significantly higher probability of extended estrus than the control females (Table H-2 and Table H-3; Figure H-1).

The severity of chronic progressive nephropathy was increased in 625 and 1,250 mg/L males and that of hyaline droplet accumulation in proximal renal tubules was increased in 1,250 mg/L males (Table 4). The concentrations of renal α2u-globulin were significantly increased in 312 mg/L or greater males compared to the controls (Table 4). These findings are consistent with α2u-globulin nephropathy.

Table 4 Incidences of Nonneoplastic Kidney Lesions and α2u-Globulin Concentrations for Male Rats in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
Number Examined Microscopically
| 10 | 10 | 10 | 10 | 10 | 10
Nephropathy^b^
| 10 (1.2)^c^ | 10 (1.0) | 10 (1.0) | 10 (1.2) | 10 (2.2) | 10 (2.9)
Renal Tubule, Accumulation, Hyaline Droplet
| 10 (1.3) | 10 (1.1) | 10 (1.2) | 10 (1.1) | 10 (1.0) | 10 (2.0)
α2u-Globulin Concentration (ng/mL)
| 2.044 ± 0.157 | 1.943 ± 0.113 | 1.893 ± 0.090 | 8.676 ± 0.478** | 9.955 ± 0.542** | 10.124 ± 0.458**
α2u-Globulin (ng/μg soluble protein)
| 42.74 ± 2.98 | 39.39 ± 2.37 | 38.76 ± 1.56 | 181.92 ± 9.62** | 214.52 ± 7.04** | 217.60 ± 11.16**
α2u-Globulin (nmol/g kidney)
| 174.9 ± 13.4 | 166.2 ± 9.6 | 161.9 ± 7.7 | 742.3 ± 40.9** | 851.8 ± 46.3** | 866.2 ± 39.2**
α2u-Globulin (mg/g kidney)
| 3.280 ± 0.249 | 3.110 ± 0.183 | 3.040 ± 0.140 | 13.910 ± 0.766** | 15.970 ± 0.864** | 16.210 ± 0.734**

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ α2u-Globulin data are given as mean ± standard error, n = 10. Statistical tests were performed on unrounded data.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure Concentration Selection Rationale: Based on decreased mean body weights (16% and 14% in males and females, respectively), decreased water consumption in both sexes, and the severity of nephropathy observed in males at 1,250 mg/L, β-picoline exposure concentrations selected for the 2-year drinking water study in rats were 156.25, 312.5, and 625 mg/L.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 5 and in the Kaplan-Meier survival curves (Figure 3). Survival of exposed groups of male and female rats was similar to that of the control groups.

Table 5 Survival of Rats in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 9 | 12 | 15 | 23
Natural deaths | 8 | 7 | 3 | 3
Animals surviving to study termination | 33 | 31 | 32 | 24
Percent probability of survival at end of study^a^ | 66 | 62 | 64 | 48
Mean survival (days)^b^ | 668 | 700 | 697 | 681
Survival analysis^c^ | P = 0.092 | P = 1.000 | P = 1.000 | P = 0.160
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 15 | 13 | 14 | 15
Natural deaths | 5 | 5 | 3 | 5
Animals surviving to study termination | 30^d^ | 32 | 33 | 30
Percent probability of survival at end of study | 60 | 64 | 66 | 60
Mean survival (days) | 688 | 688 | 700 | 686
Survival analysis | P = 0.951 | P = 0.853N | P = 0.671N | P = 1.000

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^27^ is in the control column, and the results of the life table pairwise comparisons^26^ with the controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^d^ Includes one animal that died during the last week of the study.

Figure 3

Kaplan-Meier Survival Curves for Rats Exposed to β-Picoline in Drinking Water for Two Years

### Body Weights, Water and Compound Consumption, and Clinical Findings

Mean body weights of the 156.25 and 312.5 mg/L groups of male and female rats were similar to those of the control groups throughout the study (Table 6 and Table 7; Figure 4). Mean body weights of 625 mg/L males were slightly less than those of controls throughout the study, and were 10% less at the end of the study. In 625 mg/L females, mean body weights were slightly less than those of controls for most of the study, and 9% less for a 16-week period towards the end of the study. Decreased water consumption was evident in 625 mg/L males and females compared to that in the controls throughout the 2-year study (Table 8, Table J-1, and Table J-2). Drinking water concentrations of 156.25, 312.5, and 625 mg/L resulted in average daily doses of approximately 6, 12, and 22 mg β-picoline/kg body weight to male rats and 7, 14, and 26 mg/kg to female rats. No clinical findings related to β-picoline exposure were observed.

Table 6 Mean Body Weights and Survival of Male Rats in the Two-year Drinking Water Study of β-Picoline

Day | 0 mg/L | | 156.25 mg/L | | | 312.5 mg/L | | | 625 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 116 | 50 | 115 | 99 | 50 | 116 | 101 | 50 | 115 | 99 | 50
8 | 150 | 50 | 147 | 98 | 50 | 148 | 99 | 50 | 142 | 95 | 50
15 | 181 | 50 | 179 | 99 | 50 | 181 | 100 | 50 | 171 | 94 | 50
22 | 212 | 49 | 208 | 98 | 50 | 208 | 98 | 50 | 195 | 92 | 50
29 | 232 | 49 | 229 | 99 | 50 | 230 | 99 | 50 | 215 | 93 | 50
36 | 248 | 49 | 248 | 100 | 50 | 248 | 100 | 50 | 234 | 94 | 50
43 | 262 | 49 | 263 | 100 | 50 | 263 | 100 | 50 | 247 | 94 | 50
50 | 277 | 49 | 276 | 100 | 50 | 278 | 100 | 50 | 259 | 94 | 50
57 | 289 | 49 | 289 | 100 | 50 | 290 | 100 | 50 | 271 | 94 | 50
64 | 301 | 49 | 301 | 100 | 50 | 302 | 100 | 50 | 281 | 93 | 50
71 | 311 | 49 | 311 | 100 | 50 | 313 | 101 | 50 | 289 | 93 | 50
78 | 322 | 49 | 321 | 100 | 50 | 323 | 100 | 50 | 298 | 93 | 50
85 | 330 | 49 | 329 | 100 | 50 | 330 | 100 | 50 | 305 | 93 | 50
113 | 357 | 49 | 354 | 99 | 50 | 357 | 100 | 50 | 332 | 93 | 50
141 | 378 | 49 | 376 | 100 | 50 | 383 | 102 | 50 | 352 | 93 | 50
169 | 400 | 49 | 399 | 100 | 50 | 402 | 101 | 50 | 374 | 93 | 50
197 | 409 | 49 | 409 | 100 | 50 | 416 | 102 | 50 | 387 | 95 | 50
225 | 423 | 49 | 420 | 99 | 50 | 429 | 102 | 50 | 400 | 95 | 50
253 | 434 | 49 | 435 | 100 | 50 | 441 | 102 | 50 | 410 | 95 | 50
281 | 442 | 48 | 441 | 100 | 50 | 453 | 103 | 50 | 422 | 96 | 50
309 | 453 | 48 | 453 | 100 | 50 | 462 | 102 | 50 | 431 | 95 | 50
337 | 458 | 48 | 460 | 100 | 50 | 467 | 102 | 50 | 436 | 95 | 50
365 | 468 | 48 | 467 | 100 | 50 | 477 | 102 | 50 | 445 | 95 | 50
393 | 478 | 47 | 478 | 100 | 50 | 488 | 102 | 49 | 452 | 95 | 50
421 | 481 | 47 | 480 | 100 | 50 | 487 | 101 | 49 | 453 | 94 | 50
449 | 486 | 47 | 487 | 100 | 50 | 493 | 101 | 49 | 457 | 94 | 50
477 | 493 | 46 | 490 | 99 | 50 | 499 | 101 | 49 | 463 | 94 | 50
505 | 501 | 44 | 499 | 100 | 49 | 506 | 101 | 49 | 471 | 94 | 49
533 | 504 | 44 | 506 | 100 | 49 | 510 | 101 | 49 | 472 | 94 | 49
561 | 508 | 44 | 508 | 100 | 48 | 511 | 101 | 49 | 475 | 93 | 45
589 | 512 | 44 | 517 | 101 | 46 | 514 | 100 | 47 | 474 | 92 | 43
617 | 516 | 42 | 516 | 100 | 46 | 516 | 100 | 46 | 474 | 92 | 42
645 | 512 | 42 | 509 | 100 | 44 | 504 | 99 | 44 | 470 | 92 | 38
673 | 507 | 39 | 512 | 101 | 40 | 508 | 100 | 39 | 465 | 92 | 34
701 | 503 | 34 | 497 | 99 | 35 | 510 | 101 | 35 | 453 | 90 | 29
Mean for Weeks
1–13 | 249 | – | 247 | 99 | – | 248 | 100 | – | 232 | 94 | –
14–52 | 417 | – | 416 | 100 | – | 423 | 101 | – | 394 | 94 | –
53–101 | 498 | – | 497 | 100 | – | 502 | 101 | – | 463 | 93 | –

Table 7 Mean Body Weights and Survival of Female Rats in the Two-year Drinking Water Study of β-Picoline

Day | 0 mg/L | | 156.25 mg/L | | | 312.5 mg/L | | | 625 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 99 | 50 | 99 | 100 | 50 | 100 | 101 | 50 | 100 | 101 | 50
8 | 117 | 50 | 116 | 99 | 50 | 116 | 99 | 50 | 114 | 97 | 50
15 | 132 | 50 | 132 | 100 | 50 | 131 | 99 | 50 | 124 | 94 | 50
22 | 144 | 50 | 144 | 101 | 50 | 144 | 100 | 50 | 137 | 95 | 50
29 | 152 | 50 | 153 | 101 | 50 | 154 | 101 | 50 | 145 | 95 | 50
36 | 162 | 50 | 165 | 102 | 50 | 165 | 101 | 50 | 157 | 97 | 50
43 | 170 | 50 | 172 | 101 | 50 | 171 | 101 | 50 | 163 | 96 | 50
50 | 175 | 50 | 176 | 101 | 50 | 175 | 100 | 50 | 168 | 96 | 50
57 | 180 | 50 | 181 | 101 | 50 | 181 | 101 | 50 | 172 | 96 | 50
64 | 184 | 50 | 186 | 101 | 50 | 185 | 100 | 50 | 175 | 95 | 50
71 | 188 | 50 | 191 | 101 | 50 | 188 | 100 | 50 | 180 | 96 | 50
78 | 192 | 50 | 193 | 101 | 50 | 192 | 100 | 50 | 183 | 95 | 50
85 | 195 | 50 | 196 | 101 | 50 | 194 | 100 | 50 | 185 | 95 | 50
113 | 207 | 50 | 208 | 101 | 50 | 208 | 100 | 50 | 197 | 95 | 50
141 | 218 | 50 | 218 | 100 | 50 | 216 | 99 | 50 | 203 | 93 | 50
169 | 223 | 50 | 226 | 101 | 50 | 225 | 101 | 50 | 213 | 96 | 50
197 | 233 | 50 | 233 | 100 | 50 | 228 | 98 | 50 | 220 | 95 | 50
225 | 238 | 50 | 241 | 101 | 50 | 238 | 100 | 50 | 229 | 96 | 50
253 | 247 | 50 | 248 | 100 | 50 | 245 | 99 | 50 | 235 | 95 | 50
281 | 253 | 50 | 256 | 101 | 50 | 251 | 99 | 50 | 242 | 96 | 50
309 | 264 | 50 | 265 | 100 | 50 | 261 | 99 | 50 | 251 | 95 | 50
337 | 270 | 50 | 271 | 100 | 50 | 265 | 98 | 50 | 256 | 95 | 50
365 | 282 | 50 | 281 | 100 | 50 | 275 | 98 | 50 | 265 | 94 | 50
393 | 294 | 50 | 293 | 100 | 50 | 285 | 97 | 50 | 274 | 93 | 50
421 | 302 | 50 | 299 | 99 | 50 | 289 | 96 | 50 | 278 | 92 | 50
449 | 311 | 50 | 309 | 100 | 50 | 299 | 96 | 50 | 286 | 92 | 50
477 | 319 | 49 | 319 | 100 | 49 | 307 | 96 | 50 | 294 | 92 | 49
505 | 328 | 48 | 329 | 100 | 48 | 319 | 97 | 50 | 305 | 93 | 49
533 | 340 | 45 | 336 | 99 | 45 | 326 | 96 | 48 | 311 | 91 | 47
561 | 344 | 45 | 340 | 99 | 45 | 331 | 96 | 48 | 313 | 91 | 45
589 | 348 | 44 | 346 | 100 | 44 | 336 | 97 | 46 | 316 | 91 | 43
617 | 352 | 43 | 353 | 100 | 41 | 344 | 98 | 45 | 322 | 91 | 41
645 | 353 | 40 | 352 | 100 | 38 | 348 | 99 | 44 | 322 | 91 | 39
673 | 350 | 40 | 355 | 102 | 37 | 348 | 100 | 41 | 326 | 93 | 37
701 | 346 | 34 | 349 | 101 | 37 | 351 | 101 | 34 | 323 | 93 | 32
Mean for Weeks
1–13 | 161 | – | 162 | 101 | – | 161 | 100 | – | 154 | 96 | –
14–52 | 239 | – | 241 | 101 | – | 237 | 99 | – | 227 | 95 | –
53–101 | 328 | – | 328 | 100 | – | 320 | 97 | – | 303 | 92 | –

Figure 4

Growth Curves for Rats Exposed to β-Picoline in Drinking Water for Two Years

Table 8 Water and Compound Consumption by Rats in the Two-year Drinking Water Study of β-Picoline

Mean for Weeks | 0 mg/L | | 156.25 mg/L | | | 312.5 mg/L | | | 625 mg/L
Mean for Weeks | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1–13 | 15.9 | 249 | 15.9 | 247 | 11 | 15.4 | 248 | 22 | 13.0 | 232 | 38
14–52 | 15.5 | 417 | 15.2 | 416 | 6 | 15.1 | 423 | 11 | 13.1 | 394 | 21
53–101 | 16.9 | 498 | 16.3 | 497 | 5 | 15.3 | 501 | 10 | 13.6 | 463 | 18
Female
1–13 | 11.0 | 161 | 11.0 | 162 | 11 | 10.2 | 161 | 21 | 8.9 | 154 | 38
14–52 | 10.6 | 239 | 10.3 | 241 | 7 | 9.8 | 237 | 13 | 8.9 | 227 | 25
53–101 | 13.3 | 328 | 13.0 | 328 | 6 | 12.1 | 319 | 12 | 11.4 | 303 | 23

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the lung and oral cavity. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Lung: The incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in exposed groups of males were similar to that in the controls (Table 9, Table A-1, and Table A-2). In males, alveolar/bronchiolar carcinoma occurred in the 312.5 and 625 mg/L groups; four incidences occurred in 312.5 mg/L males and two incidences occurred in 625 mg/L males. The increased incidence of alveolar/bronchiolar carcinoma in 312.5 mg/L males was not significant compared to the controls (0/50), but this neoplasm has not occurred in the historical controls for drinking water studies and the 8% incidence slightly exceeded the historical control range for all routes of administration (Table 9 and Table A-3). In females, alveolar/bronchiolar adenoma occurred in all exposed groups, but not in the controls (Table 9, Table B-1, and Table B-2). A single incidence of alveolar/bronchiolar carcinoma occurred in a 156.25 mg/L female. Incidences of alveolar/bronchiolar adenoma in the 625 mg/L females were significantly greater than those in the controls and slightly exceeded the historical control ranges for drinking water studies and all routes of administration (Table 9 and Table B-3). The incidences of alveolar epithelium hyperplasia and squamous metaplasia were increased, but not significantly, in all exposed groups of females compared to those in the controls (Table 9 and Table B-4).

Table 9 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Rats in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar/bronchiolar Adenoma^a,b^ | 3 | 5 | 1 | 2
Alveolar/bronchiolar Carcinoma (includes multiple)^c^
Overall rate^d^ | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate^e^ | 0.0% | 0.0% | 8.8% | 4.7%
Terminal rate^f^ | 0/33 (0%) | 0/31 (0%) | 3/32 (9%) | 1/24 (4%)
First incidence (days) | –^h^ | – | 615 | 607
Poly-3 test^g^ | P = 0.095 | –^i^ | P = 0.069 | P = 0.238
Alveolar/bronchiolar Adenoma or Carcinoma^j^
Overall rate | 3/50 (6%) | 5/50 (10%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 7.0% | 11.0% | 11.0% | 9.3%
Terminal rate | 2/33 (6%) | 5/31 (16%) | 4/32 (13%) | 2/24 (8%)
First incidence (days) | 600 | 726 (T) | 615 | 607
Poly-3 test | P = 0.478 | P = 0.387 | P = 0.389 | P = 0.501
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia | 7 (1.3)^k^ | 14 (1.5) | 14 (2.1) | 11 (1.2)
Alveolar Epithelium, Metaplasia, Squamous | 0 | 3 (1.3) | 1 (2.0) | 1 (1.0)
Alveolar/bronchiolar Adenoma^l^
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 0.0% | 6.7% | 4.4% | 11.5%
Terminal rate | 0/30 (0%) | 1/32 (3%) | 2/33 (6%) | 4/30 (13%)
First incidence (days) | – | 526 | 727 (T) | 638
Poly-3 test | P = 0.029 | P = 0.122 | P = 0.245 | P = 0.030
Alveolar/bronchiolar Carcinoma^m^ | 0 | 1 | 0 | 0
Alveolar/bronchiolar Adenoma or Carcinoma^n^
Overall rate | 0/50 (0%) | 4/50 (8%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 0.0% | 9.0% | 4.4% | 11.5%
Terminal rate | 0/30 (0%) | 2/32 (6%) | 2/33 (6%) | 4/30 (13%)
First incidence (days) | – | 526 | 727 (T) | 638
Poly-3 test | P = 0.050 | P = 0.063 | P = 0.245 | P = 0.030

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Historical incidence for 2-year drinking water studies with untreated control groups (mean ± standard deviation): 7/100 (7.0% ± 1.4%), range 6%–8%; all routes: 31/1,249 (2.5% ± 2.6%), range 0%–8%.

^c^ Historical incidence for drinking water studies: 0/100; all routes: 15/1,249 (1.2% ± 1.4%), range 0%–6%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

^j^ Historical incidence for drinking water studies: 7/100 (7.0% ± 1.4%), range 6%–8%; all routes: 45/1,249 (3.6% ± 2.8%), range 0%–10%.

^k^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^l^ Historical incidence for drinking water studies: 4/100 (4.0% ± 5.7%), range 0%–8%; all routes: 25/1,200 (2.1% ± 2.9%), range 0%–8%.

^m^ Historical incidence for drinking water studies: 0/100; all routes: 3/1,200 (0.3% ± 0.7%), range 0%–2%.

^n^ Historical incidence for drinking water studies: 4/100 (4.0% ± 5.7%), range 0%–8%; all routes: 27/1,200 (2.3% ± 2.9%), range 0%–8%.

Alveolar bronchiolar adenomas were discrete, moderately cellular masses that distorted and replaced alveolar architecture and obliterated alveolar spaces. The proliferative cells generally formed irregular papillary structures supported by delicate, fibrovascular stroma. The cells were polygonal, moderately uniform in size, and had small to moderate amounts of eosinophilic cytoplasm. Nuclei were round to oval, moderately uniform, and mitoses were few. Carcinomas were generally not well circumscribed and contained stratification of the neoplastic epithelium, solid areas of growth, cellular pleomorphism and atypia, or anaplastic cells associated with a scirrhous reaction. Alveolar epithelium hyperplasia consisted of focal areas of increased numbers of Type II pneumocytes lining alveolar walls in the absence of cellular atypia with maintenance of alveolar architecture. Alveolar epithelium metaplasia consisted of a change from the normal cubiodal epithelium lining the alveoli to a flattened, squamous epithelium.

Oral Cavity: An expanded review of the oral cavity for all proliferative lesions was performed because squamous cell neoplasms were observed grossly during necropsy. One squamous cell carcinoma of the tongue each occurred in 312.5 and 625 mg/L males (0 mg/L, 0/50; 156.25 mg/L, 0/50; 312.5 mg/L, 1/50; 625 mg/L, 1/50); none occurred in females (Table A-1 and Table B-1). Incidences of squamous cell papilloma or carcinoma (combined) in the oral mucosa or tongue (combined) were increased in 312.5 and 625 mg/L males and females (males: 1/50, 1/50, 2/50, 2/50; females: 0/50, 0/50, 1/50, 2/50). Due to the low incidences, these lesions were not considered to be related to treatment.

## Mice

### Three-month Study

All mice survived to the end of the study (Table 10). Final mean body weights and body weight gains of exposed groups of male and female mice were generally similar to those of the control groups (Table 10 and Figure 5). Water consumption by the exposed and control groups was generally similar; water consumption by 1,250 mg/L males was initially less than that by the controls due to palatability. Drinking water concentrations of 78, 156, 312, 625, and 1,250 mg/L resulted in average daily doses of approximately 10, 20, 37, 77, and 148 mg β-picoline/kg body weight to males and 9, 18, 38, 72, and 134 mg/kg to females. There were no clinical findings related to β-picoline exposure.

Table 10 Survival, Body Weights, and Water Consumption of Mice in the Three-month Drinking Water Study of β-Picoline^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 13
Male
0 | 10/10 | 21.8 ± 0.4 | 38.5 ± 1.3 | 16.7 ± 1.0 | | 3.7 | 3.3
78 | 10/10 | 22.1 ± 0.7 | 39.5 ± 0.8 | 17.4 ± 1.1 | 103 | 3.6 | 3.2
156 | 10/10 | 22.3 ± 0.5 | 39.9 ± 1.2 | 17.6 ± 0.9 | 104 | 3.7 | 3.7
312 | 10/10 | 21.8 ± 0.5 | 39.9 ± 1.3 | 18.1 ±1.1 | 104 | 3.6 | 3.3
625 | 10/10 | 21.8 ± 0.5 | 39.6 ± 1.1 | 17.8 ± 1.0 | 103 | 3.6 | 3.3
1,250 | 10/10 | 22.2 ± 0.5 | 37.9 ± 1.0 | 15.7 ± 0.8 | 98 | 3.4 | 3.1
Female
0 | 10/10 | 18.3 ± 0.6 | 27.2 ± 0.9 | 8.8 ± 0.9 | | 2.1 | 2.6
78 | 10/10 | 17.9 ± 0.4 | 27.6 ± 1.0 | 9.7 ± 0.7 | 102 | 2.3 | 2.8
156 | 10/10 | 18.6 ± 0.5 | 30.1 ± 1.0 | 11.5 ± 0.8 | 111 | 2.3 | 2.6
312 | 10/10 | 18.2 ± 0.5 | 28.0 ± 1.1 | 9.7 ± 0.8 | 103 | 2.3 | 2.8
625 | 10/10 | 18.1 ± 0.5 | 27.6 ± 0.5 | 9.5 ± 0.6 | 102 | 2.3 | 2.7
1,250 | 10/10 | 18.2 ± 0.6 | 27.9 ± 0.9 | 9.7 ± 0.7 | 103 | 2.1 | 2.6

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 5

Growth Curves for Mice Exposed to β-Picoline in Drinking Water for Three Months

There were no changes in the hematology data that were considered attributable to β-picoline administration (Table F-2).

Absolute and relative lung weights of 1,250 mg/L females were significantly less than those of the controls (Table G-2).

There were no significant differences in sperm parameters of male mice or in the estrous cycles of female mice exposed to 312, 625, or 1,250 mg/L when compared to the controls (Table H-4 and Table H-5).

No gross or microscopic lesions were observed that were considered to be due to β-picoline exposure.

Exposure Concentration Selection Rationale: Based on the absence of exposure-related effects in the 3-month study in mice, β-picoline exposure concentrations selected for the 2-year drinking water study in mice were 312.5, 625, and 1,250 mg/L.

### Two-year Study

#### Survival

Estimates of the 2-year survival probabilities for male and female mice are shown in Table 11 and in the Kaplan-Meier survival curves (Figure 6). Survival of all exposed groups was similar to that of the control groups; however, there was a positive trend in the survival of male mice.

Table 11 Survival of Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 6 | 4 | 8 | 7
Natural deaths | 20 | 20 | 15 | 10
Animals surviving to study termination | 24 | 26 | 27 | 33
Percent probability of survival at end of study^a^ | 48 | 52 | 54 | 66
Mean survival (days)^b^ | 645 | 674 | 671 | 688
Survival analysis^c^ | P = 0.041N | P = 0.503N | P = 0.456N | P = 0.058N
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 4 | 3 | 1 | 4
Natural deaths | 8 | 15 | 14 | 13
Animals surviving to study termination | 38 | 32 | 35^d^ | 33
Percent probability of survival at end of study | 76 | 64 | 70 | 66
Mean survival (days) | 702 | 694 | 700 | 694
Survival analysis | P = 0.446 | P = 0.294 | P = 0.656 | P = 0.325

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^27^ is in the control column, and the results of the life table pairwise comparisons^26^ with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^d^ Includes one animal that died during the last week of the study.

Figure 6

Kaplan-Meier Survival Curves for Mice Exposed to β-Picoline in Drinking Water for Two Years

### Body Weights, Water and Compound Consumption, and Clinical Findings

Mean body weights of 1,250 mg/L males were at least 10% less than those of the control group after week 57, and those of 1,250 mg/L females were generally 10% less after week 13 (Table 12 and Table 13 and Figure 7). Water consumption was lower in 625 and 1,250 mg/L males and 1,250 mg/L females compared to that in the controls after the first 13 weeks of the study (Table 14, Table J-3, and Table J-4). Drinking water concentrations of 312.5, 625, and 1,250 mg/L resulted in average daily doses of approximately 26, 50, and 92 mg β-picoline/kg body weight to males and 18, 37, and 68 mg/kg to females. No chemical-related clinical findings were observed.

Table 12 Mean Body Weights and Survival of Male Mice in the Two-year Drinking Water Study of β-Picoline

Day | 0 mg/L | | 312.5 mg/L | | | 625 mg/L | | | 1,250 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 23.7 | 50 | 23.8 | 100 | 50 | 23.6 | 99 | 50 | 23.7 | 100 | 50
8 | 25.8 | 50 | 25.5 | 99 | 50 | 25.2 | 98 | 50 | 25.2 | 98 | 50
15 | 27.2 | 50 | 27.0 | 99 | 50 | 26.5 | 98 | 50 | 26.6 | 98 | 50
22 | 28.8 | 50 | 28.7 | 100 | 50 | 28.1 | 98 | 50 | 28.1 | 98 | 50
29 | 30.9 | 50 | 30.5 | 99 | 50 | 29.8 | 96 | 50 | 29.9 | 97 | 50
36 | 33.0 | 50 | 32.5 | 98 | 50 | 31.6 | 96 | 50 | 31.5 | 95 | 50
43 | 35.0 | 50 | 34.5 | 99 | 50 | 33.3 | 95 | 50 | 33.3 | 95 | 50
50 | 36.6 | 50 | 35.9 | 98 | 50 | 34.8 | 95 | 50 | 34.7 | 95 | 50
57 | 38.1 | 50 | 37.5 | 99 | 50 | 36.2 | 95 | 50 | 36.2 | 95 | 50
64 | 39.7 | 50 | 39.0 | 98 | 50 | 37.7 | 95 | 50 | 37.7 | 95 | 50
71 | 41.2 | 50 | 40.7 | 99 | 50 | 39.3 | 95 | 50 | 39.3 | 95 | 50
78 | 42.9 | 50 | 42.2 | 98 | 50 | 40.8 | 95 | 50 | 40.8 | 95 | 50
85 | 44.1 | 50 | 43.2 | 98 | 50 | 41.8 | 95 | 50 | 41.8 | 95 | 50
113 | 48.0 | 50 | 46.8 | 98 | 50 | 45.4 | 95 | 50 | 45.3 | 94 | 50
141 | 49.5 | 50 | 48.5 | 98 | 50 | 47.2 | 95 | 50 | 46.5 | 94 | 50
169 | 50.2 | 50 | 49.1 | 98 | 50 | 47.9 | 95 | 50 | 47.1 | 94 | 50
197 | 51.9 | 50 | 50.8 | 98 | 50 | 49.6 | 96 | 50 | 48.5 | 94 | 50
225 | 52.9 | 50 | 52.0 | 98 | 50 | 50.5 | 95 | 50 | 49.1 | 93 | 50
253 | 54.0 | 50 | 52.9 | 98 | 50 | 51.3 | 95 | 50 | 49.7 | 92 | 50
281 | 55.1 | 50 | 54.0 | 98 | 50 | 52.2 | 95 | 50 | 50.3 | 91 | 50
309 | 55.9 | 50 | 55.3 | 99 | 50 | 53.2 | 95 | 50 | 51.0 | 91 | 50
337 | 56.7 | 50 | 55.7 | 98 | 50 | 53.2 | 94 | 50 | 51.5 | 91 | 50
365 | 56.7 | 50 | 55.9 | 99 | 50 | 54.1 | 95 | 50 | 52.1 | 92 | 50
393 | 57.1 | 50 | 56.5 | 99 | 50 | 53.9 | 94 | 50 | 51.9 | 91 | 50
421 | 57.0 | 49 | 56.0 | 98 | 49 | 53.4 | 94 | 50 | 51.1 | 90 | 49
449 | 56.3 | 48 | 55.6 | 99 | 49 | 52.9 | 94 | 50 | 50.8 | 90 | 48
477 | 56.3 | 45 | 55.6 | 99 | 48 | 53.1 | 94 | 48 | 49.9 | 89 | 47
505 | 56.3 | 44 | 55.0 | 98 | 48 | 52.9 | 94 | 47 | 48.8 | 87 | 47
533 | 55.4 | 41 | 54.1 | 98 | 47 | 52.5 | 95 | 44 | 47.2 | 85 | 46
561 | 54.3 | 39 | 52.5 | 97 | 46 | 51.4 | 95 | 40 | 46.1 | 85 | 43
589 | 53.2 | 36 | 51.4 | 97 | 43 | 50.3 | 95 | 39 | 44.9 | 84 | 42
617 | 50.3 | 32 | 51.5 | 102 | 39 | 49.0 | 98 | 39 | 42.7 | 85 | 42
645 | 48.5 | 29 | 51.1 | 105 | 32 | 46.5 | 96 | 36 | 40.6 | 84 | 42
673 | 46.8 | 26 | 48.6 | 104 | 32 | 45.0 | 96 | 33 | 37.9 | 81 | 42
701 | 43.0 | 25 | 47.7 | 111 | 30 | 42.7 | 99 | 30 | 36.8 | 86 | 39
Mean for Weeks
1–13 | 34.4 | – | 33.9 | 99 | – | 33.0 | 96 | – | 33.0 | 96 | –
14–52 | 52.7 | – | 51.7 | 98 | – | 50.1 | 95 | – | 48.8 | 93 | –
53–101 | 53.2 | – | 53.2 | 100 | – | 50.6 | 95 | – | 46.2 | 87 | –

Table 13 Mean Body Weights and Survival of Female Mice in the Two-year Drinking Water Study of β-Picoline

Day | 0 mg/L | | 312.5 mg/L | | | 625 mg/L | | | 1,250 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.6 | 50 | 18.8 | 101 | 50 | 18.7 | 101 | 50 | 18.5 | 100 | 50
8 | 19.7 | 50 | 19.7 | 100 | 50 | 19.2 | 98 | 50 | 19.1 | 97 | 50
15 | 20.7 | 50 | 20.6 | 99 | 50 | 20.2 | 97 | 50 | 20.0 | 97 | 50
22 | 21.4 | 50 | 21.7 | 101 | 50 | 21.3 | 100 | 50 | 20.8 | 97 | 50
29 | 22.3 | 50 | 22.7 | 102 | 50 | 22.1 | 99 | 50 | 21.5 | 96 | 50
36 | 23.4 | 50 | 23.4 | 100 | 50 | 22.7 | 97 | 50 | 22.4 | 96 | 50
43 | 24.5 | 50 | 24.6 | 101 | 50 | 23.7 | 97 | 50 | 23.3 | 95 | 50
50 | 25.1 | 50 | 25.0 | 100 | 50 | 24.4 | 98 | 50 | 23.6 | 94 | 50
57 | 26.6 | 50 | 26.6 | 100 | 50 | 25.5 | 96 | 50 | 24.8 | 93 | 50
64 | 27.5 | 50 | 27.7 | 101 | 50 | 27.1 | 99 | 50 | 25.8 | 94 | 50
71 | 29.3 | 50 | 29.3 | 100 | 50 | 28.5 | 97 | 50 | 26.5 | 90 | 50
78 | 30.5 | 50 | 30.6 | 100 | 50 | 30.1 | 99 | 50 | 27.9 | 92 | 50
85 | 31.8 | 50 | 32.1 | 101 | 50 | 31.1 | 98 | 50 | 28.9 | 91 | 50
113 | 37.6 | 50 | 37.5 | 100 | 50 | 36.5 | 97 | 50 | 33.7 | 90 | 50
141 | 43.3 | 50 | 42.9 | 99 | 50 | 41.2 | 95 | 50 | 38.8 | 90 | 50
169 | 47.3 | 50 | 47.2 | 100 | 50 | 45.0 | 95 | 50 | 42.3 | 89 | 50
197 | 50.4 | 50 | 50.2 | 100 | 50 | 47.8 | 95 | 50 | 45.3 | 90 | 50
225 | 53.3 | 50 | 53.3 | 100 | 50 | 51.0 | 96 | 50 | 48.2 | 90 | 50
253 | 55.2 | 50 | 55.6 | 101 | 50 | 52.9 | 96 | 50 | 50.3 | 91 | 50
281 | 57.5 | 50 | 57.3 | 100 | 50 | 54.8 | 95 | 50 | 51.9 | 90 | 50
309 | 58.6 | 50 | 58.4 | 100 | 50 | 56.0 | 96 | 49 | 53.0 | 90 | 50
337 | 59.7 | 50 | 59.5 | 100 | 50 | 57.1 | 96 | 49 | 54.7 | 92 | 50
365 | 61.5 | 49 | 60.5 | 98 | 50 | 58.5 | 95 | 49 | 55.5 | 90 | 50
393 | 62.8 | 48 | 62.6 | 100 | 49 | 60.2 | 96 | 49 | 56.8 | 90 | 50
421 | 63.8 | 48 | 63.6 | 100 | 49 | 61.3 | 96 | 49 | 57.5 | 90 | 50
449 | 65.0 | 48 | 64.8 | 100 | 49 | 62.2 | 96 | 49 | 58.1 | 89 | 50
477 | 65.6 | 48 | 65.4 | 100 | 49 | 62.5 | 95 | 49 | 59.0 | 90 | 50
505 | 67.3 | 48 | 66.1 | 98 | 48 | 63.4 | 94 | 49 | 59.3 | 88 | 49
533 | 67.4 | 48 | 65.5 | 97 | 46 | 63.1 | 94 | 48 | 60.6 | 90 | 47
561 | 66.2 | 48 | 65.1 | 98 | 45 | 64.1 | 97 | 47 | 60.0 | 91 | 47
589 | 65.3 | 48 | 65.2 | 100 | 44 | 64.0 | 98 | 47 | 60.3 | 92 | 44
617 | 64.9 | 47 | 64.8 | 100 | 44 | 63.7 | 98 | 46 | 58.6 | 90 | 43
645 | 63.9 | 45 | 63.6 | 100 | 43 | 62.5 | 98 | 44 | 56.5 | 89 | 41
673 | 61.2 | 43 | 61.0 | 100 | 41 | 60.2 | 98 | 41 | 56.5 | 92 | 37
701 | 60.6 | 39 | 57.4 | 95 | 37 | 57.5 | 95 | 40 | 53.3 | 88 | 36
Mean for Weeks
1–13 | 24.7 | – | 24.8 | 100 | – | 24.2 | 98 | – | 23.3 | 95 | –
14–52 | 51.4 | – | 51.3 | 100 | – | 49.1 | 96 | – | 46.5 | 90 | –
53–101 | 64.3 | – | 63.5 | 99 | – | 61.8 | 96 | – | 57.8 | 90 | –

Figure 7

Growth Curves for Mice Exposed to β-Picoline in Drinking Water for Two Years

Table 14 Water and Compound Consumption by Mice in the Two-year Drinking Water Study of β-Picoline

Mean for Weeks | 0 mg/L | | 312.5 mg/L | | | 625 mg/L | | | 1,250 mg/L
Mean for Weeks | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1–13 | 3.7 | 34.4 | 3.6 | 33.9 | 34 | 3.5 | 33.0 | 69 | 3.4 | 33.0 | 132
14–52 | 4.1 | 52.7 | 3.7 | 51.7 | 23 | 3.5 | 50.1 | 43 | 3.2 | 48.8 | 81
53–101 | 4.7 | 53.2 | 4.5 | 53.2 | 26 | 4.0 | 50.6 | 50 | 3.3 | 46.2 | 90
Female
1–13 | 2.8 | 24.7 | 2.6 | 24.8 | 34 | 2.5 | 24.2 | 66 | 2.3 | 23.3 | 123
14–52 | 2.5 | 51.4 | 2.5 | 51.3 | 15 | 2.4 | 49.1 | 31 | 2.2 | 46.5 | 60
53–101 | 3.3 | 64.3 | 3.4 | 63.4 | 17 | 3.3 | 61.8 | 34 | 2.8 | 57.8 | 60

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver, lung, and nose. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: Compared to controls, the incidences of hepatocellular adenoma were significantly increased in 312.5 and 625 mg/L females, with a significant increase in multiple hepatocellular adenomas in 312.5 mg/L females (Table 15, Table D-1, and Table D-2). The incidences of hepatocellular carcinoma were significantly increased in all exposed groups of females compared to that in the controls. The incidences of hepatocellular carcinoma in all exposed groups of females exceeded the historical control range for drinking water studies and the incidence in 625 mg/L females exceeded the historical control range for all routes of administration. The incidences of hepatoblastoma in all exposed groups of females were greater than that in the controls; although not significantly increased, these incidences exceeded the historical control ranges for drinking water studies and for all routes of administration. A single incidence of multiple hepatoblastoma occurred in each of the 625 and 1,250 mg/L groups of females. The combined incidences of hepatocellular carcinoma and hepatoblastoma were significantly increased in all exposed groups of females and exceeded the historical control ranges for drinking water studies and for all routes of administration in the 625 and 1,250 mg/L groups. There were no treatment-related effects on the incidences of liver neoplasms in male mice.

Table 15 Incidences of Neoplasms of the Liver in Female Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Number Examined Microscopically | 49 | 50 | 50 | 50
Hepatocellular Adenoma, Multiple^a^ | 27 | 43** | 36 | 30
Hepatocellular Adenoma (includes multiple)^b^
Overall rate^c^ | 38/49 (78%) | 46/50 (92%) | 46/50 (92%) | 39/50 (78%)
Adjusted rate^d^ | 80.4% | 94.9% | 93.1% | 81.5%
Terminal rate^e^ | 31/38 (82%) | 31/32 (97%) | 35/35 (100%) | 26/33 (79%)
First incidence (days) | 598 | 494 | 309 | 509
Poly-3 test^f^ | P = 0.403N | P = 0.025 | P = 0.052 | P = 0.551
Hepatocellular Carcinoma, Multiple | 5 | 7 | 10 | 5
Hepatocellular Carcinoma (includes multiple)^g^
Overall rate | 11/49 (22%) | 20/50 (40%) | 26/50 (52%) | 23/50 (46%)
Adjusted rate | 23.6% | 43.9% | 55.3% | 50.9%
Terminal rate | 7/38 (18%) | 14/32 (44%) | 21/35 (60%) | 18/33 (55%)
First incidence (days) | 639 | 533 | 549 | 586
Poly-3 test | P = 0.006 | P = 0.031 | P < 0.001 | P = 0.005
Hepatoblastoma, Multiple | 0 | 0 | 1 | 1
Hepatoblastoma (includes multiple)^h^
Overall rate | 1/49 (2%) | 3/50 (6%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 2.2% | 6.7% | 8.8% | 9.1%
Terminal rate | 0/38 (0%) | 1/32 (3%) | 4/35 (11%) | 3/33 (9%)
First incidence (days) | 674 | 662 | 729 (T) | 721
Poly-3 test | P = 0.140 | P = 0.295 | P = 0.174 | P = 0.166
Hepatocellular Carcinoma or Hepatoblastoma^i^
Overall rate | 12/49 (24%) | 21/50 (42%) | 28/50 (56%) | 24/50 (48%)
Adjusted rate | 25.7% | 45.8% | 59.5% | 53.1%
Terminal rate | 7/38 (18%) | 14/32 (44%) | 23/35 (66%) | 19/33 (58%)
First incidence (days) | 639 | 533 | 549 | 586
Poly-3 test | P = 0.005 | P = 0.033 | P < 0.001 | P = 0.005

** Significantly different (P ≤ 0.01) from the control group by the Poly-3 test.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Historical incidence for 2-year drinking water studies with untreated control groups (mean ± standard deviation: 52/98 (53.1% ± 34.6%), range 29%–78%; all routes: 380/1,195 (31.8% ± 21.4%), range 2%–78%.

^c^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend in an exposure group is indicated by N.

^g^ Historical incidence for drinking water studies: 19/98 (19.4% ± 4.3%), range 16%–22%; all routes: 144/1,195 (12.1% ± 10.8%), range 0%–46%.

^h^ Historical incidence for drinking water studies: 1/98 (1.0% ± 1.4%), range 0%–2%; all routes: 4/1,195 (0.3% ± 0.8%), range 0%–2%.

^i^ Historical incidence for drinking water studies: 20/98 (20.4% ± 5.8%), range 16%–24%; all routes: 148/1,195 (12.4% ± 11.2%), range 0%–46%.

The hepatocellular adenomas were typically well-demarcated nodular masses that caused compression of the surrounding parenchyma on all sides and lacked normal architecture. They were composed of variably pleomorphic hepatocytes arranged in irregular cords that intersected at sharp angles with the cords of the surrounding parenchyma. The majority of the hepatocellular carcinomas were composed of pleomorphic hepatocytes arranged in a trabecular pattern, with trabeculae that were three or more cells thick. Many contained large blood-filled spaces and areas of necrosis. Solid and glandular patterns were also noted. Hepatoblastomas were often located within or adjacent to hepatocellular carcinomas or adenomas. In such cases, only a diagnosis of hepatoblastoma was recorded. Hepatoblastoma was diagnosed when all or a portion of a mass was composed of a densely cellular proliferation of small cells containing round to oval hyperchromatic nuclei and scant cytoplasm, often arranged in nests and palisading around blood-filled vascular spaces.

Lung: The incidence of alveolar/bronchiolar adenoma was significantly increased in 625 mg/L males compared to that in the controls (Table 16, Table C-1, and Table C-2) and the time to first incidence in this exposed group (470 days) was 260 days shorter than in the controls. In females, there was a positive trend in the incidences of alveolar/bronchiolar adenoma with an incidence in the 1,250 mg/L group that exceeded the historical control ranges for drinking water studies and for all routes of administration (Table 16, Table D-1, and Table D-2). The incidences of alveolar/bronchiolar carcinoma in all exposed groups of females were greater than that in the controls, but these increases were not statistically significant. Multiple alveolar/bronchiolar carcinomas occurred in two 312.5 mg/L, two 625 mg/L, and four 1,250 mg/L females. There was a positive trend in the combined incidences of alveolar/bronchiolar adenoma or carcinoma in females, and the incidence in the 1,250 mg/L group was significantly greater than that in the controls. The combined incidences of alveolar/bronchiolar adenoma or carcinoma were increased without significance in all exposed groups of males, exceeded the historical control ranges for drinking water studies and for all routes combined in 625 mg/L males, and exceeded the historical control range for drinking water studies, but not for all routes combined, in 312.5 mg/L males. The incidence of alveolar epithelium hyperplasia was significantly increased in 1,250 mg/L females and bronchiole hyperplasia was observed in a few 625 and 1,250 mg/L females.

Table 16 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia^a^ | 4 (1.8)^b^ | 6 (1.2) | 6 (2.7) | 7 (1.7)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 0 | 2 | 2
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^d^ | 6/50 (12%) | 11/50 (22%) | 16/50 (32%) | 8/50 (16%)
Adjusted rate^e^ | 16.3% | 25.8% | 36.1% | 18.2%
Terminal rate^f^ | 6/24 (25%) | 5/26 (19%) | 8/27 (30%) | 6/33 (18%)
First incidence (days) | 730 (T) | 627 | 470 | 709
Poly-3 test^g^ | P = 0.504N | P = 0.222 | P = 0.037 | P = 0.526
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 2 | 0 | 3
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 9/50 (18%) | 9/50 (18%) | 8/50 (16%) | 9/50 (18%)
Adjusted rate | 23.2% | 21.2% | 19.4% | 20.6%
Terminal rate | 5/24 (21%) | 5/26 (19%) | 6/27 (22%) | 8/33 (24%)
First incidence (days) | 455 | 512 | 628 | 724
Poly-3 test | P = 0.448N | P = 0.516N | P = 0.443N | P = 0.490N
Alveolar/bronchiolar Adenoma or Carcinoma^i^
Overall rate | 14/50 (28%) | 19/50 (38%) | 21/50 (42%) | 15/50 (30%)
Adjusted rate | 36.2% | 42.8% | 47.0% | 34.2%
Terminal rate | 10/24 (42%) | 9/26 (35%) | 12/27 (44%) | 12/33 (36%)
First incidence (days) | 455 | 512 | 470 | 709
Poly-3 test | P = 0.382N | P = 0.343 | P = 0.213 | P = 0.517N
Female
Number Examined Microscopically | 50 | 50 | 49 | 50
Alveolar Epithelium, Hyperplasia | 2 (1.5) | 4 (2.5) | 3 (1.3) | 8* (1.8)
Bronchiole, Hyperplasia | 0 | 0 | 3 (2.0) | 1 (2.0)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | 0 | 1
Alveolar/bronchiolar Adenoma (includes multiple)^j^
Overall rate | 5/50 (10%) | 6/50 (12%) | 4/49 (8%) | 11/50 (22%)
Adjusted rate | 10.9% | 13.5% | 8.9% | 24.5%
Terminal rate | 5/38 (13%) | 5/32 (16%) | 3/35 (9%) | 8/33 (24%)
First incidence (days) | 729 (T) | 700 | 669 | 533
Poly-3 test | P = 0.046 | P = 0.477 | P = 0.511N | P = 0.075
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 2 | 2 | 4
Alveolar/bronchiolar Carcinoma (includes multiple)^k^
Overall rate | 7/50 (14%) | 8/50 (16%) | 10/49 (20%) | 13/50 (26%)
Adjusted rate | 15.2% | 17.9% | 21.6% | 28.5%
Terminal rate | 6/38 (16%) | 6/32 (19%) | 7/35 (20%) | 8/33 (24%)
First incidence (days) | 669 | 700 | 522 | 509
Poly-3 test | P = 0.061 | P = 0.471 | P = 0.297 | P = 0.096
Alveolar/bronchiolar Adenoma or Carcinoma^l^
Overall rate | 11/50 (22%) | 13/50 (26%) | 13/49 (27%) | 21/50 (42%)
Adjusted rate | 23.8% | 29.1% | 28.1% | 45.4%
Terminal rate | 10/38 (26%) | 11/32 (34%) | 10/35 (29%) | 14/33 (42%)
First incidence (days) | 669 | 700 | 522 | 509
Poly-3 test | P = 0.015 | P = 0.368 | P = 0.407 | P = 0.022

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year drinking water studies with untreated control groups (mean ± standard deviation): 21/100 (21.0% ± 12.7%), range 12%–30%; all routes: 172/1,150 (15.0% ± 6.9%), range 2%–30%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical incidence for drinking water studies: 12/100 (12.0% ± 8.5%), range 6%–18%; all routes: 144/1,150 (12.5% ± 7.1%),range 4%–24%.

^i^ Historical incidence for drinking water studies: 30/100 (30.0% ± 2.8%), range 28%–32%; all routes: 301/1,150 (26.2% ± 6.3%), range 14%–40%.

^j^ Historical incidence for drinking water studies: 6/100 (6.0% ± 5.7%), range 2%–10%; all routes: 60/1,196 (5.0% ± 3.6%), range 0%–12%.

^k^ Historical incidence for drinking water studies: 9/100 (9.0% ± 7.1%), range 4%–14%; all routes: 44/1,196 (3.7% ± 3.3%), range 0%–14%.

^l^ Historical incidence for drinking water studies: 13/100 (13.0% ± 12.7%), range 4%–22%; all routes: 100/1,196 (8.4% ± 4.3%), range 2%–22%.

Alveolar/bronchiolar adenomas consisted of a well-demarcated, densely cellular proliferation of cuboidal to columnar cells supported by a fine fibrovascular stroma and forming short projections into alveolar spaces and causing compression of the surrounding parenchyma. Alveolar/bronchiolar carcinomas tended to be larger and were characterized by irregular, often poorly demarcated proliferations of pleomorphic cuboidal to columnar cells containing pleomorphic nuclei with occasional mitoses. The cells formed irregular papillary structures and/or solid clusters, with most neoplasms containing a combination of the two patterns. Alveolar epithelium and bronchiole hyperplasia were typically focal lesions characterized by increased numbers of large, plump cuboidal cells (type II pneumocytes) containing large, hyperchromatic nuclei, with maintenance of the alveolar and bronchiole architectures.

Nose: The incidences of olfactory epithelium atrophy in 1,250 mg/L females and olfactory epithelium respiratory metaplasia in 625 mg/L males and in 1,250 mg/L males and females were significantly increased compared to the controls (Table 17, Table C-4, and Table D-5).

Table 17 Incidences of Nonneoplastic Lesions of the Nose in Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Olfactory Epithelium, Atrophy^a^ | 3 (1.3)^b^ | 4 (1.3) | 8 (1.5) | 7 (1.6)
Olfactory Epithelium, Metaplasia, Respiratory | 8 (1.0) | 12 (1.1) | 30** (1.3) | 41** (1.7)
Female
Number Examined Microscopically | 49 | 44 | 49 | 47
Olfactory Epithelium, Atrophy | 1 (1.0) | 2 (1.0) | 2 (1.0) | 7* (1.3)
Olfactory Epithelium, Metaplasia, Respiratory | 2 (1.0) | 2 (1.0) | 7 (1.0) | 14** (1.2)

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Nose olfactory epithelium atrophy was characterized by thinning of the pseudostratified columnar epithelium and respiratory metaplasia was characterized by replacement of olfactory epithelium with a single layer of ciliated columnar (respiratory) epithelium. Respiratory epithelium hyperplasia consisted of hyperplastic epithelium that was thickened due to increased cellularity with a folded or scalloped appearance due to mucosal invaginations with the formation of intraepithelial crypt-like structures or “pseudoglands.” This hyperplastic epithelium quite often had a rugose appearance of the mucosal surface due to numerous deep invaginations with a notable expansion of the mucosa and lamina propria. Pseudoglands were sometimes filled with inflammatory cells and mucus.

## Genetic Toxicology

β-Picoline was tested in three independent bacterial gene mutation studies, and negative results were obtained in all studies (Table E-1 and Table E-2). In the first study (with concentrations ranging from 85.4 to 8,540 μg/plate), no increases in the numbers of mutant colonies were seen in Salmonella typhimurium strains TA98, TA100, TA1535, and TA1537 with and without 10% S9 derived from induced hamster or rat liver. In the second study, negative results were obtained over a concentration range of 100 to 10,000 μg/plate in S. typhimurium strains TA97, TA98, TA100, and TA1535 with and without 10% or 30% S9 derived from induced hamster or rat liver. In the third study, which tested the same chemical lot 11108CI that was used in the 3-month and 2-year studies, negative results were obtained over a concentration range of 1,000 to 10,000 μg/plate in S. typhimurium strains TA98 and TA100 and 100 to 5,000 μg/plate in Escherichia coli WP2 uvrA/pKM101, with and without 10% rat liver S9.

In vivo, no significant increases in the frequencies of micronucleated normochromatic erythrocytes, an indicator of chromosomal damage, were observed in peripheral blood of male or female B6C3F1/N mice exposed to 78 to 1,250 mg β-picoline/L in drinking water for 3 months (Table E-3). No significant alterations in the percentage of circulating polychromatic erythrocytes (reticulocytes) were observed, suggesting that β-picoline did not induce bone marrow toxicity over the exposure concentration range tested.