# Materials and Methods

## Procurement and Characterization

### β-Picoline

β-Picoline was obtained from Aldrich Chemical Company, Inc. (Milwaukee, WI), in one lot (11108CI) that was used during the 3-month and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) and the study laboratory at Battelle Columbus Operations (Columbus, OH); Karl Fischer titration and elemental analyses were performed by Galbraith Laboratories, Inc. (Knoxville, TN) (Appendix I). One additional lot (14517PS) obtained from Aldrich Chemical Company was used by the analytical chemistry laboratory for dose formulation stability studies and was not used in the 3-month or 2-year animal studies. Reports on analyses performed in support of the β-picoline studies are on file at the National Institute of Environmental Health Sciences.

Lot 11108CI, a clear, pale-yellow liquid, was identified as β-picoline by the analytical chemistry laboratory and the study laboratory using infrared spectroscopy; the analytical chemistry laboratory also used proton and carbon-13 nuclear magnetic resonance spectroscopy. Karl Fischer titration was used to determine the water content of lot 11108CI and elemental analyses were used to determine the carbon, hydrogen, and nitrogen content. The purity of lot 11108CI was determined by the analytical chemistry laboratory using gas chromatography and differential scanning calorimetry.

Differential scanning calorimetry analysis indicated a purity of 96.4%. Karl Fischer titration indicated a 2.5% water content. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for β-picoline. Gas chromatography with flame ionization detection analysis indicated one major peak (β-picoline) and only two impurities with individual peak areas greater than 0.1%. The peak areas for the impurities represented a total of 1% of lot 11108CI (0.6% and 0.4%, respectively).

To ensure stability, the bulk chemical was stored at room temperature in amber glass bottles sealed with Teflon^®^-lined lids under a nitrogen head space.

Periodic reanalyses of the bulk chemical were performed by the study laboratory using gas chromatography at the beginning and end of the 3-month and 2-year studies, and approximately every 6 months during the 2-year studies; no degradation of the bulk chemical occurred.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared five times for the 3-month studies and approximately every 4 weeks for the 2-year studies by mixing β-picoline with tap water (Table I-1). The pH was adjusted if necessary to bring it within the range of 6 to 7.5 by the addition of acetic acid. The dose formulations were determined to be true solutions. Stability studies of 10 µg/mL formulations were performed by the analytical chemistry laboratory using a high-performance liquid chromatography with ultraviolet light detection. Stability was confirmed for at least 42 days for formulations stored in sealed polyethylene bottles protected from light at 5°C and for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of β-picoline were performed by the study laboratory using high-performance liquid chromatography with ultraviolet detection. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations analyzed and used for rats and mice were within 10% of the target concentrations (Table I-2). Animal room samples of these dose formulations were also analyzed; all 15 animal room samples for rats and all 15 for mice were within 10% of the target concentrations. During the 2 year studies, the dose formulations were analyzed at least every 12 weeks. All 50 dose formulations analyzed and used for rats and all 50 for mice were within 10% of the target concentrations (Table I-3). Animal room samples were also analyzed; all 12 animal room samples for rats and all 12 for mice were within 10% of the target concentrations.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to β-picoline and to determine the appropriate exposure concentrations to be used in the 2-year studies.

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc., Germantown, NY. On receipt, the rats and mice were approximately 4 weeks old. Rats were quarantined for 11 (males) or 12 (females) days and mice for 14 (females) or 15 (males) days. Rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At 1 month and at the end of the studies, serologic analyses were performed on five male and five female sentinel rats and mice using the protocols of the NTP Sentinel Animal Program (Appendix L).

Groups of 10 male and 10 female core study rats and mice were exposed to 0, 78, 156, 312, 625, or 1,250 mg β-picoline/L drinking water for 14 weeks. Special study groups of 10 male and 10 female rats were exposed to the same concentrations for 23 days. Feed and water were available ad libitum. Rats and female mice were housed five per cage; male mice were housed individually. Clinical findings for core study rats and mice were recorded once a week beginning on day 1 and at the end of the studies. Water consumption was recorded weekly by cage. The animals were weighed initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Drinking Water Studies of β-Picoline

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (males) or 12 (females) days Mice: 15 (males) or 14 (females) days | Rats: 14 (males) or 15 (females) days Mice: 12 (males) or 11 (females) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks | Rats: 6 to 7 weeks Mice: 5 to 6 weeks
Date of First Exposure
Rats: November 17 (males) or 18 (females), 2003 Mice: November 21 (males) or 20 females), 2003 | Rats: November 18 (males) or 19 (females), 2004 Mice: November 9 (males) or 8 (females), 2004
Duration of Exposure
Core studies: 14 weeks Special study rats: 4 weeks | 104 (male rats) or 105 weeks
Date of Last Exposure
Rats: Core study: February 17 (males) or 18 (females), 2004 Special study: December 9 (males) or 10 (females), 2003 Mice: February 20 (males) or 19 (females), 2004 | Rats: November 15 (males) or 17 (females), 2006 Mice: November 10 (males) or 8 (females), 2006
Necropsy Dates
Rats: February 17 (males) or 18 (females), 2004 Mice: February 20 (males) or 19 (females), 2004 | Rats: November 13–15 (males) or 15–17 (females), 2006 Mice: November 8–10 (males) or 6–8 (females), 2006
Average Age at Necropsy
19 to 20 weeks | Rats: 110 or 111 weeks Mice: 110 or 111 weeks (males); 109 or 110 weeks (females)
Size of Study Groups
10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 2 or 3 (males) or 5 (females) Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly | Same as 3-month studies
Water
Tap water (Columbus municipal supply) via glass sipper tube water bottles (glass bottles: Supelco, Inc., Bellfonte, PA; stainless steel double-ball bearing sipper tubes: Ancare Corp., Bellmore, NY), available ad libitum, changed at least twice weekly | Same as 3-month studies, except glass bottles used for rats and female mice supplied by VWR (West Chester, PA)
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (male mice) or twice weekly (rats and female mice) and rotated every 2 weeks | Same as 3-month studies, except changed twice weekly and rotated every 2 weeks
Bedding
Irradiated Sani-Chips (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly (male mice) or twice weekly (rats and female mice) | Same as 3-month studies, except changed twice weekly
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as 3-month studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as 3-month studies
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour
Exposure Concentrations
0, 78, 156, 312, 625, or 1,250 mg/L in drinking water, available ad libitum | Rats: 0, 156.25, 312.5, or 625 mg/L in drinking water, available ad libitum Mice: 0, 312.5, 625, or 1,250 mg/L in drinking water, available ad libitum
Type and Frequency of Observation
Observed twice daily; clinical findings were recorded and core study animals were weighed initially, weekly, and at the end of the studies. Water consumption was recorded weekly by cage. | Observed twice daily; clinical findings were recorded every 4 weeks beginning week 5 and at the end of the studies; animals were weighed initially, weekly for 13 weeks, monthly thereafter, and at the end of the studies. Water consumption was recorded weekly for the first 13 weeks of the study, then monthly thereafter by cage.
Method of Kill
Carbon dioxide asphyxiation | Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
Blood was collected from the retroorbital sinus of special study rats on days 4 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose (week 14 only), total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids | None
Cytochrome P450 Activity
On day 23, tissue samples from the liver of special study rats were taken for determination of 7-pentoxyresorufin-O-dealkylase activity. | None
Histopathology
Complete histopathologic examinations were performed on 0 and 1,250 mg/L core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), left kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus. The left kidney was also examined in the remaining groups of core study rats. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, oral mucosa, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, tongue, trachea, urinary bladder, and uterus.
α2u-Globulin
At the end of the study, the right kidneys of core study male rats were collected for α2u-globulin determination. | None
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male rats in the 0, 156, 312, and 625 mg/L groups and from male mice in the 0, 312, 625, and 1,250 mg/L groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from female rats in the 0, 156, 312, and 625 mg/L groups and from female mice in the 0, 312, 625, and 1,250 mg/L groups. | None

For determination of hepatic cytochrome P450 2B1 (CYP2B1) activity, liver tissue samples were collected from special study rats on day 23 and stored frozen at −70°C until shipped to Battelle Toxicology Northwest (Richland, WA) for analysis. Microsomal suspensions were prepared using the Pearce Method.^21^ The concentration of protein in each suspension was determined using the microtiter plate method of the Coomassie^®^ Plus Protein Assay (Pierce Chemical Co., Rockford, IL) with bovine serum albumin as the standard. CYP2B1-associated pentoxyresorufin-O-dealkylase activities were determined in microsomal proteins and isolated from frozen liver samples according to established procedures.

After anesthesia with carbon dioxide, blood was collected from the retroorbital sinus of special study rats on days 4 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. Blood samples for hematology analyses were placed in tubes containing EDTA and gently inverted to prevent clotting. All automated hematology measurements were performed on an ADVIA^®^ 120 Hematology Analyzer (Bayer, Inc., Tarrytown, NY) using reagents supplied by manufacturer (Siemens Healthcare Diagnostics, city, state). Leukocyte differentials were counted on slides stained with a modified Wright’s stain using an Ames Hema-Tek slide stainer (Miles Laboratory, Ames Division, Elkhart, IN). Leukocyte and reticulocyte counts, erythrocyte and platelet counts and morphologies were determined from blood smears by light microscopy. Clinical chemistry parameters in rats were determined using a Roche Hitachi 911 chemistry analyzer (Roche Diagnostics, Corp., Indianapolis, IN). The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on core study rats exposed to 0, 156, 312, or 625 mg/L and mice exposed to 0, 312, 625, or 1,250 mg/L. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin; the left kidney of rats was also stained with Mallory Heidenhain. Complete histopathologic examinations were performed on 0 and 1,250 mg/L core study rats and mice; the left kidney was examined in all core study rats. Table 1 lists the tissues and organs routinely examined.

After weighing, the right kidneys of core study rats were frozen and shipped to Battelle Toxicology Northwest for measurement of soluble protein and α2u-globulin concentrations. Kidneys were thawed, homogenized with sodium/potassium phosphate buffer (pH 7.2), and centrifuged. Soluble protein concentrations in the supernatants were determined using the Roche (biuret) Total Protein Assay (Roche Diagnostics Corp.) performed on the Hitachi 912 Analyzer (Roche Diagnostics Corp.). Analyses of α2u-globulin were conducted using the Quantikine^®^ M Rat α2u-Globulin Immunoassay (R&D Systems, Inc., Minneapolis, MN).

After a review of the laboratory reports and selected histopathology slides by a quality assessment pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, NTP pathologist, reviewing pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^22^ and Boorman et al.^23^

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats were exposed to 0, 156.25, 312.5, or 625 mg β-picoline/L drinking water for 104 (males) or 105 (females) weeks. Groups of 50 male and 50 female mice were exposed to drinking water containing β-picoline at concentrations of 0, 312.5, 625, or 1,250 mg/L for 105 weeks.

### Source and Specification of Animals

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY), for use in the 2-year studies. Rats were quarantined for 14 or 15 days and mice for 11 or 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were 6 to 7 weeks old and mice 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program using extra animals at 1 month; sentinel animals at 6, 12, and 18 months; and 625 mg/L rats and 1,250 mg/L mice at the end of the studies; five males and five females were used at each timepoint (Appendix L).

### Animal Maintenance

All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

Male rats were housed two or three per cage, female rats and mice five per cage, and male mice individually. Feed and water were available ad libitum. Cages were changed twice weekly and rotated every 2 weeks; racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix K.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings were recorded every 4 weeks beginning week 5 and at study termination. Body weights were recorded initially, weekly for 13 weeks, monthly thereafter, and at study termination. Water consumption was recorded weekly by cage for the first 13 weeks of the study, then at 4-week intervals until the end of the study.

Complete necropsies and microscopic examinations were performed on all rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. An examination was conducted for gross lesions of the tongue and remnants of oral cavity for all rats and mice. The tongue of all male and female rats and mice and all untrimmed potential oral mucosa lesions were processed and evaluated. Previously recorded proliferative lesions of the oral cavity were also reevaluated. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the lung of all animals and the liver and nose of mice.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^22^ and Boorman et al.^23^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^24^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^25^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^26^ method for testing two groups for equality and Tarone’s^27^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-4, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, and Table D-5 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^28-30^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^28^ Unless otherwise specified, a value of k=3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^28^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice.^31^ Bailer and Portier^28^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^32^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^33^ and Williams.^34,35^ Hematology, clinical chemistry, CYP2B1, α2u-globulin, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^36^ (as modified by Williams^37^) and Dunn.^38^ Jonckheere’s test^39^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^40^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^41^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^42^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provisions for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical database must be generally similar. One significant factor affecting the background incidence of neoplasms at a variety of sites is diet. In 1995, NTP incorporated a new diet^17^ that contains less protein and more fiber and fat than the NIH-07 diet previously used in toxicity and carcinogenicity studies.^43,44^ The NTP historical database contains all studies that use the NTP-2000 diet with histopathology findings completed within the most recent 5-year period. A second potential source of variability is route of administration. In general, the historical database for a given study will include studies using the same route of administration, and the overall incidences of neoplasms for all routes of administration are included for comparison, including the present study.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^45^ In addition, as records from the 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of β-picoline was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^46,47^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive data-base permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^48^ and the somatic mutation theory of cancer.^49,50^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^51^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^52,53^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^54,55^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^56^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.