# Introduction

Figure 1

β-Picoline (CASRN 108-99-6; Chemical Formula: C_6_H_7_N; Molecular Weight: 93.13)

Synonyms: β-methylpyridine; 3-methylpyridine; m-methylpyridine; m-picoline.

## Chemical and Physical Properties

β-picoline is an aromatic heterocyclic compound that is structurally similar to pyridine. It is a clear, pale-yellow liquid with a boiling point of 143 to 144°C and a specific gravity of 0.9613.^1^ It is combustible, has a vapor pressure of 6.05 mm Hg at 25°C^2^ and a flash point of 40°C.^3^ It is very soluble in acetone and miscible with water, alcohol, and ether.^1,2^

## Production, Use, and Human Exposure

β-picoline is a high production volume chemical with a reported annual United States production volume of approximately 21.2 to 29.1 million pounds.^4^ It is produced from the vapor-phase reaction of acetaldehyde and ammonia with formaldehyde and/or methanol in the presence of a catalyst, or from the vapor-phase reaction of acrolein with ammonia in the presence of an acid catalyst.^2^ It can also be produced using cyclohexylamine, ammonia, and zinc chloride or from the pyrolysis of coal tar or bone oil.^5^

β-Picoline is used as a solvent in the synthesis of pharmaceuticals, resins, dyes, rubber accelerators, and insecticides.^6,7^ It is also used as a laboratory reagent and as an intermediate in the manufacture of waterproofing agents, niacin, and niacinamide.^1,7^ While occupational exposures primarily occur via inhalation or dermal contact during the production or utilization of β-picoline, environmental exposures to humans can occur via contaminated drinking water and food, ambient air, and dermal contact with products containing β-picoline.^2^ Environmental contamination primarily occurs through the release in various waste streams from its use as a solvent, chemical intermediate, and laboratory agent. It is also present in effluents from the manufacture and use of coal-derived liquid fuels and from the disposal of coal liquefaction and gasoline waste byproducts.^2^ β-Picoline released into water may volatize into air where it exists as a vapor but remains in water until degraded as it is not expected to adsorb to suspended solids or sediment.^2^ β-Picoline is also found as a component of cigarette smoke.^2^

## Regulatory Status

β-Picoline is regulated by the U.S. Environmental Protection Agency (USEPA) under the Clean Air Act as part of the national emission standards for organic hazardous air pollutants.^8^ Additionally, the USEPA regulates β-picoline as a substituted pyridine under the Toxic Substances Control Act by requiring any significant new use to be reported to the USEPA,^9^ and by requiring manufacturers, importers, and processors to submit unpublished health and safety studies.^10^ The U.S. Coast Guard and the U.S. Department of Transportation (DOT) regulate the transport of β-picoline. The U.S. Coast Guard considers β-picoline a hazardous aromatic amine and requires transport on ocean vessels with other aromatic amines to avoid incompatibility or reactivity with other chemicals.^11^ The DOT considers β-picoline a hazardous material and requires specific criteria with respect to labeling and packaging for transport.^12^

## Absorption, Distribution, Metabolism, and Excretion

There is limited information available on the absorption, distribution, metabolism, and excretion of β-picoline. β-Picoline is readily absorbed from the gastrointestinal tract, intraperitoneal cavity, and the lungs and moderately well absorbed through the skin.^3^ Gorrod and Damani^13^ investigated in vitro carbon (C) and nitrogen (N)-oxidation of β-picoline to 3-pyridylcarbinol and 3-methylpyridine N-oxide, respectively, with hepatic and lung microsomes from various species. These studies demonstrated species- and sex-specific variability in hepatic N-oxidation with male rats producing greater amounts of 3-methylpyridine N-oxide and 3-pyridylcarbinol than females. The reverse was observed in mice with females producing greater amounts of C- and N-oxidation products than males. Further studies by Gorrod and Damani^14^ investigated metabolic N-oxidation of β-picoline in vivo following intraperitoneal administration in mice, hamsters, rats, guinea pigs, rabbits, and ferrets. These studies demonstrated that less than 7% of β-picoline was excreted as 3-methylpyridine N-oxide in the urine of each species.

## Toxicity

### Experimental Animals

Acute studies with β-picoline have reported an oral LD_50_ in rats and mice of 400 to 1,600 mg/kg, and an intraperitoneal LD_50_ of 100 to 200 mg/kg in rats and 400 to 800 mg/kg in mice. In Long-Evans hooded rats administered 100 mg/kg, Dyer et al.^15^ investigated the neurophysiological effects of acute exposure to β-picoline. These studies demonstrated increased latency of evoked potentials and increased latency to pentylenetetrazol-induced seizures, measures of sensory function and cerebral excitability, respectively. These effects are consistent with other chemicals that induce central nervous system depression. In male New Zealand albino rabbits, β-picoline produced moderate to severe dermal and ocular irritation.^16^ Histological examination demonstrated keratitis lesions in corneal epithelial tissue, fibrillary edematous lamellae dissociation, and cellular inflammatory infiltration in the eye, and necrosis, ulceration, and regeneration in the skin.

β-Picoline is structurally related to pyridine, but differs from pyridine in the presence of a methyl group on the beta (3-) carbon. The National Toxicology Program (NTP) has previously conducted toxicology and carcinogenesis studies of pyridine administered in drinking water.^17^ Thirteen-week and 2-year studies were conducted in male and female F344/N rats and B6C3F1 mice, and male Wistar rats. In the 13-week subchronic studies, pyridine administration in the drinking water induced significant liver toxicity and/or altered hepatic function in both F344/N and Wistar rats. Kidney lesions consistent with α2u-globulin nephropathy were observed in F344/N males, but these lesions were not observed in the Wistar males, which are generally considered nonresponsive to chemicals that mediate α2u-globulin nephropathy. In mice, no treatment-related lesions were observed after 13 weeks of exposure.

### Humans

No specific toxicity studies of β-picoline in humans were found in the literature.

## Reproductive and Developmental Toxicity

No information regarding the reproductive and developmental effects of β-picoline in experimental animals or humans were found in the literature.

## Carcinogenicity

No information regarding the carcinogenic effects of β-picoline in experimental animals or epidemiology studies in humans were found in the literature. In the National Toxicology Program^17^ carcinogenicity studies, administration of pyridine induced renal tubule neoplasms in male F344/N rats and malignant hepatocellular neoplasms in male and female B6C3F1 mice. There were also increased incidences of mononuclear cell leukemia in male F344/N rats and interstitial cell adenoma of the testis in male Wistar rats. Based on these findings, it was concluded that there was evidence of carcinogenic activity in male F344/N rats and male and female B6C3F1 mice.

## Genetic Toxicity

There is no evidence that β-picoline induces genetic damage, although published studies are limited to three bacterial gene mutation assays. β-Picoline did not induce revertants, in tests conducted with or without metabolic activation, in Salmonella typhimurium strains TA97, TA98, TA100, or TA102 at concentrations up to 5,000 µg/plate^18^ or in strains TA98, TA100, TA1535, or TA1537 at concentrations ranging up to 8,540 µg/plate.^19^ Ho et al.^20^ also reported negative results for gene mutation induction in S. typhimurium strain TA98 tested with β-picoline concentrations up to 1,000 µg/plate.

## Study Rationale

β-Picoline was nominated by the National Institute of Environmental Health Sciences for toxicological evaluation and carcinogenicity studies based on its high production volume and potential for human exposure. Animals were exposed via the drinking water because this is a primary route of exposure for humans.