# Appendix M Summary of Peer Review Panel Comments

On February 8, 2012, the draft Technical Report on the toxicology and carcinogenesis studies of β-picoline received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.E. Wyde, NIEHS, introduced the toxicology and carcinogenesis studies of β-picoline by describing the uses of the chemical and its structural similarity to pyridine. Much of the initial knowledge used to design the studies was derived from data on pyridine. Dr. Wyde described the design and results of the studies in rats and mice, including nonneoplastic and neoplastic lesions in test animals. The proposed conclusions were no evidence of carcinogenic activity of β-picoline in male F344/N rats, some evidence of carcinogenic activity of β-picoline in female F344/N rats, equivocal evidence of carcinogenic activity of β-picoline in male B6C3F1/N mice, and clear evidence of carcinogenic activity of β-picoline in female B6C3F1/N mice.

Dr. Mirsalis, the first primary reviewer, felt that it was a good report and he agreed with the proposed conclusions. He noted that the purity of the test article was 96%, and inquired about the other 4%. He requested more discussion on the compound’s palatability. He noted the “high” 78% incidence of hepatocellular adenoma in the female mouse controls and questioned the significance of the increase in the incidences of hepatocellular adenoma in the exposed groups. Finally, he suggested that β-picoline might be a good candidate for reproductive toxicity tests in rats.

Dr. Pino, the second primary reviewer, recommended that the conclusion for male F344/N rats should have been equivocal evidence of carcinogenic activity based on the alveolar/bronchiolar carcinomas, as the report indicated that while the incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in males were similar between control and exposed groups, these observations (referring to the carcinomas in males) may suggest a treatment related progression from benign tumors to malignancy. He asked for more discussion in the text about whether or not hepatocellular adenomas in the female mice might be compound related, which was not mentioned in the conclusion. He asked whether the incidence of multiple alveolar/bronchiolar carcinoma in male mice was above the historical range, because if so, he felt that it should be included in the conclusion. He asked why an increased severity of nephropathy was seen in the 3-month study in male rats, but not in the 2-year study at the same doses. He asked whether the estrous data in rats were skewed by the fact that the estrous cycle was longer than 12 days or unclear in four of the 10 control rats, because if so, he felt that information should be indicated in the discussion.

Dr. Alcorn, the third primary reviewer, questioned the exposure concentrations selected for the studies. She believed that they may have been too high given changes in body weight and water consumption in the 3-month studies. Based on those concerns, she endorsed changing the conclusion for female rats from some evidence to equivocal evidence. She also noted that the control mice lost significant weight in the last year of the study. She asked why the CYP2B1 liver microsomes were assessed, as there was no indication of the importance in the report. She said she would like to see less reference to pyridine in the report.

Dr. Wyde said that most of the impurity in the test article was water, and that there were two impurities at 0.6% and 0.4%. Regarding the high incidence of liver neoplasms in the female mouse controls, he said the proposed conclusion was mainly based on the hepatoblastomas and the hepatocellular carcinomas rather than the adenomas. He said the NTP would consider conducting reproductive studies. He discussed the rationale for the no evidence call in male rats. Dr. S.A. Elmore, NIEHS, explained the approach for evaluating the oral carcinomas. Dr. Mirsalis recommended including information about the compound’s purity in the report.

Dr. Wyde said the intent of the exposure concentration selection had been to be sure the animals were challenged sufficiently. He said the information on pyridine was used as a starting point in the study design due to the lack of information on β-picoline. He said that the body weight loss in mice in the second year of the study was a typical response. He also explained that the call of some evidence of carcinogenic activity in the female rats was based on the occurrence of lung neoplasms in all three exposed groups, increased rates of hyperplasia in the exposed groups, and the potential for the adenomas to progress to carcinomas.

Dr. Roberts noted that there were at least two proposed changes to the conclusions. Dr. Pino said that perhaps the call for male rats should be equivocal evidence of carcinogenic activity based on the alveolar/bronchiolar carcinomas, or that the sentence regarding a possible compound-related progression to malignancy be deleted.

Dr. Anderson, private consultant, said there may have been some confusion as to nomenclature for reviewers who were not accustomed to reading the technical reports. Dr. M.J. Hooth, NIEHS, explained that the NTP makes calls assigning one level of evidence for each sex and species based upon the highest call for each. Dr. Alcorn said she accepted Dr. Wyde’s explanation about dosing and was comfortable with the proposed conclusion regarding the female rats. Dr. Roberts called for a motion on the conclusions for β-picoline. Dr. Mirsalis moved to accept the conclusions as written and Dr. Alcorn seconded the motion. The panel accepted unanimously with 10 votes in favor to accept the conclusions as written.