# Appendix L Sentinel Animal Program

## L.1 Methods

Rodents used in the Carcinogenesis Program of the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of chemical compounds.

For the 3-month studies, serum samples were collected from five male and five female sentinel rats and mice at 1 month and at study termination. For the 2-year studies, serum samples were collected from five male and five female extra rats and mice at 1 month, from five male and five female sentinel rats and mice at 6, 12, and 18 months, and from five male and five female 625 mg/L rats and 1,250 mg/L mice at study termination. Fecal samples were taken from five male and five female sentinel mice at 18 months in the 2-year study for Helicobacter spp. by polymerase chain reaction testing. Blood from each animal was collected and allowed to clot, and the serum was separated. The samples were processed appropriately and sent to BioReliance Corporation (Rockville, MD) for determination of antibody titers. The laboratory methods and agents for which testing was performed are tabulated below; the times at which blood was collected during the studies are also listed.

Table L-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
ELISA
PVM (pneumonia virus of mice) | Study start, 1 month, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study start, 1 month, study termination
Sendai | Study start, 1 month, study termination
Immunofluorescence Assay
Parvovirus | Study start, 1 month, study termination
Sendai | Study start
Two-year Study
ELISA
Mycoplasma arthritidis | Study termination
Mycoplasma pulmonis | Study termination
PVM | Study start, 1, 6, 12, and 18 months, study termination
RCV/SDA | Study start, 1, 6, 12, and 18 months, study termination
Sendai | Study start, 1, 6, 12, and 18 months, study termination
Immunofluorescence Assay
Parvovirus | Study start, 1, 6, 12, and 18 months, study termination
Mice
Three-month Study
ELISA
Ectromelia virus | Study start, 1 month, study termination
EDIM (epizootic diarrhea of infant mice) | Study start, 1 month, study termination
GDVII (mouse encephalomyelitis virus) | Study start, 1 month, study termination
LCM (lymphocytic choriomeningitis virus) | Study start, 1 month, study termination
Mouse adenoma virus | Study start, 1 month, study termination
MHV (mouse hepatitis virus) | Study start, 1 month, study termination
PVM | Study start, 1 month, study termination
Reovirus 3 | Study start, 1 month, study termination
Sendai | Study start, 1 month, study termination
Immunofluorescence Assay
Parvovirus | Study start, 1 month, study termination
Two-year Study
ELISA
Ectromelia virus | Study start, 1, 6, 12, and 18 months, study termination
EDIM | Study start, 1, 6, 12, and 18 months, study termination
GDVII | Study start, 1, 6, 12, and 18 months, study termination
LCM | Study start, 1, 6, 12, and 18 months, study termination
MMV, VP2 (mouse minute virus, viral protein 2) | Study start, 1, 6, 12, and 18 months, study termination
MPV, VP2 (mouse parvovirus, viral protein 2) | Study start, 1, 6, 12, and 18 months, study termination
Mouse adenoma virus-1 | 12, 18 months, study termination
Mouse adenoma virus-FL | Study start, 1, 6 months
MHV | Study start, 1, 6, 12, and 18 months, study termination
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | Study start, 1, 6, 12, and 18 months, study termination
Reovirus 3 | Study start, 1, 6, 12, and 18 months, study termination
Sendai | Study start, 1, 6, 12, and 18 months, study termination
Immunofluorescence Assay
GDVII | 12 months
MPV, VP2 | 18 months
Mouse adenoma virus-1 | 1 month
MCMV (mouse cytomegalovirus) | Study termination
Reovirus 3 | 1, 6 months
Polymerase Chain Reaction
Helicobacter species | 18 months

## L.2 Results

All test results were negative.