# Appendix K Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table K-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table K-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU | –
Niacin | 23 mg | –
Folic acid | 1.1 mg | –
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table K-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.6 ± 0.68 | 13.5–16.3 | 25
Crude fat (% by weight) | 8.2 ± 0.35 | 7.6–9.3 | 25
Crude fiber (% by weight) | 9.2 ± 0.46 | 8.4–10.0 | 25
Ash (% by weight) | 4.9 ± 0.25 | 4.6–5.4 | 25
Amino Acids (% of total diet)
Arginine | 0.778 ± 0.068 | 0.670–0.970 | 21
Cystine | 0.220 ± 0.025 | 0.150–0.250 | 21
Glycine | 0.701 ± 0.042 | 0.620–0.800 | 21
Histidine | 0.354 ± 0.079 | 0.270–0.680 | 21
Isoleucine | 0.544 ± 0.045 | 0.430–0.660 | 21
Leucine | 1.092 ± 0.068 | 0.960–1.240 | 21
Lysine | 0.704 ± 0.112 | 0.310–0.840 | 21
Methionine | 0.409 ± 0.047 | 0.260–0.490 | 21
Phenylalanine | 0.626 ± 0.040 | 0.540–0.720 | 21
Threonine | 0.503 ± 0.043 | 0.430–0.610 | 21
Tryptophan | 0.148 ± 0.027 | 0.110–0.200 | 21
Tyrosine | 0.397 ± 0.058 | 0.280–0.540 | 21
Valine | 0.666 ± 0.044 | 0.550–0.730 | 21
Essential Fatty Acids (% of total diet)
Linoleic | 3.92 ± 0.227 | 3.49–4.54 | 21
Linolenic | 0.30 ± 0.030 | 0.21–0.35 | 21
Vitamins
Vitamin A (IU/kg) | 3,940 ± 775 | 2,340–5,590 | 25
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 80.1 ± 22.48 | 27.0–124.0 | 21
Thiamine (ppm)^b^ | 7.8 ± 1.20 | 6.3–10.5 | 25
Riboflavin (ppm) | 7.1 ± 1.91 | 4.20–11.20 | 21
Niacin (ppm) | 78.6 ± 9.16 | 66.4–98.2 | 21
Pantothenic acid (ppm) | 27.1 ± 12.89 | 17.4–81.0 | 21
Pyridoxine (ppm)^b^ | 9.47 ± 2.01 | 6.4–13.7 | 21
Folic acid (ppm) | 1.63 ± 0.49 | 1.15–3.27 | 21
Biotin (ppm) | 0.319 ± 0.10 | 0.200–0.704 | 21
Vitamin B_12_ (ppb) | 53.8 ± 40.6 | 18.3–174.0 | 21
Choline (ppm)^b^ | 2,885 ± 459 | 1,820–3,790 | 21
Minerals
Calcium (%) | 0.977 ± 0.048 | 0.895–1.080 | 25
Phosphorus (%) | 0.567 ± 0.033 | 0.499–0.623 | 25
Potassium (%) | 0.663 ± 0.027 | 0.626–0.732 | 21
Chloride (%) | 0.387 ± 0.039 | 0.300–0.474 | 21
Sodium (%) | 0.190 ± 0.016 | 0.160–0.222 | 21
Magnesium (%) | 0.216 ± 0.063 | 0.185–0.490 | 21
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 185 ± 40.1 | 135–311 | 21
Manganese (ppm) | 51.6 ± 10.49 | 21.0–73.1 | 21
Zinc (ppm) | 53.6 ± 8.62 | 43.3–78.5 | 21
Copper (ppm) | 7.07 ± 2.611 | 3.21–16.30 | 21
Iodine (ppm) | 0.497 ± 0.209 | 0.158–0.972 | 21
Chromium (ppm) | 0.684 ± 0.279 | 0.330–1.380 | 20
Cobalt (ppm) | 0.26 ± 0.164 | 0.11–0.86 | 19

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table K-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.23 ± 0.058 | 0.16–0.39 | 25
Cadmium (ppm) | 0.05 ± 0.007 | 0.04–0.07 | 25
Lead (ppm) | 0.09 ± 0.014 | 0.07–0.13 | 25
Mercury (ppm) | <0.02 | – | 25
Selenium (ppm) | 0.29 ± 0.099 | 0.18–0.49 | 25
Aflatoxins (ppb) | <5.00 | – | 25
Nitrate nitrogen (ppm)^c^ | 13.78 ± 7.33 | 4.76–36.8 | 25
Nitrite nitrogen (ppm)^c^ | <0.61 | – | 25
BHA (ppm)^d^ | <1.0 | – | 25
BHT (ppm)^d^ | <1.0 | – | 25
Aerobic plate count (CFU/g) | 10 ± 0.0 | 10.0–10.0 | 25
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0–3.0 | 25
Escherichia coli (MPN/g) | <10 | – | 25
Salmonella (MPN/g) | Negative | – | 25
Total nitrosoamines (ppb)^e^ | 4.95 ± 1.68 | 2.0–9.9 | 25
N-Nitrosodimethylamine (ppb)^e^ | 2.8 ± 1.21 | 1.0–6.3 | 25
N-Nitrosopyrrolidine (ppb)^e^ | 2.1 ± 0.73 | 1.1–3.6 | 25
Pesticides (ppm)
α-BHC | <0.01 | – | 25
β-BHC | <0.02 | – | 25
γ-BHC | <0.01 | – | 25
δ-BHC | <0.01 | – | 25
Heptachlor | <0.01 | – | 25
Aldrin | <0.01 | – | 25
Heptachlor epoxide | <0.01 | – | 25
DDE | <0.01 | – | 25
DDD | <0.01 | – | 25
DDT | <0.01 | – | 25
HCB | <0.01 | – | 25
Mirex | <0.01 | – | 25
Methoxychlor | <0.05 | – | 25
Dieldrin | <0.01 | – | 25
Endrin | <0.01 | – | 25
Telodrin | <0.01 | – | 25
Chlordane | <0.05 | – | 25
Toxaphene | <0.10 | – | 25
Estimated PCBs | <0.20 | – | 25
Ronnel | <0.01 | – | 25
Ethion | <0.02 | – | 25
Trithion | <0.05 | – | 25
Diazinon | <0.10 | – | 25
Methyl chlorpyrifos | 0.138 ± 0.128 | 0.020–0.416 | 25
Methyl parathion | <0.02 | – | 25
Ethyl parathion | <0.02 | – | 25
Malathion | 0.245 ± 0.243 | 0.020–0.997 | 25
Endosulfan I | <0.01 | – | 25
Endosulfan II | <0.01 | – | 25
Endosulfan sulfate | <0.03 | – | 25

^a^ All samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.