# Appendix J Water and Compound Consumption in the Two-year Drinking Water Studies of β-Picoline

Table J-1 Water and Compound Consumption by Male Rats in the Two-year Drinking Water Study of β-Picoline

Week | 0 mg/L | | 156.25 mg/L | | | 312.5 mg/L | | | 625 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 14.8 | 116 | 14.7 | 115 | 20 | 14.3 | 116 | 38 | 11.3 | 115 | 62
2 | 16.3 | 150 | 15.9 | 147 | 17 | 15.9 | 148 | 34 | 12.9 | 142 | 57
3 | 17.5 | 181 | 17.0 | 179 | 15 | 16.7 | 181 | 29 | 13.5 | 171 | 49
4 | 17.8 | 212 | 17.3 | 208 | 13 | 17.2 | 208 | 26 | 14.1 | 195 | 45
5 | 16.9 | 232 | 17.1 | 229 | 12 | 16.6 | 230 | 23 | 14.0 | 215 | 41
6 | 16.2 | 248 | 16.3 | 248 | 10 | 16.3 | 248 | 21 | 13.8 | 234 | 37
7 | 15.6 | 262 | 15.3 | 263 | 9 | 14.9 | 263 | 18 | 13.4 | 247 | 34
8 | 15.5 | 277 | 15.7 | 276 | 9 | 14.8 | 278 | 17 | 12.7 | 259 | 31
9 | 15.3 | 289 | 15.6 | 289 | 8 | 14.4 | 290 | 16 | 12.5 | 271 | 29
10 | 14.9 | 301 | 15.2 | 301 | 8 | 14.5 | 302 | 15 | 12.4 | 281 | 28
11 | 15.1 | 311 | 15.5 | 311 | 8 | 14.8 | 313 | 15 | 12.6 | 289 | 27
12 | 15.5 | 322 | 15.4 | 321 | 8 | 14.7 | 323 | 14 | 12.6 | 298 | 26
13 | 15.8 | 330 | 15.9 | 329 | 8 | 15.3 | 330 | 15 | 13.0 | 305 | 27
17 | 15.2 | 357 | 14.8 | 354 | 7 | 14.9 | 357 | 13 | 12.0 | 332 | 23
21 | 15.7 | 378 | 16.0 | 376 | 7 | 15.7 | 383 | 13 | 13.6 | 352 | 24
25 | 16.0 | 400 | 15.9 | 399 | 6 | 15.8 | 402 | 12 | 13.8 | 374 | 23
29 | 14.7 | 409 | 14.8 | 409 | 6 | 14.9 | 416 | 11 | 13.0 | 387 | 21
33 | 15.4 | 423 | 15.0 | 420 | 6 | 14.7 | 429 | 11 | 13.0 | 400 | 20
37 | 15.9 | 434 | 15.4 | 435 | 6 | 14.9 | 441 | 11 | 12.9 | 410 | 20
41 | 15.0 | 442 | 14.4 | 441 | 5 | 14.7 | 453 | 10 | 13.0 | 422 | 19
45 | 15.1 | 453 | 14.7 | 453 | 5 | 14.9 | 462 | 10 | 12.9 | 431 | 19
49 | 16.3 | 458 | 16.0 | 460 | 5 | 15.6 | 467 | 10 | 13.7 | 436 | 20
53 | 16.3 | 468 | 16.2 | 467 | 5 | 16.0 | 477 | 11 | 14.5 | 445 | 20
57 | 16.9 | 478 | 16.6 | 478 | 5 | 16.1 | 487 | 10 | 14.2 | 452 | 20
61 | 17.0 | 481 | 16.8 | 480 | 6 | 15.7 | 487 | 10 | 13.8 | 453 | 19
65 | 16.4 | 486 | 16.2 | 487 | 5 | 15.8 | 493 | 10 | 13.6 | 457 | 19
69 | 16.5 | 493 | 15.9 | 490 | 5 | 15.3 | 499 | 10 | 13.8 | 463 | 19
73 | 17.2 | 501 | 16.8 | 499 | 5 | 15.9 | 506 | 10 | 13.9 | 471 | 19
77 | 16.5 | 504 | 16.3 | 506 | 5 | 15.2 | 510 | 9 | 13.5 | 472 | 18
81 | 16.5 | 508 | 15.8 | 508 | 5 | 14.9 | 511 | 9 | 14.1 | 475 | 19
85 | 17.7 | 512 | 16.7 | 514 | 5 | 15.6 | 514 | 10 | 13.7 | 474 | 18
89 | 16.3 | 516 | 15.4 | 516 | 5 | 13.6 | 516 | 8 | 12.6 | 474 | 17
93 | 16.2 | 512 | 15.6 | 508 | 5 | 13.7 | 504 | 9 | 12.9 | 470 | 17
97 | 16.7 | 507 | 16.6 | 506 | 5 | 14.9 | 502 | 9 | 12.7 | 459 | 17
101 | 19.0 | 503 | 17.3 | 497 | 5 | 15.8 | 501 | 10 | 13.3 | 451 | 18
Mean for Weeks
1–13 | 15.9 | 249 | 15.9 | 247 | 11 | 15.4 | 248 | 22 | 13.0 | 232 | 38
14–52 | 15.5 | 417 | 15.2 | 416 | 6 | 15.1 | 423 | 11 | 13.1 | 394 | 21
53–101 | 16.9 | 498 | 16.3 | 497 | 5 | 15.3 | 501 | 10 | 13.6 | 463 | 18

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.

Table J-2 Water and Compound Consumption by Female Rats in the Two-year Drinking Water Study of β-Picoline

Week | 0 mg/L | | 156.25 mg/L | | | 312.5 mg/L | | | 625 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 11.0 | 99 | 10.6 | 99 | 17 | 10.4 | 100 | 33 | 8.7 | 100 | 54
2 | 12.1 | 117 | 11.9 | 116 | 16 | 10.9 | 116 | 29 | 8.7 | 114 | 48
3 | 12.4 | 132 | 12.4 | 132 | 15 | 11.8 | 131 | 28 | 9.3 | 124 | 47
4 | 11.6 | 144 | 11.6 | 144 | 13 | 11.0 | 144 | 24 | 9.4 | 137 | 43
5 | 11.1 | 152 | 11.3 | 153 | 12 | 10.8 | 154 | 22 | 9.5 | 145 | 41
6 | 11.1 | 162 | 11.6 | 165 | 11 | 10.4 | 165 | 20 | 9.5 | 157 | 38
7 | 10.6 | 170 | 11.1 | 172 | 10 | 10.7 | 171 | 20 | 8.8 | 163 | 34
8 | 10.8 | 175 | 10.7 | 176 | 10 | 10.0 | 175 | 18 | 8.6 | 168 | 32
9 | 10.2 | 180 | 10.3 | 181 | 9 | 9.8 | 181 | 17 | 8.4 | 172 | 31
10 | 10.4 | 184 | 10.0 | 186 | 8 | 9.3 | 185 | 16 | 8.4 | 175 | 30
11 | 10.3 | 188 | 10.7 | 191 | 9 | 9.5 | 188 | 16 | 8.8 | 180 | 31
12 | 10.4 | 192 | 10.5 | 193 | 9 | 9.5 | 192 | 16 | 8.8 | 183 | 30
13 | 10.5 | 195 | 10.4 | 196 | 8 | 8.9 | 194 | 14 | 8.6 | 185 | 29
17 | 9.7 | 207 | 10.4 | 208 | 8 | 9.8 | 208 | 15 | 8.5 | 197 | 27
21 | 10.4 | 218 | 10.3 | 218 | 7 | 9.9 | 216 | 14 | 8.6 | 203 | 26
25 | 10.9 | 223 | 10.9 | 226 | 8 | 10.3 | 225 | 14 | 9.6 | 213 | 28
29 | 10.5 | 233 | 10.1 | 233 | 7 | 9.1 | 228 | 13 | 8.7 | 220 | 25
33 | 10.8 | 238 | 10.4 | 241 | 7 | 10.1 | 238 | 13 | 8.9 | 229 | 24
37 | 10.1 | 247 | 9.7 | 248 | 6 | 9.4 | 245 | 12 | 8.5 | 235 | 23
41 | 10.8 | 253 | 9.9 | 256 | 6 | 9.8 | 251 | 12 | 8.6 | 242 | 22
45 | 10.8 | 264 | 10.3 | 265 | 6 | 9.5 | 261 | 11 | 9.1 | 251 | 23
49 | 11.6 | 270 | 10.7 | 271 | 6 | 10.0 | 265 | 12 | 9.7 | 256 | 24
53 | 12.1 | 282 | 11.0 | 281 | 6 | 10.8 | 275 | 12 | 9.5 | 265 | 22
57 | 12.1 | 294 | 11.4 | 293 | 6 | 11.0 | 285 | 12 | 10.3 | 274 | 24
61 | 12.5 | 302 | 11.2 | 299 | 6 | 11.1 | 289 | 12 | 10.3 | 278 | 23
65 | 12.7 | 311 | 11.7 | 309 | 6 | 11.6 | 299 | 12 | 10.4 | 286 | 23
69 | 12.9 | 319 | 11.9 | 319 | 6 | 11.2 | 307 | 11 | 10.8 | 294 | 23
73 | 13.2 | 328 | 12.6 | 329 | 6 | 11.9 | 319 | 12 | 11.7 | 305 | 24
77 | 13.3 | 340 | 12.1 | 336 | 6 | 11.6 | 326 | 11 | 11.0 | 311 | 22
81 | 13.4 | 344 | 12.5 | 340 | 6 | 11.6 | 331 | 11 | 11.5 | 313 | 23
85 | 13.3 | 348 | 13.6 | 346 | 6 | 12.8 | 336 | 12 | 11.9 | 315 | 24
89 | 13.0 | 352 | 12.8 | 353 | 6 | 12.0 | 344 | 11 | 11.3 | 322 | 22
93 | 16.2 | 353 | 16.9 | 351 | 8 | 15.3 | 348 | 14 | 13.0 | 322 | 25
97 | 13.8 | 350 | 15.1 | 355 | 7 | 12.5 | 348 | 11 | 12.1 | 326 | 23
101 | 14.2 | 339 | 15.7 | 349 | 7 | 13.9 | 346 | 13 | 13.9 | 323 | 27
Mean for Weeks
1–13 | 11.0 | 161 | 11.0 | 162 | 11 | 10.2 | 161 | 21 | 8.9 | 154 | 38
14–52 | 10.6 | 239 | 10.3 | 241 | 7 | 9.8 | 237 | 13 | 8.9 | 227 | 25
53–101 | 13.3 | 328 | 13.0 | 328 | 6 | 12.1 | 319 | 12 | 11.4 | 303 | 23

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.

Table J-3 Water and Compound Consumption by Male Mice in the Two-year Drinking Water Study of β-Picoline

Week | 0 mg/L | | 312.5 mg/L | | | 625 mg/L | | | 1,250 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 3.9 | 23.7 | 3.7 | 23.8 | 49 | 3.7 | 23.6 | 98 | 3.4 | 23.7 | 180
2 | 3.8 | 25.8 | 3.4 | 25.5 | 42 | 3.5 | 25.2 | 87 | 3.3 | 25.2 | 164
3 | 3.8 | 27.2 | 3.6 | 27.0 | 42 | 3.4 | 26.5 | 80 | 3.3 | 26.6 | 155
4 | 3.7 | 28.8 | 3.7 | 28.7 | 40 | 3.5 | 28.1 | 78 | 3.6 | 28.1 | 160
5 | 3.8 | 30.9 | 3.6 | 30.5 | 37 | 3.5 | 29.8 | 73 | 3.5 | 29.9 | 147
6 | 3.8 | 33.0 | 3.7 | 32.5 | 36 | 3.6 | 31.6 | 71 | 3.4 | 31.5 | 135
7 | 4.0 | 35.0 | 3.8 | 34.5 | 35 | 3.7 | 33.3 | 70 | 3.7 | 33.3 | 139
8 | 3.6 | 36.6 | 3.6 | 35.9 | 31 | 3.5 | 34.8 | 63 | 3.5 | 34.7 | 126
9 | 3.7 | 38.1 | 3.4 | 37.5 | 28 | 3.4 | 36.2 | 59 | 3.2 | 36.2 | 111
10 | 3.7 | 39.7 | 3.5 | 39.0 | 28 | 3.5 | 37.7 | 58 | 3.3 | 37.7 | 110
11 | 3.5 | 41.2 | 3.4 | 40.7 | 26 | 3.4 | 39.3 | 54 | 3.2 | 39.3 | 102
12 | 3.6 | 42.9 | 3.5 | 42.2 | 26 | 3.3 | 40.8 | 51 | 3.2 | 40.8 | 98
13 | 3.6 | 44.1 | 3.4 | 43.2 | 25 | 3.4 | 41.8 | 51 | 3.2 | 41.8 | 96
17 | 3.6 | 48.0 | 3.5 | 46.8 | 23 | 3.2 | 45.4 | 44 | 3.2 | 45.3 | 88
21 | 3.7 | 49.5 | 3.4 | 48.5 | 22 | 3.4 | 47.2 | 45 | 3.4 | 46.5 | 91
25 | 3.6 | 50.2 | 3.4 | 49.1 | 22 | 3.3 | 47.9 | 43 | 3.1 | 47.1 | 82
29 | 4.2 | 51.9 | 3.8 | 50.8 | 23 | 3.5 | 49.6 | 44 | 3.4 | 48.5 | 88
33 | 4.1 | 52.9 | 3.6 | 52.0 | 22 | 3.4 | 50.5 | 42 | 3.0 | 49.1 | 76
37 | 4.2 | 54.0 | 3.8 | 52.9 | 22 | 3.6 | 51.3 | 44 | 3.2 | 49.7 | 81
41 | 4.2 | 55.1 | 3.9 | 54.0 | 23 | 3.5 | 52.2 | 42 | 3.0 | 50.3 | 75
45 | 4.4 | 55.9 | 4.1 | 55.3 | 23 | 3.7 | 53.2 | 44 | 3.0 | 51.0 | 74
49 | 4.5 | 56.7 | 4.2 | 55.7 | 24 | 3.7 | 53.2 | 43 | 3.2 | 51.5 | 78
53 | 4.8 | 56.7 | 4.4 | 55.9 | 25 | 4.0 | 54.1 | 46 | 3.3 | 52.1 | 79
57 | 5.0 | 57.1 | 4.6 | 56.5 | 25 | 4.1 | 53.9 | 48 | 3.4 | 51.9 | 82
61 | 4.9 | 57.0 | 4.5 | 56.0 | 25 | 4.2 | 53.4 | 49 | 3.3 | 51.1 | 81
65 | 4.8 | 56.3 | 4.6 | 55.6 | 26 | 4.0 | 52.9 | 47 | 3.1 | 50.8 | 76
69 | 4.8 | 56.3 | 4.6 | 55.6 | 26 | 4.1 | 53.1 | 48 | 3.2 | 49.9 | 80
73 | 4.9 | 56.2 | 4.6 | 55.0 | 26 | 4.4 | 52.9 | 52 | 3.4 | 48.8 | 87
77 | 4.7 | 55.4 | 4.6 | 54.1 | 27 | 4.1 | 52.5 | 49 | 3.1 | 47.2 | 82
81 | 4.9 | 54.3 | 4.8 | 52.5 | 29 | 4.4 | 51.4 | 54 | 3.3 | 46.1 | 89
85 | 4.5 | 53.2 | 4.3 | 51.4 | 26 | 3.9 | 50.3 | 48 | 3.3 | 44.9 | 92
89 | 4.5 | 50.3 | 4.1 | 51.5 | 25 | 3.8 | 49.0 | 48 | 3.2 | 42.7 | 94
93 | 4.4 | 48.5 | 4.2 | 51.1 | 26 | 3.8 | 46.5 | 51 | 3.2 | 40.6 | 99
97 | 4.4 | 46.8 | 4.3 | 48.6 | 28 | 3.8 | 45.0 | 53 | 3.3 | 37.9 | 109
101 | 4.4 | 43.0 | 4.4 | 47.6 | 29 | 4.0 | 42.7 | 59 | 3.4 | 36.8 | 115
Mean for Weeks
1–13 | 3.7 | 34.4 | 3.6 | 33.9 | 34 | 3.5 | 33.0 | 69 | 3.4 | 33.0 | 132
14–52 | 4.1 | 52.7 | 3.7 | 51.7 | 23 | 3.5 | 50.1 | 43 | 3.2 | 48.8 | 81
53–101 | 4.7 | 53.2 | 4.5 | 53.2 | 26 | 4.0 | 50.6 | 50 | 3.3 | 46.2 | 90

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.

Table J-4 Water and Compound Consumption by Female Mice in the Two-year Drinking Water Study of β-Picoline

Week | 0 mg/L | | 312.5 mg/L | | | 625 mg/L | | | 1,250 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 2.5 | 18.6 | 2.4 | 18.8 | 40 | 2.3 | 18.7 | 77 | 2.1 | 18.5 | 142
2 | 2.5 | 19.7 | 2.4 | 19.7 | 38 | 2.3 | 19.2 | 75 | 2.0 | 19.1 | 131
3 | 2.6 | 20.7 | 2.3 | 20.6 | 35 | 2.4 | 20.2 | 74 | 2.2 | 20.0 | 137
4 | 2.8 | 21.4 | 2.6 | 21.7 | 37 | 2.4 | 21.3 | 70 | 2.3 | 20.8 | 138
5 | 2.7 | 22.3 | 2.7 | 22.7 | 37 | 2.4 | 22.1 | 68 | 2.2 | 21.5 | 128
6 | 2.8 | 23.4 | 2.6 | 23.4 | 35 | 2.5 | 22.7 | 69 | 2.3 | 22.4 | 128
7 | 3.0 | 24.5 | 2.9 | 24.6 | 37 | 2.7 | 23.7 | 71 | 2.5 | 23.3 | 134
8 | 2.8 | 25.1 | 2.8 | 25.0 | 35 | 2.6 | 24.4 | 67 | 2.3 | 23.6 | 122
9 | 2.8 | 26.6 | 2.7 | 26.6 | 32 | 2.5 | 25.5 | 61 | 2.3 | 24.8 | 116
10 | 2.9 | 27.5 | 2.7 | 27.7 | 30 | 2.7 | 27.1 | 62 | 2.3 | 25.8 | 112
11 | 2.8 | 29.3 | 2.7 | 29.3 | 29 | 2.6 | 28.5 | 57 | 2.2 | 26.5 | 104
12 | 2.8 | 30.5 | 2.7 | 30.6 | 28 | 2.6 | 30.1 | 54 | 2.4 | 27.9 | 108
13 | 2.8 | 31.8 | 2.8 | 32.1 | 27 | 2.7 | 31.1 | 54 | 2.3 | 28.9 | 99
17 | 2.7 | 37.6 | 2.7 | 37.5 | 23 | 2.6 | 36.5 | 45 | 2.4 | 33.7 | 89
21 | 2.6 | 43.3 | 2.5 | 42.9 | 18 | 2.6 | 41.2 | 39 | 2.3 | 38.8 | 74
25 | 2.3 | 47.3 | 2.3 | 47.2 | 15 | 2.2 | 45.0 | 31 | 1.9 | 42.3 | 56
29 | 2.3 | 50.4 | 2.3 | 50.2 | 14 | 2.2 | 47.8 | 29 | 2.1 | 45.3 | 58
33 | 2.5 | 53.3 | 2.4 | 53.3 | 14 | 2.4 | 51.0 | 29 | 2.0 | 48.2 | 52
37 | 2.5 | 55.2 | 2.5 | 55.6 | 14 | 2.4 | 52.9 | 28 | 2.2 | 50.3 | 55
41 | 2.5 | 57.5 | 2.5 | 57.3 | 14 | 2.4 | 54.8 | 27 | 2.2 | 51.9 | 53
45 | 2.5 | 58.6 | 2.5 | 58.4 | 13 | 2.3 | 55.4 | 26 | 2.2 | 53.0 | 52
49 | 2.6 | 59.7 | 2.7 | 59.5 | 14 | 2.6 | 57.1 | 28 | 2.4 | 54.7 | 55
53 | 2.8 | 61.5 | 2.8 | 60.5 | 15 | 3.0 | 58.5 | 32 | 2.6 | 55.5 | 59
57 | 2.7 | 62.8 | 2.8 | 62.6 | 14 | 3.0 | 60.2 | 31 | 2.5 | 56.8 | 55
61 | 2.9 | 63.8 | 3.3 | 63.6 | 16 | 3.2 | 61.3 | 33 | 2.6 | 57.5 | 57
65 | 3.0 | 65.0 | 3.0 | 64.8 | 15 | 3.2 | 62.2 | 32 | 2.5 | 58.1 | 54
69 | 2.9 | 65.6 | 3.1 | 65.4 | 15 | 3.1 | 62.5 | 31 | 2.6 | 59.0 | 55
73 | 3.4 | 67.3 | 3.3 | 66.1 | 16 | 3.4 | 63.4 | 34 | 2.9 | 59.3 | 61
77 | 3.2 | 67.4 | 3.3 | 64.7 | 16 | 3.1 | 63.1 | 31 | 2.6 | 59.7 | 54
81 | 3.6 | 66.2 | 3.9 | 65.1 | 19 | 3.2 | 64.1 | 31 | 2.9 | 60.0 | 60
85 | 3.5 | 65.3 | 3.7 | 65.2 | 18 | 3.2 | 64.0 | 31 | 2.8 | 60.3 | 58
89 | 3.5 | 64.9 | 3.3 | 64.8 | 16 | 3.2 | 63.7 | 31 | 2.6 | 58.6 | 56
93 | 4.0 | 63.9 | 3.8 | 63.6 | 19 | 3.6 | 62.5 | 36 | 2.9 | 56.5 | 64
97 | 4.1 | 61.2 | 3.8 | 61.0 | 20 | 3.9 | 60.2 | 41 | 3.0 | 56.5 | 66
101 | 3.7 | 60.6 | 3.8 | 57.4 | 21 | 4.0 | 57.5 | 44 | 3.5 | 53.3 | 82
Mean for Weeks
1–13 | 2.8 | 24.7 | 2.6 | 24.8 | 34 | 2.5 | 24.2 | 66 | 2.3 | 23.3 | 123
14–52 | 2.5 | 51.4 | 2.5 | 51.3 | 15 | 2.4 | 49.1 | 31 | 2.2 | 46.5 | 60
53–101 | 3.3 | 64.3 | 3.4 | 63.4 | 17 | 3.3 | 61.8 | 34 | 2.8 | 57.8 | 60

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of β-picoline consumed per kilogram body weight per day.