# Appendix I Chemical Characterization and Dose Formulation Studies

## I.1 Procurement and Characterization

### I.1.1 β-Picoline

β-picoline was obtained from Aldrich Chemical Company, Inc. (Milwaukee, WI), in one lot (11108CI) that was used during the 3-month and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) and the study laboratory at Battelle Columbus Operations (Columbus, OH). Karl Fischer titration and elemental analyses were performed by Galbraith Laboratories, Inc. (Knoxville, TN). One additional lot (14517PS) obtained from Aldrich Chemical Company was used by the analytical chemistry laboratory for dose formulation stability studies and was not used in the 3-month or 2-year animal studies. Reports on analyses performed in support of the β-picoline studies are on file at the National Institute of Environmental Health Sciences.

Lot 11108CI, a clear, pale-yellow liquid, was identified as β-picoline by the analytical chemistry laboratory and the study laboratory using infrared (IR) spectroscopy; the analytical chemistry laboratory also used proton and carbon-13 nuclear magnetic resonance spectroscopy. All spectra were consistent with the literature spectra^63-65^ of β-picoline and the structure of β-picoline. A representative IR spectrum is presented in Figure I-1.

Karl Fischer titration was used to determine the water content of lot 11108CI and elemental analyses were used to determine the carbon, hydrogen, and nitrogen content. The purity of lot 11108CI was determined by the analytical chemistry laboratory using gas chromatography (GC) by system A and differential scanning calorimetry (DSC). DSC was performed using a method which included a Perkin Elmer DSC-7 instrument (Perkin Elmer, Inc., Shelton, CT) scanning from −45° to −15°C (−45 to 10°C for the first replicate) with a temperature increase of 1°C per minute under a nitrogen atmosphere.

- A) The GC system included a gas chromatograph (Agilent Inc., Palo Alto, CA) with flame ionization detection (FID), a 30 m × 0.25 mm, 0.5 µm film thickness column (Restek Corporation, Bellefonte, CA), an oven temperature program of 80°C, held for 4 minutes, increased at 5°C/minute to 130°C, held for 2 minutes, and helium carrier gas at a flow rate of 1.5 mL/minute.

Differential scanning calorimetry analysis indicated a purity of 96.4%. Karl Fischer titration indicated a 2.5% water content. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for β-picoline. GC with FID analysis indicated one major peak (β-picoline) and only two impurities with individual peak areas greater than 0.1%. The peak areas for the impurities represented a total of 1% of lot 11108CI (0.6% and 0.4%, respectively).

To ensure stability, the bulk chemical was stored at room temperature in amber glass bottles sealed with Teflon^®^-lined lids under a nitrogen head space. Periodic reanalyses of the bulk chemical were performed by the study laboratory using GC by system A at the beginning and end of the 3-month and 2-year studies, and approximately every 6 months during the 2-year studies; no degradation of the bulk chemical occurred.

## I.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared five times for the 3-month studies and approximately every 4 weeks for the 2-year studies. The dose formulations were prepared by mixing β-picoline with tap water (Table I-1). The pH was adjusted, if necessary, to bring it within the range of 6 to 7.5 by the addition of acetic acid, with stirring. The dose formulations were stored protected from light in sealed polypropylene carboys at 5°C for up to 29 (3-month studies) or 42 (2-year studies) days.

The dose formulations were determined to be true solutions; therefore, no homogeneity studies were performed. Stability studies of 10 µg/mL formulations were performed by the analytical chemistry laboratory using a high-performance liquid chromatography (HPLC) method that included an HPLC instrument (Waters, Corporation, Milford, MA), a Luna C18 (150 mm × 4.6 mm) column (Phenomenex, Torrance, CA), with ultraviolet (UV) light detection at 254 nm, a mobile phase of 5:94:1 (v:v:v) acetonitrile:5mM sodium pentane sulfonate:glacial acetic acid, isocratic, and a flow rate of 1 mL/minute. Stability was confirmed for at least 42 days for formulations stored in sealed polyethylene bottles protected from light at 5°C and for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of β-picoline were performed by the study laboratory using HPLC/UV by a method similar to that described above. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations analyzed and used for rats and mice were within 10% of the target concentrations (Table I-2). Animal room samples of these dose formulations were also analyzed; all 15 animal room samples for rats and all 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed at least every 12 weeks. All 50 dose formulations analyzed and used for rats and all 50 for mice were within 10% of the target concentrations (Table I-3). Animal room samples were also analyzed; all 12 animal room samples for rats and all 12 for mice were within 10% of the target concentrations.

Table I-1 Preparation and Storage of Dose Formulations in the Drinking Water Studies of β-Picoline

Three-month Studies | Two-year Studies
The 78 and 156 mg/L dose formulations were prepared by adding the appropriate amounts of β-picoline with rinsing by pipette or, for the 312, 625, and 1,250 mg/L dose formulations, by graduated cylinder, into approximately half the required amount of tap water in a 15-gallon Nalgene^®^ calibrated tank, stirring with an overhead drum stirrer for approximately 15 minutes; then approximately 1 L of solution was dispensed through the tap into a beaker and poured back into the top of the tank with rinsing, then diluted to volume, and stirred an additional 5 minutes. The pH was determined and adjusted, if necessary, to bring it within the range of 6 to 7.5 by the addition of acetic acid, with stirring. The dose formulations were prepared five times. | Same as the 3-month studies through January 13, 2005, when the step requiring approximately 1 L of solution to be dispensed through the tap into a beaker and poured back into the top of the tank with rinsing was discontinued.
Chemical Lot Number
11108CI | 11108CI
Maximum Storage Time
29 days | 42 days
Storage Conditions
Stored in sealed clear polypropylene carboys at 5°C, protected from light | Same as 3-month studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

Table I-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Drinking Water Studies of β-Picoline

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Rats and Mice
November 5, 2003 | November 6, 2003 | 78 | 81.48 | +4
| | 156 | 164.9 | +6
| | 312 | 326.0 | +4
| | 625 | 657.4 | +5
| | 1,250 | 1,368 | +9
December 3, 2003 | December 5, 2003 | 78 | 75.84 | −3
| | 156 | 156.3 | 0
| | 312 | 311.4 | 0
| | 625 | 623.9 | 0
| | 1,250 | 1,243 | −1
January 20, 2004 | January 23, 2004 | 78 | 79.93 | +2
| | 156 | 157.8 | +1
| | 312 | 309.9 | −1
| | 625 | 673.9 | +8
| | 1,250 | 1,302 | +4
Animal Room Samples
Rats
November 5, 2003 | December 5–6, 2003 | 78 | 75.23 | −4
| | 156 | 154.0 | −1
| | 312 | 304.3 | −2
| | 625 | 618.0 | −1
| | 1,250 | 1,222 | −2
December 3, 2003 | January 26–27, 2004 | 78 | 73.80 | −5
| | 156 | 152.6 | −2
| | 312 | 307.1 | −2
| | 625 | 645.8 | +3
| | 1,250 | 1,229 | −2
January 20, 2004 | March 12–13, 2004 | 78 | 75.20 | −4
| | 156 | 150.1 | −4
| | 312 | 299.4 | −4
| | 625 | 641.4 | +3
| | 1,250 | 1,200 | −4
Mice
November 5, 2003 | December 5–6, 2003 | 78 | 73.39 | −6
| | 156 | 151.5 | −3
| | 312 | 292.7 | −6
| | 625 | 617.6 | −1
| | 1,250 | 1,198 | −4
December 3, 2003 | January 26–27, 2004 | 78 | 79.30 | +2
| | 156 | 158.6 | +2
| | 312 | 311.2 | 0
| | 625 | 677.5 | +8
| | 1,250 | 1,308 | +5
January 20, 2004 | March 12–13, 2004 | 78 | 74.65 | −4
| | 156 | 149.6 | −4
| | 312 | 303.4 | −3
| | 625 | 633.5 | +1
| | 1,250 | 1,214 | −3

^a^ Results of duplicate analyses.

Table I-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-year Drinking Water Studies of β-Picoline

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Rats
October 26, 2004 | October 28, 2004 | 156.25 | 154.5 | −1
| | 312.5 | 320.0 | +2
| | 312.5 | 327.4 | +5
| | 625 | 640.3 | +2
| | 625 | 639.3 | +2
| December 7–9, 2004^b^ | 156.25 | 154.0 | −2
| | 312.5 | 313.8 | 0
| | 625 | 621.8 | −1
January 13, 2005 | January 17, 2005 | 156.25 | 156.3 | 0
| | 312.5 | 318.8 | +2
| | 312.5 | 330.1 | +6
| | 625 | 646.6 | +4
| | 625 | 637.6 | +2
March 28, 2005 | March 29–30, 2005 | 156.25 | 163.5 | +5
| | 312.5 | 322.6 | +3
| | 312.5 | 333.6 | +7
| | 625 | 633.0 | +1
| | 625 | 631.7 | +1
June 14, 2005 | June 15, 2005 | 156.25 | 156.1 | 0
| | 312.5 | 306.7 | −2
| | 312.5 | 319.7 | +2
| | 625 | 607.7 | −3
| | 625 | 626.9 | 0
| July 28–29, 2005^b^ | 156.25 | 155.1 | −1
| | 312.5 | 312.9 | 0
| | 625 | 626.9 | 0
September 1, 2005 | September 9, 12–13, 2005 | 156.25 | 153.9 | −2
| | 312.5 | 304.9 | −2
| | 312.5 | 304.9 | −2
| | 625 | 611.1 | −2
| | 625 | 620.8 | −1
November 15, 2005 | November 16–17, 2005 | 156.25 | 147.9 | −5
| | 312.5 | 317.8 | +2
| | 312.5 | 306.0 | −2
| | 625 | 622.8 | 0
| | 625 | 614.3 | −2
February 2, 2006 | February 7–8, 2006 | 156.25 | 156.6 | 0
| | 312.5 | 326.7 | +5
| | 312.5 | 316.0 | +1
| | 625 | 637.0 | +2
| | 625 | 637.0 | +2
| March 14–15, 2006^b^ | 156.25 | 151.9 | −3
| | 312.5 | 321.2 | +3
| | 625 | 625.3 | 0
April 20, 2006 | April 21–22, 2006 | 156.25 | 155.7 | 0
| | 312.5 | 320.5 | +3
| | 312.5 | 307.6 | −2
| | 625 | 622.1 | −1
| | 625 | 617.9 | −1
July 6, 2006 | July 11–12, 2006 | 156.25 | 154.7 | −1
| | 312.5 | 322.0 | +3
| | 312.5 | 312.5 | 0
| | 625 | 611.9 | −2
| | 625 | 624.5 | 0
September 25, 2006 | September 27, 2006 | 156.25 | 154.1 | −1
| | 312.5 | 322.3 | +3
| | 312.5 | 312.7 | 0
| | 625 | 613.4 | −2
| | 625 | 629.5 | +1
| November 14–15, 2006^b^ | 156.25 | 150.7 | −4
| | 312.5 | 313.7 | 0
| | 625 | 599.6 | −4
Mice
October 26, 2004 | October 28, 2004 | 312.5 | 320.0 | +2
| | 312.5 | 327.4 | +5
| | 625 | 640.3 | +2
| | 625 | 639.3 | +2
| | 1,250 | 1,277 | +2
| December 7–9, 2004^b^ | 312.5 | 309.6 | −1
| | 625 | 629.9 | +1
| | 1,250 | 1,243 | −1
January 13, 2005 | January 17, 2005 | 312.5 | 318.8 | +2
| | 312.5 | 330.1 | +6
| | 625 | 646.6 | +4
| | 625 | 637.6 | +2
| | 1,250 | 1,277 | +2
March 28, 2005 | March 29–30, 2005 | 312.5 | 322.6 | +3
| | 312.5 | 333.6 | +7
| | 625 | 633.0 | +1
| | 625 | 631.7 | +1
| | 1,250 | 1,277 | +2
June 14, 2005 | June 15, 2005 | 312.5 | 306.7 | −2
| | 312.5 | 319.7 | +2
| | 625 | 607.7 | −3
| | 625 | 626.9 | 0
| | 1,250 | 1,237 | −1
| July 28–29, 2005^b^ | 312.5 | 311.5 | 0
| | 625 | 597.5 | −4
| | 1,250 | 1,199 | −4
September 1, 2005 | September 9, 12–13, 2005 | 312.5 | 304.9 | −2
| | 312.5 | 304.9 | −2
| | 625 | 611.1 | −2
| | 625 | 620.8 | −1
| | 1,250 | 1,214 | −3
November 15, 2005 | November 16–17, 2005 | 312.5 | 317.8 | +2
| | 312.5 | 306.0 | −2
| | 625 | 622.8 | 0
| | 625 | 614.3 | −2
| | 1,250 | 1,231 | −2
February 2, 2006 | February 7–8, 2006 | 312.5 | 326.7 | +5
| | 312.5 | 316.0 | +1
| | 625 | 637.0 | +2
| | 625 | 637.0 | +2
| | 1,250 | 1,250 | 0
| March 14–15, 2006^b^ | 312.5 | 308.9 | −1
| | 625 | 617.0 | −1
| | 1,250 | 1,238 | −1
April 20, 2006 | April 21–22, 2006 | 312.5 | 320.5 | +3
| | 312.5 | 307.6 | −2
| | 625 | 622.1 | −1
| | 625 | 617.9 | −1
| | 1,250 | 1,205 | −4
July 6, 2006 | July 11–12, 2006 | 312.5 | 322.0 | +3
| | 312.5 | 312.5 | 0
| | 625 | 611.9 | −2
| | 625 | 624.5 | 0
| | 1,250 | 1,237 | −1
September 25, 2006 | September 27, 2006 | 312.5 | 322.3 | +3
| | 312.5 | 312.7 | 0
| | 625 | 613.4 | −2
| | 625 | 629.5 | +1
| | 1,250 | 1,266 | +1
| November 14–15, 2006^b^ | 312.5 | 305.5 | −2
| | 625 | 619.6 | −1
| | 1,250 | 1,226 | −2

^a^ Results of duplicate analyses.

^b^ Animal room samples.

Figure I-1

Infrared Absorption Spectrum of β-Picoline