# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156 mg/L | 312 mg/L | 625 mg/L
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 356 ± 5 | 352 ± 4 | 356 ± 4 | 332 ± 4**
L. Cauda epididymis | 0.1458 ± 0.0036 | 0.1446 ± 0.0036 | 0.1436 ± 0.0018 | 0.1455 ± 0.0038
L. Epididymis | 0.4315 ± 0.0046 | 0.4169 ± 0.0090 | 0.4289 ± 0.0057 | 0.4265 ± 0.0043
L. Testis | 1.5383 ± 0.0107 | 1.4650 ± 0.0272* | 1.4857 ± 0.0156 | 1.4805 ± 0.0103
Spermatid measurements
Spermatid heads (10^6^/testis) | 181.13 ± 5.24 | 169.50 ± 10.42 | 167.88 ± 6.28 | 175.63 ± 5.67
Spermatid heads (10^6^/g testis) | 131.7 ± 3.9 | 128.1 ± 6.3 | 125.0 ± 3.9 | 134.0 ± 4.3
Epididymal spermatozoal measurements
Sperm motility (%) | 77.2 ± 0.9 | 77.7 ± 1.2 | 78.0 ± 1.2 | 78.8 ± 1.0
Sperm (10^6^/cauda epididymis) | 113.13 ± 5.98 | 109.38 ± 4.49 | 121.25 ± 4.63 | 106.13 ± 3.73
Sperm (10^6^/g cauda epididymis) | 777.6 ± 40.9 | 760.9 ± 36.1 | 845.0 ± 32.5 | 730.7 ± 23.8

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (cauda epididymis and epididymis weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-2 Estrous Cycle Characterization for Female Rats in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156 mg/L | 312 mg/L | 625 mg/L
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 207 ± 5 | 205 ± 4 | 205 ± 3 | 192 ± 3*
Proportion of regular cycling females^b^ | 6/6 | 4/6 | 8/10 | 8/9
Estrous cycle length (days) | 4.8 ± 0.11^c^ | 5.3 ± 0.33^c^ | 5.1 ± 0.10 | 5.1 ± 0.06^d^
Estrous stages (% of cycle)
Diestrus | 70.0 | 74.2 | 61.7 | 65.0
Proestrus | 7.5 | 7.5 | 10.8 | 10.8
Estrus | 17.5 | 15.8 | 25.0 | 23.3
Metestrus | 5.0 | 2.5 | 2.5 | 0.8

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices indicated a significantly higher probability of extended estrus for female rats in the 312 and 625 mg/L groups compared to the control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in four of 10 animals.

^d^ Estrous cycle was longer than 12 days or unclear in one of 10 animals.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Exposed to β-Picoline in Drinking Water for Three Months

Stage | Comparison^a^ | P-Value | Trend^b^
Overall Tests | Overall | <0.001
Overall Tests | Low vs. controls | 0.819 | N
Overall Tests | Mid vs. controls | <0.001 | –
Overall Tests | High vs. controls | <0.001 | –
Extended Estrus | Overall | 0.347
Extended Estrus | Low vs. controls | 0.836 | N
Extended Estrus | Mid vs. controls | 0.049 | –
Extended Estrus | High vs. controls | 0.842 | –
Extended Diestrus | Overall | <0.001
Extended Diestrus | Low vs. controls | 0.709 | –
Extended Diestrus | Mid vs. controls | <0.001 | –
Extended Diestrus | High vs. controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | Low vs. controls | 1 | –
Extended Metestrus | Mid vs. controls | 1 | –
Extended Metestrus | High vs. controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | Low vs. controls | 1 | –
Extended Proestrus | Mid vs. controls | 1 | –
Extended Proestrus | High vs. controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | Low vs. controls | 1 | –
Skipped Estrus | Mid vs. controls | 1 | –
Skipped Estrus | High vs. controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | Low vs. controls | 1 | –
Skipped Diestrus | Mid vs. controls | 1 | –
Skipped Diestrus | High vs. controls | 1 | –
Summary of Significant Groups
Overall Tests | Mid vs. controls | <0.001 | –
Overall Tests | High vs. controls | <0.001 | –
Extended Estrus | Mid vs. controls | 0.049 | –
Extended Diestrus | Mid vs. controls | <0.001 | –
Extended Diestrus | High vs. controls | <0.001 | –

^a^ Controls = Vehicle Control, Low = 156 mg/L, Mid = 312 mg/L, High = 625 mg/L.

^b^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 38.5 ± 1.3 | 39.9 ± 1.3 | 39.6 ± 1.1 | 37.9 ± 1.0
L. Cauda epididymis | 0.0152 ± 0.0005 | 0.0151 ± 0.0004 | 0.0165 ± 0.0007 | 0.0289 ± 0.0134
L. Epididymis | 0.0453 ± 0.0013 | 0.0433 ± 0.0009 | 0.0454 ± 0.0011 | 0.0443 ± 0.0010
L. Testis | 0.1108 ± 0.0022 | 0.1102 ± 0.0021 | 0.1096 ± 0.0031 | 0.1100 ± 0.0026
Spermatid measurements
Spermatid heads (10^6^/testis) | 19.73 ± 0.71 | 18.55 ± 0.72 | 19.71 ± 1.00 | 18.67 ± 0.95
Spermatid heads (10^6^/g testis) | 195.8 ± 6.1 | 187.1 ± 7.2 | 198.2 ± 8.6 | 189.4 ± 8.0
Epididymal spermatozoal measurements
Sperm motility (%) | 81.3 ± 0.7 | 81.9 ± 0.6 | 81.8 ± 0.9 | 80.3 ± 0.6
Sperm (10^6^/cauda epididymis) | 18.30 ± 1.20 | 17.25 ± 1.37 | 19.33 ± 2.42 | 15.70 ± 1.14
Sperm (10^6^/g cauda epididymis) | 1,231.8 ± 103.5 | 1,136.3 ± 72.2 | 1,161.6 ± 116.4 | 1,026.0 ± 58.9

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-5 Estrous Cycle Characterization for Female Mice in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 27.2 ± 0.9 | 28.0 ± 1.1 | 27.6 ± 0.5 | 27.9 ± 0.9
Proportion of regular cycling females^b^ | 10/10 | 9/10 | 10/10 | 9/9
Estrous cycle length (days) | 3.9 ± 0.13 | 4.1 ± 0.15^c^ | 4.2 ± 0.18 | 4.3 ± 0.62^c^
Estrous stages (% of cycle)
Diestrus | 35.8 | 33.3 | 35.8 | 43.3
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 41.7 | 45.8 | 43.3 | 39.2
Metestrus | 22.5 | 20.8 | 20.8 | 17.5

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices indicated no significant differences in the probability of altered cycle for any exposed group compared to the control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in one of 10 animals.

Figure H-1

Vaginal Cytology Plots for Female Rats in the Three-month Drinking Water Study of β-Picoline^a^

^a^D = diestrus, P = proestrus, E = estrus, M = metestrus.