# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 356 ± 5 | 349 ± 7 | 352 ± 4 | 356 ± 4 | 332 ± 4** | 298 ± 5**
Heart
Absolute | 0.97 ± 0.01 | 0.94 ± 0.02 | 0.98 ± 0.01 | 0.96 ± 0.02 | 0.92 ± 0.03* | 0.82 ± 0.02**
Relative | 2.735 ± 0.032 | 2.699 ± 0.036 | 2.779 ± 0.036 | 2.711 ± 0.049 | 2.771 ± 0.060 | 2.769 ± 0.040
R. Kidney
Absolute | 1.09 ± 0.02 | 1.05 ± 0.02 | 1.08 ± 0.01 | 1.14 ± 0.02 | 1.10 ± 0.02 | 1.07 ± 0.03
Relative | 3.046 ± 0.060 | 3.018 ± 0.037 | 3.055 ± 0.034 | 3.196 ± 0.033* | 3.324 ± 0.048** | 3.597 ± 0.062**
Liver
Absolute | 12.73 ± 0.36 | 12.22 ± 0.32 | 12.63 ± 0.24 | 12.47 ± 0.23 | 11.52 ± 0.16** | 10.38 ± 0.23**
Relative | 35.671 ± 0.686 | 35.001 ± 0.436 | 35.848 ± 0.440 | 35.063 ± 0.415 | 34.763 ± 0.393 | 34.894 ± 0.432
Lung
Absolute | 1.98 ± 0.08 | 1.89 ± 0.07 | 1.82 ± 0.05 | 1.92 ± 0.07 | 1.80 ± 0.07 | 1.58 ± 0.06**
Relative | 5.560 ± 0.226 | 5.419 ± 0.183 | 5.186 ± 0.178 | 5.410 ± 0.186 | 5.425 ± 0.226 | 5.296 ± 0.160
R. Testis
Absolute | 1.430 ± 0.020 | 1.423 ± 0.022 | 1.422 ± 0.015 | 1.428 ± 0.014 | 1.405 ± 0.020 | 1.344 ± 0.020**
Relative | 4.016 ± 0.060 | 4.082 ± 0.046 | 4.042 ± 0.065 | 4.022 ± 0.065 | 4.243 ± 0.072** | 4.520 ± 0.029**
Thymus
Absolute | 0.311 ± 0.013 | 0.314 ± 0.014 | 0.318 ± 0.015 | 0.292 ± 0.008 | 0.288 ± 0.013 | 0.262 ± 0.012*
Relative | 0.874 ± 0.039 | 0.901 ± 0.037 | 0.903 ± 0.038 | 0.824 ± 0.030 | 0.870 ± 0.042 | 0.884 ± 0.045
Female
Necropsy body wt | 207 ± 5 | 206 ± 2 | 205 ± 4 | 205 ± 3 | 192 ± 3** | 177 ± 4**
Heart
Absolute | 0.64 ± 0.01 | 0.66 ± 0.01 | 0.66 ± 0.02 | 0.64 ± 0.01 | 0.60 ± 0.02 | 0.55 ± 0.01**
Relative | 3.082 ± 0.069 | 3.195 ± 0.070 | 3.202 ± 0.054 | 3.114 ± 0.049 | 3.126 ± 0.072 | 3.118 ± 0.056
R. Kidney
Absolute | 0.69 ± 0.02 | 0.74 ± 0.02 | 0.72 ± 0.01 | 0.72 ± 0.01 | 0.71 ± 0.02 | 0.69 ± 0.02
Relative | 3.358 ± 0.076 | 3.563 ± 0.048 | 3.520 ± 0.052 | 3.517 ± 0.055 | 3.702 ± 0.056** | 3.894 ± 0.078**
Liver
Absolute | 6.69 ± 0.21 | 6.62 ± 0.15 | 6.37 ± 0.19 | 6.28 ± 0.13 | 6.02 ± 0.13** | 5.42 ± 0.09**
Relative | 32.295 ± 0.521 | 32.124 ± 0.543 | 31.040 ± 0.433 | 30.585 ± 0.369* | 31.289 ± 0.290* | 30.651 ± 0.408*
Lung
Absolute | 1.29 ± 0.03 | 1.24 ± 0.03 | 1.23 ± 0.04 | 1.26 ± 0.03 | 1.22 ± 0.06 | 1.11 ± 0.03**
Relative | 6.274 ± 0.200 | 6.008 ± 0.127 | 6.004 ± 0.161 | 6.147 ± 0.163 | 6.368 ± 0.339 | 6.267 ± 0.098
Thymus
Absolute | 0.281 ± 0.012 | 0.253 ± 0.010 | 0.259 ± 0.010 | 0.246 ± 0.010* | 0.231 ± 0.012** | 0.216 ± 0.008**
Relative | 1.358 ± 0.049 | 1.232 ± 0.053 | 1.262 ± 0.033 | 1.200 ± 0.057 | 1.201 ± 0.050 | 1.219 ± 0.039

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 38.5 ± 1.3 | 39.5 ± 0.8 | 39.9 ± 1.2 | 39.9 ± 1.3 | 39.6 ± 1.1 | 37.9 ± 1.0
Heart
Absolute | 0.20 ± 0.01 | 0.22 ± 0.01 | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01
Relative | 5.346 ± 0.284 | 5.625 ± 0.165 | 5.385 ± 0.194 | 5.527 ± 0.244 | 5.625 ± 0.258 | 5.951 ± 0.306
R. Kidney
Absolute | 0.30 ± 0.01 | 0.33 ± 0.01 | 0.33 ± 0.01 | 0.33 ± 0.01 | 0.32 ± 0.01 | 0.31 ± 0.01
Relative | 7.923 ± 0.264 | 8.252 ± 0.193 | 8.318 ± 0.237 | 8.289 ± 0.239 | 7.982 ± 0.185 | 8.112 ± 0.215
Liver
Absolute | 1.79 ± 0.05 | 1.90 ± 0.05 | 1.97 ± 0.08 | 2.01 ± 0.09 | 2.02 ± 0.09 | 1.84 ± 0.05
Relative | 46.637 ± 0.816 | 48.228 ± 0.895 | 49.402 ± 0.715 | 50.212 ± 1.084* | 50.851 ± 0.936** | 48.599 ± 0.589
Lung
Absolute | 0.31 ± 0.02 | 0.32 ± 0.01 | 0.28 ± 0.01 | 0.34 ± 0.01 | 0.34 ± 0.03 | 0.34 ± 0.01
Relative | 8.100 ± 0.643 | 8.163 ± 0.272 | 7.136 ± 0.253 | 8.603 ± 0.312 | 8.430 ± 0.646 | 9.113 ± 0.379
R. Testis
Absolute | 0.115 ± 0.003 | 0.118 ± 0.003 | 0.119 ± 0.002 | 0.115 ± 0.002 | 0.112 ± 0.003 | 0.115 ± 0.002
Relative | 3.020 ± 0.130 | 3.000 ± 0.074 | 3.003 ± 0.086 | 2.905 ± 0.107 | 2.846 ± 0.098 | 3.055 ± 0.095
Thymus
Absolute | 0.049 ± 0.004 | 0.050 ± 0.003 | 0.058 ± 0.005 | 0.054 ± 0.003 | 0.054 ± 0.003 | 0.046 ± 0.004
Relative | 1.276 ± 0.107 | 1.264 ± 0.058 | 1.439 ± 0.093 | 1.353 ± 0.059 | 1.371 ± 0.090 | 1.212 ± 0.088
Female
Necropsy body wt | 27.2 ± 0.9 | 27.6 ± 1.0 | 30.1 ± 1.0 | 28.0 ± 1.1 | 27.6 ± 0.5 | 27.9 ± 0.9
Heart
Absolute | 0.16 ± 0.00 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01
Relative | 5.902 ± 0.256 | 6.072 ± 0.310 | 5.474 ± 0.232 | 5.714 ± 0.262 | 6.146 ± 0.184 | 5.776 ± 0.206
R. Kidney
Absolute | 0.17 ± 0.00 | 0.18 ± 0.00 | 0.19 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.00 | 0.17 ± 0.01
Relative | 6.403 ± 0.166 | 6.409 ± 0.160 | 6.316 ± 0.243 | 6.142 ± 0.147 | 6.193 ± 0.138 | 6.274 ± 0.125
Liver
Absolute | 1.17 ± 0.04 | 1.27 ± 0.04 | 1.36 ± 0.03** | 1.25 ± 0.05 | 1.24 ± 0.02 | 1.26 ± 0.05
Relative | 43.251 ± 1.075 | 46.058 ± 0.702 | 45.281 ± 0.899 | 44.763 ± 0.798 | 44.928 ± 1.015 | 45.250 ± 1.043
Lung
Absolute | 0.30 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.02 | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.25 ± 0.02**
Relative | 11.005 ± 0.494 | 10.777 ± 0.500 | 8.931 ± 0.652* | 9.726 ± 0.383* | 10.022 ± 0.364* | 8.787 ± 0.469**
Thymus
Absolute | 0.055 ± 0.004 | 0.055 ± 0.004 | 0.060 ± 0.003 | 0.049 ± 0.002 | 0.050 ± 0.001 | 0.054 ± 0.001
Relative | 2.043 ± 0.139 | 2.026 ± 0.161 | 2.005 ± 0.071 | 1.769 ± 0.100 | 1.807 ± 0.065 | 1.965 ± 0.075

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).